# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematology
Hematocrit (auto) (%)
Day 4 | 46.1 ± 0.6 | 45.0 ± 0.7 | 46.1 ± 0.6 | 45.9 ± 0.7 | 47.8 ± 0.7 | 50.6 ± 1.0**
Day 23 | 50.1 ± 0.7 | 52.0 ± 0.8 | 51.2 ± 0.6 | 49.5 ± 0.2 | 50.9 ± 0.5 | 49.9 ± 0.6
Week 13 | 47.9 ± 0.3 | 47.7 ± 0.3 | 47.8 ± 0.3 | 47.0 ± 0.4 | 47.2 ± 0.3 | 47.0 ± 0.6
Hemoglobin (g/dL)
Day 4 | 13.7 ± 0.2 | 13.4 ± 0.2 | 13.6 ± 0.2 | 13.7 ± 0.2 | 14.2 ± 0.2 | 15.0 ± 0.3**
Day 23 | 15.0 ± 0.2 | 15.6 ± 0.2 | 15.6 ± 0.2 | 15.1 ± 0.1 | 15.3 ± 0.2 | 15.4 ± 0.2
Week 13 | 15.1 ± 0.1 | 14.9 ± 0.1 | 15.0 ± 0.1 | 14.8 ± 0.2 | 15.0 ± 0.1 | 14.8 ± 0.1
Erythrocytes (10^6^/μL)
Day 4 | 7.36 ± 0.09 | 7.08 ± 0.12 | 7.29 ± 0.09 | 7.35 ± 0.13 | 7.64 ± 0.14 | 8.06 ± 0.16*
Day 23 | 7.80 ± 0.11 | 8.08 ± 0.13 | 8.05 ± 0.08 | 7.73 ± 0.04 | 7.91 ± 0.08 | 8.09 ± 0.08
Week 13 | 9.09 ± 0.05 | 9.06 ± 0.05 | 9.00 ± 0.05 | 8.84 ± 0.07** | 8.89 ± 0.05** | 8.84 ± 0.10*
Reticulocytes (10^6^/μL)
Day 4 | 0.52 ± 0.02 | 0.56 ± 0.02 | 0.57 ± 0.03 | 0.38 ± 0.02 | 0.49 ± 0.02 | 0.39 ± 0.01**
Day 23 | 0.32 ± 0.02 | 0.30 ± 0.01 | 0.27 ± 0.01 | 0.33 ± 0.01 | 0.33 ± 0.07 | 0.19 ± 0.04
Week 13 | 0.24 ± 0.05 | 0.24 ± 0.05 | 0.23 ± 0.08 | 0.24 ± 0.06 | 0.23 ± 0.08 | 0.22 ± 0.10
Mean cell volume (fL)
Day 4 | 62.6 ± 0.4 | 63.6 ± 0.3 | 63.2 ± 0.3 | 62.5 ± 0.3 | 62.6 ± 0.4 | 62.8 ± 0.2
Day 23 | 64.3 ± 0.3 | 64.3 ± 0.4 | 63.7 ± 0.3 | 63.9 ± 0.2 | 64.3 ± 0.4 | 61.6 ± 0.5**
Week 13 | 52.7 ± 0.2 | 52.7 ± 0.2 | 53.2 ± 0.2 | 53.1 ± 0.2 | 53.0 ± 0.2 | 53.2 ± 0.3
Mean cell hemoglobin (pg)
Day 4 | 18.6 ± 0.1 | 18.9 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.2 | 18.6 ± 0.1
Day 23 | 19.3 ± 0.1 | 19.3 ± 0.1 | 19.3 ± 0.1 | 19.5 ± 0.1 | 19.4 ± 0.1 | 19.0 ± 0.1
Week 13 | 16.6 ± 0.1 | 16.5 ± 0.1 | 16.7 ± 0.1 | 16.7 ± 0.1 | 16.8 ± 0.1 | 16.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 29.6 ± 0.2 | 29.8 ± 0.1 | 29.6 ± 0.2 | 29.8 ± 0.2 | 29.7 ± 0.3 | 29.6 ± 0.1
Day 23 | 30.0 ± 0.1 | 30.0 ± 0.1 | 30.4 ± 0.2 | 30.5 ± 0.2 | 30.1 ± 0.2 | 30.9 ± 0.2**
Week 13 | 31.4 ± 0.1 | 31.3 ± 0.2 | 31.4 ± 0.1 | 31.5 ± 0.2 | 31.7 ± 0.2 | 31.6 ± 0.2
Platelets (10^3^/μL)
Day 4 | 1,088.7 ± 29.3 | 1,091.5 ± 30.7 | 1,128.2 ± 32.3 | 1,030.7 ± 41.7 | 1,057.9 ± 66.1 | 1,196.5 ± 31.1
Day 23 | 926.8 ± 21.4 | 890.1 ± 15.4 | 848.2 ± 15.0** | 832.1 ± 15.5** | 858.1 ± 25.7* | 724.0 ± 43.2**
Week 13 | 623.4 ± 24.4 | 651.9 ± 25.5 | 616.3 ± 22.6 | 600.7 ± 23.1 | 538.0 ± 49.4 | 589.5 ± 29.2
Leukocytes (10^3^/μL)
Day 4 | 10.17 ± 0.27 | 8.66 ± 0.49 | 9.92 ± 0.38 | 10.25 ± 0.50 | 9.01 ± 0.59 | 10.08 ± 0.45
Day 23 | 9.77 ± 0.35 | 9.61 ± 0.36 | 10.14 ± 0.40 | 9.70 ± 0.49 | 10.27 ± 0.40 | 8.63 ± 0.42
Week 13 | 7.79 ± 0.45 | 8.15 ± 0.37 | 7.69 ± 0.51 | 7.75 ± 0.27 | 8.11 ± 0.30 | 8.52 ± 0.43
Segmented neutrophils (10^3^/μL)
Day 4 | 1.13 ± 0.05 | 0.97 ± 0.06 | 1.15 ± 0.05 | 1.10 ± 0.05 | 1.05 ± 0.05 | 1.12 ± 0.05
Day 23 | 1.10 ± 0.09 | 1.03 ± 0.04 | 1.02 ± 0.04 | 1.21 ± 0.06 | 1.09 ± 0.07 | 1.08 ± 0.13
Week 13 | 1.35 ± 0.09 | 1.43 ± 0.14 | 1.34 ± 0.10 | 1.38 ± 0.07 | 1.82 ± 0.14* | 1.67 ± 0.10*
Lymphocytes (10^3^/μL)
Day 4 | 8.66 ± 0.24 | 7.38 ± 0.43 | 8.40 ± 0.37 | 8.76 ± 0.44 | 7.62 ± 0.55 | 8.63 ± 0.42
Day 23 | 8.39 ± 0.37 | 8.31 ± 0.33 | 8.85 ± 0.36 | 8.23 ± 0.43 | 8.92 ± 0.33 | 7.31 ± 0.33
Week 13 | 6.08 ± 0.37 | 6.38 ± 0.25 | 6.01 ± 0.47 | 6.04 ± 0.29 | 5.91 ± 0.18 | 6.47 ± 0.36
Monocytes (10^3^/μL)
Day 4 | 0.30 ± 0.02 | 0.24 ± 0.02 | 0.27 ± 0.02 | 0.30 ± 0.03 | 0.24 ± 0.02 | 0.23 ± 0.02
Day 23 | 0.17 ± 0.02 | 0.16 ± 0.01 | 0.17 ± 0.02 | 0.17 ± 0.02 | 0.16 ± 0.01 | 0.15 ± 0.01
Week 13 | 0.21 ± 0.02 | 0.20 ± 0.02 | 0.22 ± 0.02 | 0.19 ± 0.01 | 0.23 ± 0.02 | 0.22 ± 0.02
Basophils (10^3^/μL)
Day 4 | 0.040 ± 0.003 | 0.041 ± 0.005 | 0.057 ± 0.012 | 0.047 ± 0.003 | 0.038 ± 0.007 | 0.053 ± 0.006
Day 23 | 0.041 ± 0.003 | 0.038 ± 0.005 | 0.033 ± 0.004 | 0.040 ± 0.004 | 0.036 ± 0.003 | 0.035 ± 0.004
Week 13 | 0.046 ± 0.005 | 0.028 ± 0.004* | 0.033 ± 0.004 | 0.034 ± 0.004 | 0.035 ± 0.006 | 0.048 ± 0.010
Eosinophils (10^3^/μL)
Day 4 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.01 | 0.07 ± 0.02 | 0.04 ± 0.00
Day 23 | 0.08 ± 0.03 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.02 | 0.07 ± 0.01
Week 13 | 0.11 ± 0.01 | 0.11 ± 0.02 | 0.09 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.01
Clinical Chemistry
Urea nitrogen (mg/dL)
Day 4 | 13.0 ± 0.5 | 12.5 ± 0.4 | 12.5 ± 0.3 | 14.4 ± 0.6 | 15.2 ± 0.9 | 16.9 ± 1.1**
Day 23 | 13.9 ± 0.3 | 15.6 ± 0.7 | 16.3 ± 0.5** | 16.6 ± 1.1* | 17.8 ± 1.2** | 17.9 ± 1.4**
Week 13 | 15.3 ± 0.5 | 15.7 ± 0.3 | 15.7 ± 0.5 | 14.8 ± 0.3 | 15.9 ± 0.4 | 15.9 ± 0.3
Creatinine (mg/dL)
Day 4 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.43 ± 0.02 | 0.43 ± 0.02 | 0.42 ± 0.01 | 0.43 ± 0.02
Day 23 | 0.47 ± 0.02 | 0.47 ± 0.02 | 0.45 ± 0.02 | 0.47 ± 0.02 | 0.46 ± 0.02 | 0.47 ± 0.02
Week 13 | 0.56 ± 0.02 | 0.56 ± 0.02 | 0.54 ± 0.02 | 0.56 ± 0.02 | 0.56 ± 0.02 | 0.58 ± 0.01
Glucose (mg/dL)
Week 13 | 140 ± 3 | 139 ± 4 | 146 ± 6 | 130 ± 4 | 134 ± 3 | 136 ± 3
Total protein (g/dL)
Day 4 | 5.6 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.8 ± 0.1 | 6.1 ± 0.1**
Day 23 | 6.3 ± 0.1 | 6.4 ± 0.1 | 6.3 ± 0.1 | 6.1 ± 0.1 | 6.1 ± 0.1 | 5.7 ± 0.1**
Week 13 | 6.8 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1** | 6.4 ± 0.1**
Albumin (g/dL)
Day 4 | 4.0 ± 0.0 | 4.0 ± 0.1 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.1 ± 0.1 | 4.4 ± 0.1**
Day 23 | 4.3 ± 0.1 | 4.3 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.1 ± 0.1*
Week 13 | 4.5 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.0* | 4.4 ± 0.0**
Alanine aminotransferase (IU/L)
Day 4 | 48 ± 2 | 52 ± 1 | 49 ± 2 | 46 ± 1 | 45 ± 2 | 39 ± 2**
Day 23 | 50 ± 1 | 55 ± 2 | 53 ± 2 | 56 ± 2 | 50 ± 3 | 52 ± 3
Week 13 | 142 ± 16 | 98 ± 8 | 126 ± 16 | 96 ± 8 | 115 ± 11 | 80 ± 6**
Alkaline phosphatase (IU/L)
Day 4 | 615 ± 15 | 628 ± 13 | 637 ± 12 | 601 ± 15 | 633 ± 17 | 647 ± 14
Day 23 | 461 ± 10 | 460 ± 11 | 447 ± 10 | 474 ± 9 | 472 ± 7 | 395 ± 27
Week 13 | 208 ± 4 | 200 ± 2 | 206 ± 3 | 199 ± 3 | 204 ± 4 | 217 ± 4
Creatine kinase (IU/L)
Day 4 | 374 ± 36 | 383 ± 76 | 441 ± 58 | 435 ± 61 | 421 ± 40 | 407 ± 38
Day 23 | 290 ± 45 | 290 ± 51 | 255 ± 32 | 266 ± 40 | 244 ± 23 | 244 ± 39
Week 13 | 135 ± 21 | 161 ± 38 | 129 ± 19 | 110 ± 9 | 135 ± 35 | 146 ± 26
Sorbitol dehydrogenase (IU/L)
Day 4 | 14 ± 0 | 13 ± 1 | 13 ± 0 | 14 ± 0 | 13 ± 0 | 15 ± 0
Day 23 | 16 ± 1 | 16 ± 1 | 16 ± 1 | 16 ± 1 | 15 ± 1 | 14 ± 1
Week 13 | 46 ± 6 | 32 ± 3 | 40 ± 5 | 33 ± 4 | 44 ± 5 | 31 ± 2
Bile salts (µmol/L)
Day 4 | 7.5 ± 0.8 | 7.3 ± 0.7 | 7.8 ± 0.8 | 10.4 ± 1.0 | 7.5 ± 0.7 | 7.5 ± 1.1
Day 23 | 5.8 ± 1.3 | 7.7 ± 1.1 | 4.5 ± 0.6 | 5.9 ± 0.8 | 5.3 ± 1.4 | 5.1 ± 0.7
Week 13 | 5.9 ± 1.0 | 6.6 ± 1.3 | 7.0 ± 1.6 | 4.9 ± 0.6 | 6.3 ± 1.7 | 10.5 ± 1.3
Female
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 9
Week 13 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%)
Day 4 | 47.7 ± 0.7 | 49.1 ± 1.2 | 47.9 ± 0.7 | 48.8 ± 0.8 | 47.9 ± 0.8 | 50.0 ± 1.0
Day 23 | 48.2 ± 0.6 | 48.1 ± 0.6 | 48.6 ± 0.6 | 49.4 ± 0.7 | 47.7 ± 0.6 | 47.6 ± 0.8
Week 13 | 44.7 ± 0.5 | 45.3 ± 0.5 | 45.1 ± 0.5 | 45.7 ± 0.4 | 45.3 ± 0.4 | 43.8 ± 0.4
Hemoglobin (g/dL)
Day 4 | 14.1 ± 0.2 | 14.5 ± 0.3 | 14.2 ± 0.2 | 14.3 ± 0.3 | 14.1 ± 0.2 | 14.8 ± 0.3
Day 23 | 15.3 ± 0.2 | 15.6 ± 0.2 | 15.4 ± 0.2 | 15.8 ± 0.2 | 15.2 ± 0.2 | 15.0 ± 0.2
Week 13 | 14.6 ± 0.1 | 14.8 ± 0.1 | 14.8 ± 0.2 | 14.9 ± 0.1 | 14.7 ± 0.1 | 14.4 ± 0.1
Erythrocytes (10^6^/μL)
Day 4 | 7.58 ± 0.12 | 7.80 ± 0.18 | 7.70 ± 0.12 | 7.72 ± 0.15 | 7.67 ± 0.15 | 8.06 ± 0.16
Day 23 | 8.13 ± 0.12 | 8.17 ± 0.08 | 8.21 ± 0.08 | 8.32 ± 0.13 | 8.03 ± 0.10 | 8.05 ± 0.12
Week 13 | 8.13 ± 0.07 | 8.26 ± 0.09 | 8.17 ± 0.09 | 8.29 ± 0.08 | 8.19 ± 0.07 | 7.99 ± 0.06
Reticulocytes (10^6^/μL)
Day 4 | 0.45 ± 0.02 | 0.46 ± 0.02 | 0.42 ± 0.03 | 0.45 ± 0.03 | 0.37 ± 0.02* | 0.34 ± 0.03**
Day 23 | 0.15 ± 0.01 | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.19 ± 0.01** | 0.20 ± 0.01** | 0.21 ± 0.01**
Week 13 | 0.19 ± 0.01 | 0.17 ± 0.01 | 0.22 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01
Mean cell volume (fL)
Day 4 | 62.9 ± 0.5 | 63.0 ± 0.3 | 62.2 ± 0.3 | 63.3 ± 0.4 | 62.5 ± 0.4 | 62.1 ± 0.3
Day 23 | 59.3 ± 0.3 | 58.9 ± 0.3 | 59.2 ± 0.3 | 59.5 ± 0.3 | 59.4 ± 0.3 | 59.1 ± 0.4
Week 13 | 55.0 ± 0.1 | 54.9 ± 0.1 | 55.2 ± 0.1 | 55.1 ± 0.2 | 55.3 ± 0.2 | 54.9 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.4 ± 0.1 | 18.5 ± 0.1 | 18.4 ± 0.1 | 18.4 ± 0.1
Day 23 | 18.9 ± 0.1 | 19.1 ± 0.1 | 18.8 ± 0.1 | 19.0 ± 0.1 | 18.9 ± 0.1 | 18.6 ± 0.1
Week 13 | 18.0 ± 0.1 | 18.0 ± 0.1 | 18.1 ± 0.1 | 18.0 ± 0.1 | 18.0 ± 0.1 | 18.0 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 29.6 ± 0.2 | 29.6 ± 0.1 | 29.6 ± 0.1 | 29.2 ± 0.2 | 29.4 ± 0.2 | 29.6 ± 0.2
Day 23 | 31.8 ± 0.2 | 32.4 ± 0.2 | 31.8 ± 0.2 | 32.0 ± 0.1 | 31.8 ± 0.2 | 31.5 ± 0.2
Week 13 | 32.7 ± 0.1 | 32.8 ± 0.1 | 32.7 ± 0.2 | 32.6 ± 0.2 | 32.5 ± 0.1 | 32.8 ± 0.1
Platelets (10^3^/μL)
Day 4 | 1,036.3 ± 45.2 | 1,041.6 ± 16.5 | 929.9 ± 48.5 | 1,044.3 ± 37.1 | 1,033.7 ± 34.2 | 1,040.4 ± 27.8
Day 23 | 789.5 ± 56.4 | 772.0 ± 26.7 | 722.9 ± 61.4 | 763.2 ± 56.5 | 817.7 ± 22.9 | 839.2 ± 46.9
Week 13 | 630.3 ± 34.5 | 594.4 ± 34.0 | 648.0 ± 19.5 | 665.6 ± 20.6 | 562.8 ± 33.7 | 606.6 ± 33.5
Leukocytes (10^3^/μL)
Day 4 | 10.51 ± 0.74 | 10.43 ± 0.29 | 10.05 ± 0.45 | 10.57 ± 0.37 | 10.75 ± 0.26 | 10.89 ± 0.54
Day 23 | 9.11 ± 0.58 | 9.15 ± 0.59 | 6.86 ± 0.37* | 8.64 ± 0.40 | 7.88 ± 0.69 | 7.65 ± 0.32
Week 13 | 7.14 ± 0.24 | 6.10 ± 0.44 | 6.86 ± 0.13 | 5.84 ± 0.37* | 6.20 ± 0.22 | 7.38 ± 0.36
Segmented neutrophils (10^3^/μL)
Day 4 | 0.96 ± 0.10 | 1.00 ± 0.06 | 0.92 ± 0.06 | 1.14 ± 0.08 | 1.00 ± 0.07 | 0.88 ± 0.03
Day 23 | 0.99 ± 0.14 | 1.05 ± 0.13 | 0.73 ± 0.06 | 0.91 ± 0.09 | 0.90 ± 0.10 | 0.95 ± 0.07
Week 13 | 1.41 ± 0.09 | 1.04 ± 0.11 | 1.38 ± 0.09 | 1.18 ± 0.11 | 1.24 ± 0.05 | 1.80 ± 0.13
Lymphocytes (10^3^/μL)
Day 4 | 9.20 ± 0.67 | 9.07 ± 0.27 | 8.82 ± 0.42 | 9.05 ± 0.32 | 9.36 ± 0.29 | 9.64 ± 0.52
Day 23 | 7.89 ± 0.46 | 7.84 ± 0.55 | 5.94 ± 0.32* | 7.50 ± 0.35 | 6.79 ± 0.60 | 6.49 ± 0.36
Week 13 | 5.38 ± 0.24 | 4.75 ± 0.36 | 5.15 ± 0.08 | 4.37 ± 0.26* | 4.67 ± 0.20 | 5.25 ± 0.27
Monocytes (10^3^/μL)
Day 4 | 0.23 ± 0.02 | 0.25 ± 0.01 | 0.21 ± 0.02 | 0.26 ± 0.02 | 0.26 ± 0.02 | 0.26 ± 0.01
Day 23 | 0.13 ± 0.01 | 0.12 ± 0.02 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.12 ± 0.01
Week 13 | 0.21 ± 0.01 | 0.19 ± 0.03 | 0.20 ± 0.02 | 0.17 ± 0.02 | 0.14 ± 0.01* | 0.19 ± 0.02
Basophils (10^3^/μL)
Day 4 | 0.062 ± 0.006 | 0.049 ± 0.003 | 0.053 ± 0.005 | 0.064 ± 0.006 | 0.054 ± 0.006 | 0.056 ± 0.005
Day 23 | 0.030 ± 0.004 | 0.034 ± 0.006 | 0.030 ± 0.005 | 0.037 ± 0.004 | 0.028 ± 0.004 | 0.021 ± 0.004
Week 13 | 0.025 ± 0.003 | 0.025 ± 0.006 | 0.026 ± 0.005 | 0.030 ± 0.006 | 0.022 ± 0.004 | 0.032 ± 0.004
Eosinophils (10^3^/μL)
Day 4 | 0.07 ± 0.02 | 0.07 ± 0.02 | 0.05 ± 0.01 | 0.07 ± 0.03 | 0.08 ± 0.03 | 0.07 ± 0.02
Day 23 | 0.07 ± 0.02 | 0.11 ± 0.03 | 0.06 ± 0.01 | 0.08 ± 0.02 | 0.06 ± 0.01 | 0.06 ± 0.02
Week 13 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01 | 0.12 ± 0.01 | 0.11 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 13.9 ± 0.5 | 12.5 ± 0.3 | 13.4 ± 0.7 | 13.1 ± 0.4 | 14.2 ± 0.4 | 15.0 ± 0.3
Day 23 | 17.8 ± 0.6 | 18.1 ± 0.4 | 15.6 ± 0.6 | 17.6 ± 0.4 | 17.9 ± 0.4 | 16.0 ± 0.3
Week 13 | 15.3 ± 0.5 | 15.0 ± 0.2 | 14.7 ± 0.4 | 15.4 ± 0.4 | 15.4 ± 0.5 | 15.4 ± 0.4
Creatinine (mg/dL)
Day 4 | 0.44 ± 0.02 | 0.44 ± 0.02 | 0.45 ± 0.02 | 0.42 ± 0.01 | 0.43 ± 0.02 | 0.43 ± 0.02
Day 23 | 0.51 ± 0.01 | 0.51 ± 0.01 | 0.52 ± 0.01 | 0.53 ± 0.02 | 0.51 ± 0.01 | 0.50 ± 0.00
Week 13 | 0.52 ± 0.01 | 0.51 ± 0.01 | 0.50 ± 0.00 | 0.50 ± 0.00 | 0.51 ± 0.01 | 0.51 ± 0.01
Glucose (mg/dL)
Week 13 | 141 ± 4 | 139 ± 3 | 148 ± 7 | 147 ± 5 | 143 ± 6 | 144 ± 5
Total protein (g/dL)
Day 4 | 6.0 ± 0.1 | 6.1 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.1 | 6.1 ± 0.1
Day 23 | 6.6 ± 0.1 | 6.7 ± 0.1 | 6.6 ± 0.1 | 6.8 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.1
Week 13 | 6.4 ± 0.1 | 6.8 ± 0.2 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.2 ± 0.1 | 6.0 ± 0.1*
Albumin (g/dL)
Day 4 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.1
Day 23 | 4.7 ± 0.1 | 4.8 ± 0.1 | 4.7 ± 0.0 | 4.8 ± 0.0 | 4.7 ± 0.0 | 4.7 ± 0.1
Week 13 | 4.5 ± 0.1 | 4.9 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.1 | 4.4 ± 0.0 | 4.4 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 41 ± 1 | 42 ± 2 | 43 ± 2 | 43 ± 2 | 40 ± 1 | 36 ± 3
Day 23 | 36 ± 2 | 37 ± 1 | 40 ± 1* | 39 ± 1 | 38 ± 1 | 38 ± 1
Week 13 | 59 ± 4 | 62 ± 4 | 49 ± 4 | 52 ± 4 | 50 ± 3 | 54 ± 2
Alkaline phosphatase (IU/L)
Day 4 | 520 ± 12 | 518 ± 10 | 517 ± 12 | 524 ± 10 | 510 ± 12 | 525 ± 10
Day 23 | 344 ± 8 | 341 ± 7 | 347 ± 6 | 353 ± 4 | 376 ± 8* | 391 ± 9**
Week 13 | 157 ± 7 | 136 ± 2 | 145 ± 5 | 149 ± 5 | 158 ± 4 | 166 ± 5
Creatine kinase (IU/L)
Day 4 | 408 ± 47 | 342 ± 31 | 379 ± 72 | 376 ± 57 | 368 ± 45 | 436 ± 52
Day 23 | 286 ± 63 | 279 ± 43 | 252 ± 38 | 218 ± 28 | 202 ± 22 | 298 ± 42
Week 13 | 149 ± 33 | 81 ± 10 | 137 ± 31 | 135 ± 39 | 164 ± 35 | 111 ± 21
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 15 ± 1 | 14 ± 1 | 15 ± 0 | 13 ± 1 | 13 ± 1
Day 23 | 13 ± 1 | 14 ± 0 | 13 ± 1 | 13 ± 0 | 13 ± 1 | 14 ± 1
Week 13 | 19 ± 2 | 16 ± 1 | 15 ± 1 | 16 ± 1 | 17 ± 1 | 15 ± 1
Bile salts (µmol/L)
Day 4 | 5.2 ± 0.7 | 6.2 ± 0.9 | 5.8 ± 0.8 | 6.4 ± 0.7 | 5.0 ± 0.5 | 5.3 ± 0.4
Day 23 | 5.8 ± 0.8 | 4.1 ± 0.4 | 5.1 ± 0.6 | 6.4 ± 1.2 | 4.9 ± 0.5 | 4.8 ± 0.5
Week 13 | 7.4 ± 1.3 | 7.7 ± 1.1 | 11.4 ± 1.0 | 9.1 ± 2.0 | 10.5 ± 3.1 | 7.9 ± 1.3

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Mean ± standard error. Statistical tests were performed on unrounded data.

Table F-2 Hematology Data for Mice in the Three-month Drinking Water Study of β-Picoline^a^

| 0 mg/L | 78 mg/L | 156 mg/L | 312 mg/L | 625 mg/L | 1,250 mg/L
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (auto) (%) | 47.8 ± 0.4 | 47.6 ± 0.5 | 47.4 ± 0.6 | 48.6 ± 0.7 | 46.3 ± 0.4 | 48.1 ± 0.5
Hemoglobin (g/dL) | 16.2 ± 0.2 | 16.2 ± 0.2 | 15.9 ± 0.2 | 16.5 ± 0.2 | 15.8 ± 0.2 | 16.4 ± 0.2
Erythrocytes (10^6^/µL) | 10.91 ± 0.08 | 10.83 ± 0.11 | 10.73 ± 0.15 | 11.04 ± 0.15 | 10.48 ± 0.11 | 10.95 ± 0.13
Reticulocytes (10^6^/µL) | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.00 | 0.27 ± 0.01 | 0.27 ± 0.00 | 0.27 ± 0.00
Mean cell volume (fL) | 43.8 ± 0.1 | 44.0 ± 0.2 | 44.2 ± 0.1 | 44.0 ± 0.2 | 44.2 ± 0.2 | 43.9 ± 0.2
Mean cell hemoglobin (pg) | 14.9 ± 0.0 | 15.0 ± 0.1 | 14.8 ± 0.1 | 15.0 ± 0.1 | 15.1 ± 0.1* | 14.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.9 ± 0.1 | 34.1 ± 0.2 | 33.6 ± 0.2 | 34.0 ± 0.2 | 34.1 ± 0.2 | 34.0 ± 0.1
Platelets (10^3^/µL) | 816.3 ± 55.5 | 843.1 ± 46.0 | 922.0 ± 41.2 | 772.8 ± 44.4 | 916.3 ± 43.4 | 764.9 ± 31.8
Leukocytes (10^3^/µL) | 5.20 ± 0.32 | 4.82 ± 0.40 | 5.83 ± 0.16 | 5.09 ± 0.49 | 4.61 ± 0.42 | 5.15 ± 0.53
Segmented neutrophils (10^3^/µL) | 0.87 ± 0.09 | 0.67 ± 0.08 | 0.79 ± 0.10 | 0.73 ± 0.11 | 0.81 ± 0.05 | 0.66 ± 0.07
Lymphocytes (10^3^/µL) | 4.04 ± 0.27 | 3.86 ± 0.32 | 4.68 ± 0.14 | 4.03 ± 0.41 | 3.54 ± 0.37 | 4.20 ± 0.47
Monocytes (10^3^/µL) | 0.19 ± 0.02 | 0.21 ± 0.05 | 0.28 ± 0.04 | 0.20 ± 0.02 | 0.18 ± 0.05 | 0.22 ± 0.04
Basophils (10^3^/µL) | 0.002 ± 0.001 | 0.014 ± 0.007 | 0.002 ± 0.001 | 0.004 ± 0.004 | 0.000 ± 0.000 | 0.000 ± 0.000
Eosinophils (10^3^/µL) | 0.11 ± 0.03 | 0.07 ± 0.02 | 0.08 ± 0.02 | 0.13 ± 0.03 | 0.08 ± 0.02 | 0.07 ± 0.02
Female
n | 10 | 9 | 10 | 10 | 10 | 10
Hematocrit (auto) (%) | 48.3 ± 0.6 | 46.4 ± 0.4 | 45.9 ± 0.6* | 46.8 ± 0.4 | 47.7 ± 0.7 | 45.8 ± 0.3**
Hemoglobin (g/dL) | 16.5 ± 0.2 | 16.0 ± 0.2 | 15.7 ± 0.2* | 16.1 ± 0.1 | 16.4 ± 0.2 | 15.8 ± 0.1*
Erythrocytes (10^6^/µL) | 10.93 ± 0.14 | 10.46 ± 0.08 | 10.35 ± 0.14* | 10.56 ± 0.08 | 10.79 ± 0.15 | 10.37 ± 0.07*
Reticulocytes (10^6^/µL) | 0.30 ± 0.02 | 0.34 ± 0.04 | 0.29 ± 0.02 | 0.29 ± 0.02 | 0.28 ± 0.01 | 0.27 ± 0.02
Mean cell volume (fL) | 44.2 ± 0.2 | 44.4 ± 0.2 | 44.3 ± 0.2 | 44.3 ± 0.1 | 44.2 ± 0.2 | 44.2 ± 0.2
Mean cell hemoglobin (pg) | 15.1 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.0 | 15.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 34.3 ± 0.1 | 34.5 ± 0.1 | 34.3 ± 0.1 | 34.4 ± 0.2 | 34.4 ± 0.1 | 34.4 ± 0.2
Platelets (10^3^/µL) | 668.5 ± 66.7 | 723.6 ± 51.3 | 842.7 ± 73.4 | 722.8 ± 41.1 | 701.9 ± 48.4 | 802.3 ± 67.4
Leukocytes (10^3^/µL) | 5.29 ± 0.38 | 4.11 ± 0.35 | 4.71 ± 0.26 | 5.13 ± 0.31 | 4.82 ± 0.23 | 5.37 ± 0.27
Segmented neutrophils (10^3^/µL) | 0.66 ± 0.06 | 0.54 ± 0.06 | 0.63 ± 0.09 | 0.86 ± 0.11 | 0.76 ± 0.09 | 0.67 ± 0.10
Lymphocytes (10^3^/µL) | 4.29 ± 0.34 | 3.25 ± 0.35 | 3.73 ± 0.25 | 3.93 ± 0.25 | 3.71 ± 0.18 | 4.29 ± 0.20
Monocytes (10^3^/µL) | 0.25 ± 0.04 | 0.21 ± 0.06 | 0.23 ± 0.06 | 0.18 ± 0.04 | 0.19 ± 0.05 | 0.26 ± 0.06
Basophils (10^3^/µL) | 0.007 ± 0.005 | 0.003 ± 0.002 | 0.004 ± 0.002 | 0.005 ± 0.002 | 0.007 ± 0.005 | 0.008 ± 0.005
Eosinophils (10^3^/µL) | 0.08 ± 0.02 | 0.10 ± 0.03 | 0.13 ± 0.02 | 0.15 ± 0.02 | 0.15 ± 0.02 | 0.14 ± 0.03

* Significantly different (P ≤ 0.05) from the control group by Dunn’s test.

** P ≤ 0.01.

^a^ Mean ± standard error. Statistical tests were performed on unrounded data.