# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Testing procedures used in the first two studies, conducted at EG&G Mason Research Institute (Rockville, MD) and BioReliance Corporation (Rockville, MD), followed the protocol reported by Zeiger et al.^61^; in the tests conducted at SITEK Research Laboratories (Rockville, MD), using the same chemical lot 11108CI that was tested in the 3-month and 2-year drinking water studies, a slightly modified procedure was used, and that is described in more detail below. β-Picoline was tested as a coded sample. In the first two studies, β-picoline was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, TA1535, and TA1537 either in buffer or in 10% or 30% S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

The protocol used at SITEK Research Laboratories used only 10% rat liver S9 for exogenous metabolic activation, and employed Escherichia coli strain WP2 uvrA/pKM101 as a bacterial tester strain in addition to S. typhimurium strains TA98 and TA100. Incubation of bacterial strains with β-picoline and subsequent plating were carried out as described above.

In all studies, each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of β-picoline; the highest concentration tested was limited by toxicity. All trials were repeated at the same or a higher S9 concentration.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold-increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^62^ At the end of the 3-month drinking water study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were shipped to the genetic toxicity testing laboratory where they were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) among the total erythrocyte population in the peripheral blood was scored for each exposure group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Results of the 3-month study were accepted without repeat tests, because additional test data could not be obtained. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

β-Picoline was tested in three independent bacterial gene mutation studies, and negative results were obtained in all studies (Table E-1 and Table E-2). In the first study (with concentrations ranging from 85.4 to 8,540 μg/plate), no increases in the numbers of mutant colonies were seen in S. typhimurium strains TA98, TA100, TA1535, and TA1537 with and without 10% S9 derived from induced hamster or rat liver. In the second study, negative results were obtained over a concentration range of 100 to 10,000 μg/plate in S. typhimurium strains TA97, TA98, TA100, and TA1535 with and without 10% or 30% S9 derived from induced hamster or rat liver. In the third study, which tested the same chemical lot that was used in the 3-month and 2-year studies, negative results were obtained over a concentration range of 1,000 to 10,000 μg/plate in S. typhimurium strains TA98 and TA100 and 100 to 5,000 μg/plate in E. coli WP2 uvrA/pKM101, with and without 10% rat liver S9.

In vivo, no significant increases in the frequencies of micronucleated NCEs, an indicator of chromosomal damage, were observed in peripheral blood of male or female B6C3F1/N mice exposed to 78 to 1,250 mg β-picoline/L in drinking water for 3 months (Table E-3). No significant alterations in the percentage of circulating PCEs (reticulocytes) were observed, suggesting that β-picoline did not induce bone marrow toxicity over the exposure concentration range tested.

Table E-1 Mutagenicity of β-Picoline in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
Study performed at EG&G Mason Research Institute
TA100
| 0 | 118 ± 1 | 122 ± 11 | 106 ± 13 | 131 ± 6 | 121 ± 9 | 133 ± 2
| 85.4 | 111 ± 6 | 132 ± 6 | 118 ± 6 | 144 ± 3 | 128 ± 5 | 156 ± 4
| 284.7 | 107 ± 14 | 115 ± 6 | 112 ± 5 | 132 ± 7 | 120 ± 7 | 123 ± 5
| 854 | 111 ± 12 | 115 ± 13 | 113 ± 7 | 146 ± 11 | 140 ± 4 | 119 ± 10
| 2,846 | 127 ± 11 | 113 ± 7 | 108 ± 17 | 133 ± 6 | 121 ± 2 | 117 ± 5
| 8,540 | Toxic | Toxic | Toxic | 65 ± 5^b^ | 71 ± 8^b^ | 72 ± 19^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control^c^ | | 2,008 ± 50 | 1,578 ± 69 | 2,101 ± 19 | 2,930 ± 69 | 1,959 ± 21 | 2,561 ± 99
TA98
| 0 | 18 ± 3 | 17 ± 1 | 19 ± 4 | 20 ± 5 | 23 ± 1 | 25 ± 3
| 85.4 | 14 ± 1 | 15 ± 2 | 19 ± 4 | 23 ± 3 | 19 ± 2 | 19 ± 3
| 284.7 | 14 ± 2 | 17 ± 2 | 24 ± 4 | 23 ± 3 | 14 ± 1 | 23 ± 5
| 854 | 16 ± 1 | 16 ± 2 | 22 ± 3 | 21 ± 1 | 20 ± 5 | 15 ± 2
| 2,846 | 13 ± 2 | 14 ± 2 | 26 ± 2 | 20 ± 2 | 19 ± 2 | 22 ± 4
| 8,540 | Toxic | Toxic | 9 ± 2^b^ | 13 ± 1^b^ | 10 ± 1^b^ | 15 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 1,931 ± 5 | 1,191 ± 14 | 2,110 ± 100 | 2,862 ± 38 | 1,686 ± 68 | 2,029 ± 62
TA1535
| 0 | 24 ± 2 | 15 ± 0 | 4 ± 1 | 10 ± 2 | 10 ± 2 | 9 ± 3
| 85.4 | 19 ± 1 | 11 ± 1 | 8 ± 1 | 9 ± 2 | 8 ± 2 | 10 ± 2
| 284.7 | 21 ± 1 | 15 ± 1 | 10 ± 4 | 8 ± 2 | 8 ± 3 | 10 ± 1
| 854 | 22 ± 2 | 12 ± 1 | 8 ± 1 | 6 ± 1 | 7 ± 2 | 11 ± 1
| 2,846 | 19 ± 3 | 16 ± 2 | 10 ± 1 | 7 ± 1 | 8 ± 1 | 10 ± 1
| 8,540 | Toxic | 10 ± 2^b^ | Toxic | 7 ± 0^b^ | 6 ± 2^b^ | 4 ± 1^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 1,507 ± 41 | 1,188 ± 34 | 119 ± 11 | 144 ± 11 | 100 ± 14 | 138 ± 7
TA1537
| 0 | 4 ± 2 | | 6 ± 1 | 6 ± 1 | 3 ± 0 | 7 ± 1
| 85.4 | 8 ± 2 | | 7 ± 1 | 7 ± 2 | 4 ± 2 | 8 ± 1
| 284.7 | 6 ± 2 | | 5 ± 1 | 8 ± 2 | 3 ± 2 | 6 ± 1
| 854 | 7 ± 2 | | 5 ± 1 | 7 ± 2 | 4 ± 2 | 6 ± 1
| 2,846 | 6 ± 1 | | 7 ± 1 | 7 ± 1 | 6 ± 1 | 9 ± 1
| 8,540 | 3 ± 1^b^ | | 5 ± 1 | 7 ± 1^b^ | 9 ± 8^b^ | 4 ± 1^b^
Trial summary | | Negative | | Negative | Negative | Negative | Negative
Positive control | | 410 ± 28 | | 344 ± 25 | 233 ± 15 | 166 ± 10 | 193 ± 5
Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
Study performed at BioReliance Corporation
TA100
| 0 | 127 ± 6 | 101 ± 9 | 187 ± 16 | 104 ± 6 | 155 ± 9 | 140 ± 18
| 100 | 134 ± 12 | 119 ± 8 | 156 ± 11 | 128 ± 9 | 167 ± 17 | 137 ± 5
| 333 | 131 ± 12 | 91 ± 3 | 149 ± 7 | 110 ± 16 | 159 ± 6 | 132 ± 27
| 1,000 | 125 ± 4 | 120 ± 7 | 160 ± 15 | 115 ± 9 | 141 ± 6 | 129 ± 6
| 3,333 | 123 ± 5 | 10 ± 4^b^ | 145 ± 6 | 98 ± 4 | 149 ± 9 | 133 ± 5
| 10,000 | 107 ± 12 | 8 ± 4^b^ | Toxic | 93 ± 4 | Toxic | 4 ± 4^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 361 ± 14 | 338 ± 21 | 432 ± 11 | 664 ± 117 | 532 ± 72 | 332 ± 25
TA97
| 0 | 81 ± 1 | 212 ± 4^d^ | 228 ± 6 | 99 ± 9 | 232 ± 6 | 128 ± 13
| 100 | 94 ± 6 | 175 ± 11 | 248 ± 7 | 139 ± 14 | 188 ± 12 | 150 ± 14
| 333 | 92 ± 6 | 224 ± 22 | 206 ± 27 | 112 ± 8 | 216 ± 9 | 133 ± 12
| 1,000 | 91 ± 14 | 197 ± 4 | 234 ± 2 | 116 ± 6 | 203 ± 14 | 123 ± 8
| 3,333 | 85 ± 13 | 160 ± 4 | 140 ± 10 | 100 ± 9 | 186 ± 18 | 122 ± 7
| 10,000 | 25 ± 15^b^ | Toxic | 89 ± 43^b^ | 74 ± 12^b^ | 114 ± 7^b^ | 79 ± 10^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 329 ± 7 | 665 ± 23 | 1,381 ± 74 | 415 ± 54 | 806 ± 88 | 314 ± 5
| | Without S9 | Without S9 | Without S9
TA98
| 0 | 12 ± 4 | 18 ± 2 | 11 ± 2
| 100 | 11 ± 2 | 23 ± 1
| 333 | 13 ± 2 | 16 ± 1 | 14 ± 3
| 1,000 | 10 ± 0 | 19 ± 3 | 11 ± 1
| 3,333 | 10 ± 1 | 18 ± 2 | 10 ± 3
| 6,667 | | | 12 ± 1
| 10,000 | 4 ± 4^b^ | Toxic | 11 ± 3
Trial summary | | Negative | Negative | Negative
Positive control | | 162 ± 16 | 200 ± 7 | 195 ± 16
| | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
TA98
(continued) | 0 | 23 ± 2 | 26 ± 5 | 25 ± 3 | 23 ± 4
| 100 | 22 ± 3 | 27 ± 5 | 21 ± 3 | 24 ± 3
| 333 | 27 ± 4 | 28 ± 2 | 20 ± 2 | 25 ± 5
| 1,000 | 27 ± 1 | 28 ± 4 | 17 ± 2 | 20 ± 0
| 3,333 | 27 ± 8 | 33 ± 4 | 24 ± 0 | 18 ± 3
| 10,000 | 19 ± 8^b^ | 19 ± 2^b^ | Toxic | 0 ± 0^b^
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 325 ± 32 | 300 ± 71 | 253 ± 70 | 243 ± 32
Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 30% Hamster S9 | With 10% Rat S9 | With 30% Rat S9
Study performed at BioReliance Corporation (cont’d)
TA1535
| 0 | 14 ± 0 | 18 ± 1 | 13 ± 2 | 15 ± 0 | 10 ± 2 | 12 ± 1
| 100 | 12 ± 3 | 18 ± 1 | 13 ± 2 | 10 ± 1 | 14 ± 2 | 13 ± 3
| 333 | 15 ± 3 | 18 ± 4 | 15 ± 1 | 9 ± 2 | 16 ± 3 | 11 ± 1
| 1,000 | 12 ± 1 | 18 ± 1 | 13 ± 4 | 10 ± 2 | 17 ± 3 | 12 ± 4
| 3,333 | 11 ± 2 | 14 ± 2 | 11 ± 1 | 10 ± 1 | 12 ± 3 | 14 ± 1
| 10,000 | 10 ± 2^b^ | 17 ± 3^b^ | 11 ± 3^b^ | 5 ± 4^b^ | 9 ± 2^b^ | 5 ± 3^b^
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 134 ± 30 | 401 ± 55 | 53 ± 5 | 109 ± 8 | 125 ± 14 | 34 ± 5

^a^ Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^61^ 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97 and TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^d^ Contamination.

Table E-2 Mutagenicity of β-Picoline in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 84 ± 4 | 76 ± 4 | 92 ± 8 | 89 ± 3
| 1,000 | 82 ± 2 | 76 ± 3 | 99 ± 3 | 79 ± 4
| 2,500 | 84 ± 5 | 74 ± 4 | 91 ± 8 | 84 ± 0
| 5,000 | 75 ± 4 | 71 ± 6 | 83 ± 5 | 74 ± 3
| 7,500 | 72 ± 5 | 63 ± 7 | 69 ± 5 | 68 ± 2
| 10,000 | 68 ± 2 | 64 ± 6 | 62 ± 1 | 68 ± 4
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 416 ± 24 | 380 ± 37 | 1,141 ± 31 | 899 ± 29
TA98
| 0 | 17 ± 4 | 18 ± 1 | 37 ± 1 | 30 ± 2
| 1,000 | 21 ± 2 | 18 ± 2 | 28 ± 1 | 30 ± 3
| 2,500 | 21 ± 2 | 14 ± 0 | 27 ± 1 | 30 ± 6
| 5,000 | 19 ± 0 | 13 ± 2 | 29 ± 4 | 21 ± 2
| 7,500 | 17 ± 2 | 12 ± 0 | 22 ± 3 | 18 ± 3
| 10,000 | 14 ± 2 | 10 ± 1 | 15 ± 1 | 12 ± 2
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 604 ± 46 | 512 ± 24 | 1,164 ± 37 | 1,258 ± 28
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 272 ± 12 | 211 ± 3 | 312 ± 18 | 236 ± 1
| 100 | 291 ± 21 | 270 ± 19 | 345 ± 13 | 291 ± 3
| 500 | 310 ± 23 | 297 ± 11 | 342 ± 7 | 269 ± 21
| 1,500 | 275 ± 16 | 201 ± 20 | 254 ± 1 | 218 ± 11
| 3,000 | 73 ± 8 | 65 ± 7 | 20 ± 1 | 32 ± 1
| 5,000 | 53 ± 1 | 50 ± 3 | 7 ± 0 | 10 ± 0
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,880 ± 61 | 1,711 ± 62 | 1,064 ± 33 | 1,010 ± 31

^a^ Study was performed at SITEK Research Laboratories using lot no. 11108CI (same lot used in 3-month and 2-year studies). Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of β-Picoline in Drinking Water for Three Months^a^

| Exposure Concentration (mg/L) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 5 | 2.50 ± 0.52 | | 3.82 ± 0.25
β-Picoline | 78 | 5 | 2.20 ± 0.73 | 0.6693 | 3.92 ± 0.27
| 156 | 5 | 2.10 ± 0.37 | 0.7226 | 3.78 ± 0.34
| 312 | 5 | 2.60 ± 0.33 | 0.4442 | 3.50 ± 0.18
| 625 | 5 | 2.90 ± 0.78 | 0.2929 | 3.48 ± 0.25
| 1,250 | 5 | 2.60 ± 0.58 | 0.4442 | 3.66 ± 0.19
| | | P = 0.245^e^
Female
Water | 0 | 5 | 2.60 ± 0.37 | | 3.98 ± 0.55
β-Picoline | 78 | 5 | 1.90 ± 0.58 | 0.8519 | 4.04 ± 0.34
| 156 | 5 | 2.00 ± 0.22 | 0.8121 | 3.30 ± 0.26
| 312 | 5 | 1.30 ± 0.44 | 0.9814 | 3.62 ± 0.30
| 625 | 5 | 2.10 ± 0.40 | 0.7674 | 3.76 ± 0.21
| 1,250 | 5 | 2.60 ± 0.24 | 0.5000 | 3.68 ± 0.61
| | | P = 0.211

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^62^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.005.

^d^ Control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.