# Appendix D Summary of Lesions in Female Mice in the Two-year Drinking Water Study of β-Picoline

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 4 | 3 | 1 | 4
Natural deaths | 8 | 15 | 14 | 13
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 38 | 32 | 34 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Gallbladder | (43) | (36) | (36) | (35)
Hepatoblastoma, metastatic, liver | – | 1 (3%) | – | –
Intestine large, cecum | (44) | (36) | (38) | (39)
Carcinoma | – | – | 1 (3%) | –
Intestine large, colon | (44) | (35) | (40) | (38)
Intestine large, rectum | (43) | (35) | (37) | (38)
Intestine small, duodenum | (42) | (35) | (36) | (37)
Intestine small, ileum | (44) | (36) | (37) | (37)
Intestine small, jejunum | (43) | (35) | (37) | (38)
Carcinoma | – | – | – | 2 (5%)
Liver | (49) | (50) | (50) | (50)
Hemangiosarcoma | 2 (4%) | 5 (10%) | 3 (6%) | 2 (4%)
Hepatoblastoma | 1 (2%) | 3 (6%) | 3 (6%) | 3 (6%)
Hepatoblastoma, multiple | – | – | 1 (2%) | 1 (2%)
Hepatocellular adenoma | 11 (22%) | 3 (6%) | 10 (20%) | 9 (18%)
Hepatocellular adenoma, multiple | 27 (55%) | 43 (86%) | 36 (72%) | 30 (60%)
Hepatocellular carcinoma | 6 (12%) | 13 (26%) | 16 (32%) | 18 (36%)
Hepatocellular carcinoma, multiple | 5 (10%) | 7 (14%) | 10 (20%) | 5 (10%)
Mast cell tumor malignant | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Rhabdomyosarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Mesentery | (8) | (16) | (16) | (9)
Lipoma | – | – | 1 (6%) | –
Rhabdomyosarcoma, metastatic, uncertain primary site | – | – | 1 (6%) | –
Sarcoma | – | – | – | 1 (11%)
Pancreas | (48) | (42) | (46) | (45)
Rhabdomyosarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Salivary glands | (50) | (47) | (47) | (50)
Stomach, forestomach | (47) | (43) | (45) | (47)
Squamous cell carcinoma | – | 1 (2%) | – | –
Squamous cell papilloma | – | 1 (2%) | 1 (2%) | 1 (2%)
Stomach, glandular | (45) | (39) | (41) | (41)
Tongue | (0) | (0) | (0) | (1)
Squamous cell carcinoma | – | – | – | 1 (100%)
Tooth | (0) | (1) | (2) | (9)
Gingiva, fibroma, osseous | – | 1 (100%) | – | –
Cardiovascular System
Blood vessel | (2) | (3) | (1) | (0)
Heart | (50) | (50) | (49) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Pericardium, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (49) | (45) | (46) | (50)
Adenoma | – | – | – | 1 (2%)
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Adrenal medulla | (49) | (45) | (46) | (50)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | – | –
Pheochromocytoma complex | – | – | 1 (2%) | –
Pheochromocytoma malignant | – | 2 (4%) | – | –
Islets, pancreatic | (48) | (41) | (45) | (45)
Adenoma | – | 1 (2%) | – | 1 (2%)
Parathyroid gland | (38) | (34) | (40) | (41)
Pituitary gland | (50) | (46) | (47) | (46)
Pars distalis, adenoma | 4 (8%) | 5 (11%) | 2 (4%) | 3 (7%)
Thyroid gland | (48) | (45) | (45) | (49)
Follicular cell, adenoma | – | – | – | 1 (2%)
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (48) | (50)
Ovary | (49) | (48) | (48) | (47)
Cystadenoma | 3 (6%) | 4 (8%) | – | 6 (13%)
Hemangioma | – | – | – | 1 (2%)
Uterus | (49) | (47) | (49) | (49)
Hemangiosarcoma | – | – | – | 1 (2%)
Polyp stromal | 2 (4%) | – | – | –
Cervix, sarcoma | – | – | 1 (2%) | –
Endometrium, adenoma | 1 (2%) | – | – | –
Hematopoietic System
Bone marrow | (49) | (46) | (48) | (49)
Hemangiosarcoma | 1 (2%) | – | – | –
Mast cell tumor malignant | – | 1 (2%) | – | –
Lymph node | (6) | (8) | (6) | (8)
Bronchial, alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (13%)
Iliac, mast cell tumor malignant | – | 1 (13%) | – | –
Iliac, sarcoma, metastatic, mesentery | – | – | – | 1 (13%)
Lumbar, hemangiosarcoma | – | 1 (13%) | – | –
Mediastinal, sarcoma, metastatic, mesentery | – | – | – | 1 (13%)
Renal, hemangiosarcoma | – | 1 (13%) | – | –
Lymph node, mandibular | (48) | (42) | (47) | (47)
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Lymph node, mesenteric | (46) | (38) | (45) | (46)
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Spleen | (46) | (42) | (45) | (46)
Fibrosarcoma | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | 2 (5%) | – | –
Mast cell tumor malignant | – | 1 (2%) | – | –
Thymus | (45) | (44) | (48) | (47)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | 1 (2%) | – | 2 (4%)
Hemangiosarcoma | – | – | 1 (2%) | –
Rhabdomyosarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (49) | (48)
Carcinoma | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Mast cell tumor benign | 1 (2%) | – | – | –
Subcutaneous tissue, fibrous histiocytoma | – | 1 (2%) | – | –
Subcutaneous tissue, hemangiosarcoma | 2 (4%) | 1 (2%) | – | –
Subcutaneous tissue, rhabdomyosarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Subcutaneous tissue, sarcoma | 2 (4%) | 2 (4%) | 4 (8%) | 4 (8%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | 2 (4%) | – | – | –
Osteosarcoma, multiple | – | – | – | 1 (2%)
Skeletal muscle | (1) | (0) | (0) | (1)
Sarcoma, metastatic, mesentery | – | – | – | 1 (100%)
Nervous System
Brain | (50) | (47) | (47) | (50)
Peripheral nerve | (1) | (0) | (0) | (1)
Spinal cord | (1) | (0) | (0) | (1)
Respiratory System
Lung | (50) | (50) | (49) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 5 (10%) | 4 (8%) | 10 (20%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | 1 (2%)
Alveolar/bronchiolar carcinoma | 7 (14%) | 6 (12%) | 8 (16%) | 9 (18%)
Alveolar/bronchiolar carcinoma, multiple | – | 2 (4%) | 2 (4%) | 4 (8%)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | 3 (6%) | –
Hepatoblastoma, metastatic, liver | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 5 (10%) | 8 (16%) | 4 (8%)
Mast cell tumor malignant | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Sarcoma, metastatic, mesentery | – | – | – | 1 (2%)
Sarcoma, metastatic, skin | 1 (2%) | – | 1 (2%) | –
Nose | (49) | (44) | (49) | (47)
Pleura | (0) | (0) | (0) | (1)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (100%)
Trachea | (47) | (41) | (45) | (44)
Special Senses System
Eye | (43) | (35) | (36) | (39)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Harderian gland | (45) | (41) | (43) | (47)
Adenoma | 2 (4%) | – | 2 (5%) | 2 (4%)
Carcinoma | 2 (4%) | 1 (2%) | 4 (9%) | 4 (9%)
Bilateral, carcinoma | – | 1 (2%) | – | –
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (49) | (47) | (48) | (49)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Mast cell tumor malignant | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | – | 1 (2%)
Renal tubule, adenoma | – | – | – | 1 (2%)
Urinary bladder | (44) | (37) | (39) | (41)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Lymphoma malignant | 14 (28%) | 15 (30%) | 10 (20%) | 13 (26%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 43 | 49 | 50 | 47
Total primary neoplasms | 103 | 136 | 122 | 139
Total animals with benign neoplasms | 40 | 48 | 47 | 44
Total benign neoplasms | 57 | 65 | 56 | 67
Total animals with malignant neoplasms | 29 | 42 | 41 | 41
Total malignant neoplasms | 46 | 71 | 66 | 72
Total animals with metastatic neoplasms | 3 | 7 | 12 | 7
Total metastatic neoplasms | 4 | 7 | 17 | 23
Total animals with malignant neoplasms of uncertainprimary site | – | – | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate^a^ | 1/49 (2%) | 3/45 (7%) | 1/46 (2%) | 0/50 (0%)
Adjusted rate^b^ | 2.2% | 7.2% | 2.3% | 0.0%
Terminal rate^c^ | 1/38 (3%) | 2/32 (6%) | 0/35 (0%) | 0/33 (0%)
First incidence (days) | 729 (T) | 553 | 704 | –^e^
Poly-3 test^d^ | P = 0.209N | P = 0.274 | P = 0.745 | P = 0.508N
Harderian Gland: Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 4.3% | 4.5% | 8.8% | 9.0%
Terminal rate | 1/38 (3%) | 2/32 (6%) | 4/35 (11%) | 3/33 (9%)
First incidence (days) | 668 | 729 (T) | 729 (T) | 533
Poly-3 test | P = 0.201 | P = 0.680 | P = 0.329 | P = 0.322
Harderian Gland: Adenoma or Carcinoma
Overall rate | 4/50 (8%) | 2/50 (4%) | 6/50 (12%) | 6/50 (12%)
Adjusted rate | 8.7% | 4.5% | 13.1% | 13.3%
Terminal rate | 3/38 (8%) | 2/32 (6%) | 4/35 (11%) | 4/33 (12%)
First incidence (days) | 668 | 729 (T) | 647 | 533
Poly-3 test | P = 0.174 | P = 0.356N | P = 0.364 | P = 0.354
Liver: Hemangiosarcoma
Overall rate | 2/49 (4%) | 5/50 (10%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 4.4% | 11.3% | 6.6% | 4.5%
Terminal rate | 2/38 (5%) | 4/32 (13%) | 3/35 (9%) | 1/33 (3%)
First incidence (days) | 729 (T) | 724 | 729 (T) | 648
Poly-3 test | P = 0.441N | P = 0.203 | P = 0.496 | P = 0.682
Liver: Hepatocellular Adenoma
Overall rate | 38/49 (78%) | 46/50 (92%) | 46/50 (92%) | 39/50 (78%)
Adjusted rate | 80.4% | 94.9% | 93.1% | 81.5%
Terminal rate | 31/38 (82%) | 31/32 (97%) | 35/35 (100%) | 26/33 (79%)
First incidence (days) | 598 | 494 | 309 | 509
Poly-3 test | P = 0.403N | P = 0.025 | P = 0.052 | P = 0.551
Liver: Hepatocellular Carcinoma
Overall rate | 11/49 (22%) | 20/50 (40%) | 26/50 (52%) | 23/50 (46%)
Adjusted rate | 23.6% | 43.9% | 55.3% | 50.9%
Terminal rate | 7/38 (18%) | 14/32 (44%) | 21/35 (60%) | 18/33 (55%)
First incidence (days) | 639 | 533 | 549 | 586
Poly-3 test | P = 0.006 | P = 0.031 | P < 0.001 | P = 0.005
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 40/49 (82%) | 47/50 (94%) | 47/50 (94%) | 42/50 (84%)
Adjusted rate | 84% | 96.9% | 95% | 86.2%
Terminal rate | 32/38 (84%) | 31/32 (97%) | 35/35 (100%) | 27/33 (82%)
First incidence (days) | 598 | 494 | 309 | 509
Poly-3 test | P = 0.496N | P = 0.027 | P = 0.066 | P = 0.492
Liver: Hepatoblastoma
Overall rate | 1/49 (2%) | 3/50 (6%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 2.2% | 6.7% | 8.8% | 9.1%
Terminal rate | 0/38 (0%) | 1/32 (3%) | 4/35 (11%) | 3/33 (9%)
First incidence (days) | 674 | 662 | 729 (T) | 721
Poly-3 test | P = 0.140 | P = 0.295 | P = 0.174 | P = 0.166
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 12/49 (24%) | 21/50 (42%) | 28/50 (56%) | 24/50 (48%)
Adjusted rate | 25.7% | 45.8% | 59.5% | 53.1%
Terminal rate | 7/38 (18%) | 14/32 (44%) | 23/35 (66%) | 19/33 (58%)
First incidence (days) | 639 | 533 | 549 | 586
Poly-3 test | P = 0.005 | P = 0.033 | P < 0.001 | P = 0.005
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 40/49 (82%) | 47/50 (94%) | 47/50 (94%) | 42/50 (84%)
Adjusted rate | 84% | 96.9% | 95.0% | 86.2%
Terminal rate | 32/38 (84%) | 31/32 (97%) | 35/35 (100%) | 27/33 (82%)
First incidence (days) | 598 | 494 | 309 | 509
Poly-3 test | P = 0.496N | P = 0.027 | P = 0.066 | P = 0.492
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 6/50 (12%) | 4/49 (8%) | 11/50 (22%)
Adjusted rate | 10.9% | 13.5% | 8.9% | 24.5%
Terminal rate | 5/38 (13%) | 5/32 (16%) | 3/35 (9%) | 8/33 (24%)
First incidence (days) | 729 (T) | 700 | 669 | 533
Poly-3 test | P = 0.046 | P = 0.477 | P = 0.511N | P = 0.075
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 7/50 (14%) | 8/50 (16%) | 10/49 (20%) | 13/50 (26%)
Adjusted rate | 15.2% | 17.9% | 21.6% | 28.5%
Terminal rate | 6/38 (16%) | 6/32 (19%) | 7/35 (20%) | 8/33 (24%)
First incidence (days) | 669 | 700 | 522 | 509
Poly-3 test | P = 0.061 | P = 0.471 | P = 0.297 | P = 0.096
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 11/50 (22%) | 13/50 (26%) | 13/49 (27%) | 21/50 (42%)
Adjusted rate | 23.8% | 29.1% | 28.1% | 45.4%
Terminal rate | 10/38 (26%) | 11/32 (34%) | 10/35 (29%) | 14/33 (42%)
First incidence (days) | 669 | 700 | 522 | 509
Poly-3 test | P = 0.015 | P = 0.368 | P = 0.407 | P = 0.022
Ovary: Cystadenoma
Overall rate | 3/49 (6%) | 4/48 (8%) | 0/48 (0%) | 6/47 (13%)
Adjusted rate | 6.5% | 9.1% | 0.0% | 14.3%
Terminal rate | 3/38 (8%) | 3/32 (9%) | 0/35 (0%) | 6/33 (18%)
First incidence (days) | 729 (T) | 724 | – | 729 (T)
Poly-3 test | P = 0.177 | P = 0.477 | P = 0.125N | P = 0.201
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 4/50 (8%) | 5/46 (11%) | 2/47 (4%) | 3/46 (7%)
Adjusted rate | 8.7% | 11.9% | 4.6% | 7.4%
Terminal rate | 4/38 (11%) | 4/31 (13%) | 1/35 (3%) | 3/30 (10%)
First incidence (days) | 729 (T) | 494 | 712 | 729 (T)
Poly-3 test | P = 0.373N | P = 0.443 | P = 0.364N | P = 0.570N
Skin: Sarcoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 4.3% | 4.5% | 8.7% | 9.0%
Terminal rate | 0/38 (0%) | 1/32 (3%) | 1/35 (3%) | 2/33 (6%)
First incidence (days) | 698 | 700 | 620 | 612
Poly-3 test | P = 0.200 | P = 0.681 | P = 0.337 | P = 0.321
Skin (Subcutaneous Tissue): Fibrous Histiocytoma or Sarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 4.3% | 6.7% | 8.7% | 9%
Terminal rate | 0/38 (0%) | 2/32 (6%) | 1/35 (3%) | 2/33 (6%)
First incidence (days) | 698 | 700 | 620 | 612
Poly-3 test | P = 0.251 | P = 0.484 | P = 0.337 | P = 0.321
Spleen: Hemangiosarcoma
Overall rate | 1/46 (2%) | 2/42 (5%) | 0/45 (0%) | 0/46 (0%)
Adjusted rate | 2.3% | 5.0% | 0.0% | 0.0%
Terminal rate | 1/38 (3%) | 1/32 (3%) | 0/35 (0%) | 0/33 (0%)
First incidence (days) | 729 (T) | 588 | – | –
Poly-3 test | P = 0.194N | P = 0.463 | P = 0.511N | P = 0.512N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 6.5% | 13.4% | 8.8% | 9.0%
Terminal rate | 3/38 (8%) | 4/32 (13%) | 4/35 (11%) | 2/33 (6%)
First incidence (days) | 729 (T) | 588 | 729 (T) | 641
Poly-3 test | P = 0.533 | P = 0.230 | P = 0.493 | P = 0.485
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 4/50 (8%) | 5/50 (10%)
Adjusted rate | 6.5% | 13.4% | 8.8% | 11.1%
Terminal rate | 3/38 (8%) | 4/32 (13%) | 4/35 (11%) | 2/33 (6%)
First incidence (days) | 729 (T) | 588 | 729 (T) | 573
Poly-3 test | P = 0.392 | P = 0.230 | P = 0.493 | P = 0.347
All Organs: Malignant Lymphoma
Overall rate | 14/50 (28%) | 15/50 (30%) | 10/50 (20%) | 13/50 (26%)
Adjusted rate | 29.7% | 33.0% | 21.9% | 28.9%
Terminal rate | 10/38 (26%) | 10/32 (31%) | 7/35 (20%) | 10/33 (30%)
First incidence (days) | 598 | 382 | 686 | 612
Poly-3 test | P = 0.413N | P = 0.457 | P = 0.265N | P = 0.554N
All Organs: Benign Tumors
Overall rate | 40/50 (80%) | 48/50 (96%) | 47/50 (94%) | 44/50 (88%)
Adjusted rate | 84.4% | 99.0% | 94.5% | 89.2%
Terminal rate | 33/38 (87%) | 32/32 (100%) | 35/35 (100%) | 28/33 (85%)
First incidence (days) | 598 | 494 | 309 | 509
Poly-3 test | P = 0.512 | P = 0.007 | P = 0.084 | P = 0.338
All Organs: Malignant Tumors
Overall rate | 29/50 (58%) | 42/50 (84%) | 41/50 (82%) | 41/50 (82%)
Adjusted rate | 60.7% | 87.0% | 84.2% | 84.0%
Terminal rate | 21/38 (55%) | 27/32 (84%) | 29/35 (83%) | 26/33 (79%)
First incidence (days) | 598 | 382 | 522 | 509
Poly-3 test | P = 0.015 | P = 0.002 | P = 0.007 | P = 0.008
All Organs: Benign or Malignant Tumors
Overall rate | 43/50 (86%) | 49/50 (98%) | 50/50 (100%) | 47/50 (94%)
Adjusted rate | 89.7% | 99.3% | 100.0% | 95.3%
Terminal rate | 34/38 (90%) | 32/32 (100%) | 35/35 (100%) | 31/33 (94%)
First incidence (days) | 598 | 382 | 309 | 509
Poly-3 test | P = 0.237 | P = 0.038 | P = 0.024 | P = 0.245

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, lung, ovary, pituitary gland, and spleen; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

Table D-3 Historical Incidence of Neoplasms of the Liver in Untreated Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatoblastoma | Hepatocellular Carcinoma or Hepatoblastoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 38/49 | 11/49 | 1/49 | 12/49
Sodium dichromate dihydrate (September 2002) | 14/49 | 8/49 | 0/49 | 8/49
Total (%) | 52/98 (53.1%) | 19/98 (19.4%) | 1/98 (1.0%) | 20/98 (20.4%)
Mean ± standard deviation | 53.1% ± 34.6% | 19.4% ± 4.3% | 1.0% ± 1.4% | 20.4% ± 5.8%
Range | 29%–78% | 16%–22% | 0%–2% | 16%–24%
Overall Historical Incidence: All Routes
Total (%) | 380/1,195 (31.8%) | 144/1,195 (12.1%) | 4/1,195 (0.3%) | 148/1,195 (12.4%)
Mean ± standard deviation | 31.8% ± 21.4% | 12.1% ± 10.8% | 0.3% ± 0.8% | 12.4% ± 11.2%
Range | 2%–78% | 0%–46% | 0%–2% | 0%–46%

^a^ Data as of May 4, 2011.

Table D-4 Historical Incidence of Alveolar/Bronchiolar Neoplasms in Untreated Female B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 5/50 | 7/50 | 11/50
Sodium dichromate dihydrate (September 2002) | 1/50 | 2/50 | 2/50
Total (%) | 6/100 (6.0%) | 9/100 (9.0%) | 13/100 (13.0%)
Mean ± standard deviation | 6.0% ± 5.7% | 9.0% ± 7.1% | 13.0% ± 12.7%
Range | 2%–10% | 4%–14% | 4%–22%
Overall Historical Incidence: All Routes
Total (%) | 60/1,196 (5.0%) | 44/1,196 (3.7%) | 100/1,196 (8.4%)
Mean ± standard deviation | 5.0% ± 3.6% | 3.7% ± 3.3% | 8.4% ± 4.3%
Range | 0%–12% | 0%–14% | 2%–22%

^a^ Data as of May 4, 2011.

Table D-5 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 4 | 3 | 1 | 4
Natural deaths | 8 | 15 | 14 | 13
Survivors
Died last week of study | – | – | 1 | –
Terminal kill | 38 | 32 | 34 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (49) | (49) | (50)
Gallbladder | (43) | (36) | (36) | (35)
Degeneration, hyaline | – | – | 1 (3%) | 1 (3%)
Intestine large, cecum | (44) | (36) | (38) | (39)
Intestine large, colon | (44) | (35) | (40) | (38)
Intestine large, rectum | (43) | (35) | (37) | (38)
Intestine small, duodenum | (42) | (35) | (36) | (37)
Lymphangiectasis | – | – | 1 (3%) | –
Intestine small, ileum | (44) | (36) | (37) | (37)
Inflammation, acute | – | – | 1 (3%) | –
Intestine small, jejunum | (43) | (35) | (37) | (38)
Inflammation, granulomatous | – | 1 (3%) | – | –
Inflammation, acute | – | – | 1 (3%) | –
Liver | (49) | (50) | (50) | (50)
Angiectasis | 3 (6%) | 3 (6%) | 6 (12%) | 5 (10%)
Basophilic focus | 4 (8%) | 2 (4%) | 1 (2%) | 6 (12%)
Clear cell focus | 3 (6%) | 2 (4%) | 6 (12%) | –
Congestion | – | – | – | 1 (2%)
Eosinophilic focus | 11 (22%) | 10 (20%) | 14 (28%) | 15 (30%)
Fatty change | – | 4 (8%) | 1 (2%) | 2 (4%)
Hematopoietic cell proliferation | – | 1 (2%) | – | –
Mixed cell focus | – | – | – | 2 (4%)
Necrosis | 4 (8%) | 2 (4%) | 3 (6%) | 2 (4%)
Tension lipidosis | 1 (2%) | 1 (2%) | – | 2 (4%)
Thrombosis | – | 1 (2%) | – | –
Mesentery | (8) | (16) | (16) | (9)
Fat, hemorrhage | – | 1 (6%) | – | –
Fat, necrosis | 7 (88%) | 14 (88%) | 13 (81%) | 8 (89%)
Pancreas | (48) | (42) | (46) | (45)
Atrophy | 2 (4%) | – | 2 (4%) | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Duct, cyst | 1 (2%) | 1 (2%) | – | –
Salivary glands | (50) | (47) | (47) | (50)
Inflammation, chronic | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Stomach, forestomach | (47) | (43) | (45) | (47)
Hyperplasia, squamous | – | 1 (2%) | 3 (7%) | 3 (6%)
Ulcer | – | 1 (2%) | 1 (2%) | –
Stomach, glandular | (45) | (39) | (41) | (41)
Dysplasia | – | – | 1 (2%) | –
Hyperplasia | – | 1 (3%) | – | –
Mineralization | 2 (4%) | 2 (5%) | 1 (2%) | –
Tongue | (0) | (0) | (0) | (1)
Tooth | (0) | (1) | (2) | (9)
Dysplasia | – | – | 2 (100%) | 9 (100%)
Cardiovascular System
Blood vessel | (2) | (3) | (1) | (0)
Mineralization | 2 (100%) | 3 (100%) | 1 (100%) | –
Heart | (50) | (50) | (49) | (50)
Cardiomyopathy | 4 (8%) | 1 (2%) | 7 (14%) | 3 (6%)
Inflammation, suppurative | 1 (2%) | 1 (2%) | – | 1 (2%)
Mineralization | 1 (2%) | 4 (8%) | 1 (2%) | –
Necrosis | – | 1 (2%) | – | –
Thrombosis | 2 (4%) | 1 (2%) | – | –
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Capillary, hyperplasia | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (45) | (46) | (50)
Hyperplasia | 2 (4%) | – | – | 1 (2%)
Hypertrophy | 1 (2%) | 1 (2%) | – | 1 (2%)
Vacuolization cytoplasmic | – | – | 1 (2%) | –
Adrenal medulla | (49) | (45) | (46) | (50)
Hyperplasia | – | 1 (2%) | – | –
Islets, pancreatic | (48) | (41) | (45) | (45)
Hyperplasia | – | – | 1 (2%) | 1 (2%)
Parathyroid gland | (38) | (34) | (40) | (41)
Hyperplasia | – | – | 2 (5%) | –
Pituitary gland | (50) | (46) | (47) | (46)
Pars distalis, angiectasis | 3 (6%) | 1 (2%) | – | 1 (2%)
Pars distalis, hyperplasia | 8 (16%) | 14 (30%) | 13 (28%) | 7 (15%)
Thyroid gland | (48) | (45) | (45) | (49)
Cyst | – | – | – | 2 (4%)
Follicular cell, hyperplasia | 1 (2%) | – | – | 1 (2%)
Follicular cell, hypertrophy | – | – | 1 (2%) | –
General Body System
None | – | – | – | –
Genital System
Clitoral gland | (50) | (50) | (48) | (50)
Ovary | (49) | (48) | (48) | (47)
Cyst | 5 (10%) | 5 (10%) | 5 (10%) | 4 (9%)
Thrombosis | – | – | 2 (4%) | 4 (9%)
Uterus | (49) | (47) | (49) | (49)
Angiectasis | – | 1 (2%) | – | –
Inflammation, acute | – | – | – | 2 (4%)
Necrosis | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | 1 (2%) | –
Endometrium, hyperplasia, cystic | 33 (67%) | 29 (62%) | 33 (67%) | 37 (76%)
Hematopoietic System
Bone marrow | (49) | (46) | (48) | (49)
Angiectasis | – | – | – | 1 (2%)
Lymph node | (6) | (8) | (6) | (8)
Lumbar, angiectasis | 1 (17%) | – | – | –
Lumbar, hemorrhage | – | – | 1 (17%) | –
Mediastinal, hyperplasia, lymphoid | 1 (17%) | 1 (13%) | – | –
Pancreatic, ectasia | 1 (17%) | – | – | –
Renal, ectasia | 1 (17%) | 1 (13%) | 1 (17%) | –
Lymph node, mandibular | (48) | (42) | (47) | (47)
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Lymph node, mesenteric | (46) | (38) | (45) | (46)
Angiectasis | – | – | – | 1 (2%)
Hemorrhage | – | – | 1 (2%) | 1 (2%)
Spleen | (46) | (42) | (45) | (46)
Hematopoietic cell proliferation | 4 (9%) | 3 (7%) | 5 (11%) | 1 (2%)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Thrombosis | – | 1 (2%) | – | –
Thymus | (45) | (44) | (48) | (47)
Amyloid deposition | – | – | 1 (2%) | –
Hyperplasia, lymphoid | – | – | 1 (2%) | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (49) | (48)
Hyperplasia | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | 1 (2%) | – | –
Inflammation, acute | – | – | 1 (2%) | –
Inflammation, chronic active | – | 2 (4%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | – | – | – | 1 (2%)
Skeletal muscle | (1) | (0) | (0) | (1)
Nervous System
Brain | (50) | (47) | (47) | (50)
Hemorrhage | – | 1 (2%) | – | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Peripheral nerve | (1) | (0) | (0) | (1)
Spinal cord | (1) | (0) | (0) | (1)
Respiratory System
Lung | (50) | (50) | (49) | (50)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, acute | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Mineralization | 1 (2%) | 3 (6%) | 2 (4%) | –
Alveolar epithelium, hyperplasia | 2 (4%) | 4 (8%) | 3 (6%) | 8 (16%)
Alveolus, infiltration cellular, histiocyte | 2 (4%) | 1 (2%) | 1 (2%) | –
Bronchiole, hyperplasia | – | – | 3 (6%) | 1 (2%)
Nose | (49) | (44) | (49) | (47)
Inflammation, suppurative | 1 (2%) | – | – | 1 (2%)
Olfactory epithelium, atrophy | 1 (2%) | 2 (5%) | 2 (4%) | 7 (15%)
Olfactory epithelium, metaplasia, respiratory | 2 (4%) | 2 (5%) | 7 (14%) | 14 (30%)
Respiratory epithelium, hyperplasia | 7 (14%) | 2 (5%) | 6 (12%) | 13 (28%)
Pleura | (0) | (0) | (0) | (1)
Trachea | (47) | (41) | (45) | (44)
Mineralization | 1 (2%) | 1 (2%) | – | –
Special Senses System
Eye | (43) | (35) | (36) | (39)
Cataract | 1 (2%) | – | – | –
Degeneration | 1 (2%) | – | 1 (3%) | 1 (3%)
Cornea, inflammation, acute | 1 (2%) | 1 (3%) | – | –
Cornea, inflammation, chronic active | – | – | – | 1 (3%)
Harderian gland | (45) | (41) | (43) | (47)
Hyperplasia | 5 (11%) | 2 (5%) | 1 (2%) | 1 (2%)
Inflammation, chronic | – | – | 1 (2%) | –
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (49) | (47) | (48) | (49)
Amyloid deposition | 1 (2%) | 1 (2%) | 1 (2%) | –
Hydronephrosis | – | 1 (2%) | – | –
Inflammation, suppurative | 1 (2%) | – | – | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | 1 (2%) | –
Mineralization | 3 (6%) | 2 (4%) | 1 (2%) | 2 (4%)
Nephropathy | 29 (59%) | 16 (34%) | 25 (52%) | 30 (61%)
Renal tubule, necrosis | 2 (4%) | 3 (6%) | 1 (2%) | 2 (4%)
Urinary bladder | (44) | (37) | (39) | (41)
Inflammation, chronic | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.