# Appendix C Summary of Lesions in Male Mice in the Two-year Drinking Water Study of β-Picoline

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 6 | 4 | 8 | 7
Natural deaths | 20 | 20 | 15 | 10
Survivors
Terminal kill | 24 | 26 | 27 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (36) | (33) | (39) | (42)
Intestine large, cecum | (35) | (34) | (36) | (40)
Intestine large, colon | (40) | (40) | (41) | (40)
Sarcoma, metastatic, liver | – | 1 (3%) | – | –
Intestine large, rectum | (39) | (38) | (42) | (41)
Intestine small, duodenum | (36) | (31) | (35) | (40)
Adenoma | – | – | – | 1 (3%)
Intestine small, ileum | (36) | (35) | (39) | (40)
Intestine small, jejunum | (35) | (32) | (37) | (40)
Adenoma | – | 1 (3%) | – | 1 (3%)
Carcinoma | 2 (6%) | 1 (3%) | – | –
Liver | (50) | (50) | (50) | (50)
Cholangioma, multiple | – | – | – | 1 (2%)
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | 5 (10%) | 4 (8%) | 3 (6%) | 1 (2%)
Hepatoblastoma | 3 (6%) | 5 (10%) | 9 (18%) | 4 (8%)
Hepatoblastoma, multiple | 3 (6%) | 1 (2%) | 2 (4%) | –
Hepatocellular adenoma | 12 (24%) | 11 (22%) | 11 (22%) | 15 (30%)
Hepatocellular adenoma, multiple | 21 (42%) | 30 (60%) | 29 (58%) | 20 (40%)
Hepatocellular carcinoma | 20 (40%) | 13 (26%) | 17 (34%) | 15 (30%)
Hepatocellular carcinoma, multiple | 6 (12%) | 10 (20%) | 9 (18%) | 8 (16%)
Hepatocholangiocarcinoma | 2 (4%) | 2 (4%) | 1 (2%) | –
Ito cell tumor malignant | – | 1 (2%) | – | –
Sarcoma | – | 1 (2%) | – | –
Mesentery | (7) | (1) | (1) | (1)
Hepatocholangiocarcinoma, metastatic, liver | 1 (14%) | – | – | –
Pancreas | (49) | (48) | (48) | (49)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (47) | (47) | (47) | (47)
Hemangioma | – | 1 (2%) | – | –
Squamous cell carcinoma | – | – | 1 (2%) | –
Squamous cell papilloma | – | 1 (2%) | – | 3 (6%)
Stomach, glandular | (42) | (45) | (43) | (45)
Tooth | (35) | (41) | (42) | (41)
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | – | 2 (4%) | 2 (4%) | –
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (49) | (48) | (50) | (48)
Adenoma | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Subcapsular, adenoma | 2 (4%) | 2 (4%) | 5 (10%) | 2 (4%)
Subcapsular, carcinoma | – | – | – | 2 (4%)
Adrenal medulla | (49) | (47) | (50) | (48)
Hepatocellular carcinoma, metastatic, liver | – | – | 1 (2%) | –
Islets, pancreatic | (49) | (48) | (48) | (49)
Adenoma | 1 (2%) | – | 1 (2%) | –
Parathyroid gland | (37) | (39) | (44) | (31)
Pituitary gland | (47) | (49) | (49) | (49)
Pars distalis, adenoma | – | – | 1 (2%) | –
Thyroid gland | (49) | (50) | (49) | (49)
Follicular cell, adenoma | 1 (2%) | – | – | –
Follicular cell, carcinoma | – | 1 (2%) | – | –
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (2) | (0) | (0) | (0)
Epididymis | (50) | (50) | (50) | (49)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (48) | (50)
Seminal vesicle | (47) | (48) | (49) | (47)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | – | – | –
Testes | (50) | (50) | (50) | (50)
Interstitial cell, adenoma | – | 1 (2%) | 1 (2%) | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (48) | (50)
Hemangiosarcoma | 2 (4%) | – | – | 2 (4%)
Lymph node | (2) | (1) | (0) | (2)
Mediastinal, hemangiosarcoma | – | – | – | 1 (50%)
Mediastinal, hepatoblastoma, metastatic, liver | – | 1 (100%) | – | –
Mediastinal, hepatocellular carcinoma, | – | – | – | 1 (50%)
Metastatic, liver | – | – | – | –
Mediastinal, hepatocholangiocarcinoma, metastatic, liver | 1 (50%) | – | – | –
Lymph node, mandibular | (50) | (49) | (49) | (50)
Carcinoma, metastatic, harderian gland | – | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Lymph node, mesenteric | (45) | (45) | (43) | (45)
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Spleen | (46) | (48) | (47) | (46)
Hemangiosarcoma | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Thymus | (41) | (42) | (48) | (47)
Hemangiosarcoma, metastatic, liver | – | 1 (2%) | – | –
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | 1 (2%) | – | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Integumentary System
Skin | (50) | (50) | (50) | (50)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 2 (4%) | – | 1 (2%)
Subcutaneous tissue, hemangioma | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | 1 (2%) | – | 2 (4%) | 1 (2%)
Subcutaneous tissue, lipoma | – | – | 1 (2%) | 1 (2%)
Subcutaneous tissue, sarcoma | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Chondrosarcoma | – | – | 1 (2%) | –
Skeletal muscle | (1) | (0) | (0) | (0)
Rhabdomyosarcoma | 1 (100%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 6 (12%) | 11 (22%) | 14 (28%) | 6 (12%)
Alveolar/bronchiolar adenoma, multiple | – | – | 2 (4%) | 2 (4%)
Alveolar/bronchiolar carcinoma | 9 (18%) | 7 (14%) | 8 (16%) | 6 (12%)
Alveolar/bronchiolar carcinoma, multiple | – | 2 (4%) | – | 3 (6%)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | 1 (2%)
Hemangiosarcoma | 2 (4%) | – | – | –
Hemangiosarcoma, metastatic, liver | – | 1 (2%) | – | –
Hepatoblastoma, metastatic, liver | 2 (4%) | – | 1 (2%) | –
Hepatocellular carcinoma, metastatic, liver | 14 (28%) | 12 (24%) | 12 (24%) | 6 (12%)
Hepatocholangiocarcinoma, metastatic, liver | 1 (2%) | 1 (2%) | 1 (2%) | –
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Sarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Carcinoma, metastatic, harderian gland | – | – | – | 1 (2%)
Hemangiosarcoma | 1 (2%) | – | – | –
Pleura | (0) | (1) | (0) | (1)
Hepatocellular carcinoma, metastatic, liver | – | 1 (100%) | – | 1 (100%)
Trachea | (47) | (49) | (45) | (49)
Special Senses System
Eye | (36) | (39) | (43) | (40)
Harderian gland | (46) | (47) | (46) | (47)
Adenoma | 5 (11%) | 5 (11%) | 3 (7%) | 2 (4%)
Carcinoma | 2 (4%) | 4 (9%) | 1 (2%) | 3 (6%)
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (49)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | 2 (4%) | 2 (4%)
Hepatocholangiocarcinoma, metastatic, liver | – | – | 1 (2%) | –
Sarcoma, metastatic, liver | – | 1 (2%) | – | –
Renal tubule, adenoma, multiple | – | – | – | 1 (2%)
Renal tubule, carcinoma | – | – | 1 (2%) | –
Urethra | (3) | (3) | (5) | (3)
Urinary bladder | (45) | (45) | (45) | (46)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | 1 (2%) | – | –
Lymphoma malignant | – | 3 (6%) | 2 (4%) | –
Mesothelioma benign | 1 (2%) | – | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 48 | 50 | 48 | 46
Total primary neoplasms | 112 | 124 | 128 | 105
Total animals with benign neoplasms | 36 | 44 | 44 | 43
Total benign neoplasms | 49 | 63 | 69 | 58
Total animals with malignant neoplasms | 36 | 40 | 38 | 32
Total malignant neoplasms | 62 | 61 | 59 | 47
Total animals with metastatic neoplasms | 19 | 16 | 14 | 7
Total metastatic neoplasms | 32 | 31 | 23 | 15
Total animals with malignant neoplasms of uncertain primary site | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Adrenal Cortex: Adenoma
Overall rate^a^ | 2/49 (4%) | 1/48 (2%) | 6/50 (12%) | 3/48 (6%)
Adjusted rate^b^ | 5.4% | 2.6% | 14.7% | 7.2%
Terminal rate^c^ | 1/24 (4%) | 1/26 (4%) | 5/27 (19%) | 3/33 (9%)
First incidence (days) | 543 | 730 (T) | 685 | 730 (T)
Poly-3 test^d^ | P = 0.344 | P = 0.479N | P = 0.166 | P = 0.558
Harderian Gland: Adenoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 13.1% | 12.2% | 7.4% | 4.6%
Terminal rate | 2/24 (8%) | 4/26 (15%) | 2/27 (7%) | 2/33 (6%)
First incidence (days) | 562 | 722 | 707 | 730 (T)
Poly-3 test | P = 0.093N | P = 0.588N | P = 0.319N | P = 0.163N
Harderian Gland: Carcinoma
Overall rate | 2/50 (4%) | 4/50 (8%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 5.3% | 9.7% | 2.5% | 6.7%
Terminal rate | 1/24 (4%) | 2/26 (8%) | 1/27 (4%) | 1/33 (3%)
First incidence (days) | 505 | 583 | 730 (T) | 534
Poly-3 test | P = 0.561N | P = 0.383 | P = 0.472N | P = 0.581
Harderian Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 3/50 (6%) | 5/50 (10%)
Adjusted rate | 18.0% | 21.7% | 7.4% | 11.1%
Terminal rate | 3/24 (13%) | 6/26 (23%) | 2/27 (7%) | 3/33 (9%)
First incidence (days) | 505 | 583 | 707 | 534
Poly-3 test | P = 0.127N | P = 0.447 | P = 0.135N | P = 0.280N
Liver: Hemangiosarcoma
Overall rate | 5/50 (10%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 12.9% | 9.7% | 7.3% | 2.3%
Terminal rate | 1/24 (4%) | 1/26 (4%) | 2/27 (7%) | 0/33 (0%)
First incidence (days) | 402 | 583 | 631 | 709
Poly-3 test | P = 0.048N | P = 0.456N | P = 0.323N | P = 0.074N
Liver: Hepatocellular Adenoma
Overall rate | 33/50 (66%) | 41/50 (82%) | 40/50 (80%) | 35/50 (70%)
Adjusted rate | 77.5% | 84.9% | 85.3% | 73.7%
Terminal rate | 22/24 (92%) | 22/26 (85%) | 24/27 (89%) | 24/33 (73%)
First incidence (days) | 460 | 407 | 470 | 465
Poly-3 test | P = 0.227N | P = 0.242 | P = 0.225 | P = 0.425N
Liver: Hepatocellular Carcinoma
Overall rate | 26/50 (52%) | 23/50 (46%) | 26/50 (52%) | 23/50 (46%)
Adjusted rate | 59.2% | 50.9% | 56.1% | 49.8%
Terminal rate | 11/24 (46%) | 11/26 (42%) | 12/27 (44%) | 13/33 (39%)
First incidence (days) | 455 | 580 | 456 | 534
Poly-3 test | P = 0.268N | P = 0.277N | P = 0.465N | P = 0.242N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 45/50 (90%) | 46/50 (92%) | 48/50 (96%) | 42/50 (84%)
Adjusted rate | 96.2% | 92.7% | 98.4% | 88.0%
Terminal rate | 24/24 (100%) | 24/26 (92%) | 27/27 (100%) | 28/33 (85%)
First incidence (days) | 455 | 407 | 456 | 465
Poly-3 test | P = 0.084N | P = 0.374N | P = 0.468 | P = 0.114N
Liver: Hepatoblastoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 11/50 (22%) | 4/50 (8%)
Adjusted rate | 15.4% | 14.4% | 26.1% | 9.1%
Terminal rate | 2/24 (8%) | 3/26 (12%) | 5/27 (19%) | 3/33 (9%)
First incidence (days) | 519 | 627 | 456 | 715
Poly-3 test | P = 0.276N | P = 0.574N | P = 0.181 | P = 0.296N
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 26/50 (52%) | 26/50 (52%) | 32/50 (64%) | 25/50 (50%)
Adjusted rate | 59.2% | 56.9% | 68.7% | 54.1%
Terminal rate | 11/24 (46%) | 12/26 (46%) | 16/27 (59%) | 15/33 (46%)
First incidence (days) | 455 | 580 | 456 | 534
Poly-3 test | P = 0.395N | P = 0.498N | P = 0.230 | P = 0.389N
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 45/50 (90%) | 47/50 (94%) | 48/50 (96%) | 42/50 (84%)
Adjusted rate | 96.2% | 94.8% | 98.4% | 88.0%
Terminal rate | 24/24 (100%) | 25/26 (96%) | 27/27 (100%) | 28/33 (85%)
First incidence (days) | 455 | 407 | 456 | 465
Poly-3 test | P = 0.050N | P = 0.573N | P = 0.468 | P = 0.114N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 6/50 (12%) | 11/50 (22%) | 16/50 (32%) | 8/50 (16%)
Adjusted rate | 16.3% | 25.8% | 36.1% | 18.2%
Terminal rate | 6/24 (25%) | 5/26 (19%) | 8/27 (30%) | 6/33 (18%)
First incidence (days) | 730 (T) | 627 | 470 | 709
Poly-3 test | P = 0.504N | P = 0.222 | P = 0.037 | P = 0.526
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 9/50 (18%) | 9/50 (18%) | 8/50 (16%) | 9/50 (18%)
Adjusted rate | 23.2% | 21.2% | 19.4% | 20.6%
Terminal rate | 5/24 (21%) | 5/26 (19%) | 6/27 (22%) | 8/33 (24%)
First incidence (days) | 455 | 512 | 628 | 724
Poly-3 test | P = 0.448N | P = 0.516N | P = 0.443N | P = 0.490N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 14/50 (28%) | 19/50 (38%) | 21/50 (42%) | 15/50 (30%)
Adjusted rate | 36.2% | 42.8% | 47.0% | 34.2%
Terminal rate | 10/24 (42%) | 9/26 (35%) | 12/27 (44%) | 12/33 (36%)
First incidence (days) | 455 | 512 | 470 | 709
Poly-3 test | P = 0.382N | P = 0.343 | P = 0.213 | P = 0.517N
Skin (Subcutaneous Tissue): Fibrous Histiocytoma or Sarcoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 0/50 (0%) | 1/50 (2%)
Adjusted rate | 2.7% | 7.3% | 0.0% | 2.3%
Terminal rate | 1/24 (4%) | 2/26 (8%) | 0/27 (0%) | 1/33 (3%)
First incidence (days) | 730 (T) | 690 | –^e^ | 730 (T)
Poly-3 test | P = 0.360N | P = 0.343 | P = 0.481N | P = 0.721N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 0/50 (0%) | 1/50 (2%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.4% | 0.0% | 6.8%
Terminal rate | 0/24 (0%) | 0/26 (0%) | 0/27 (0%) | 2/33 (6%)
First incidence (days) | – | 704 | – | 534
Poly-3 test | P = 0.054 | P = 0.521 | –^f^ | P = 0.155
Stomach (Forestomach): Squamous Cell Papilloma or Carcinoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate | 0.0% | 2.4% | 2.5% | 6.8%
Terminal rate | 0/24 (0%) | 0/26 (0%) | 1/27 (4%) | 2/33 (6%)
First incidence (days) | – | 704 | 730 (T) | 534
Poly-3 test | P = 0.073 | P = 0.521 | P = 0.519 | P = 0.155
All Organs: Hemangiosarcoma
Overall rate | 6/50 (12%) | 5/50 (10%) | 4/50 (8%) | 4/50 (8%)
Adjusted rate | 15.5% | 11.9% | 9.8% | 9.1%
Terminal rate | 2/24 (8%) | 1/26 (4%) | 3/27 (11%) | 2/33 (6%)
First incidence (days) | 402 | 583 | 631 | 709
Poly-3 test | P = 0.244N | P = 0.443N | P = 0.331N | P = 0.292N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 7/50 (14%) | 7/50 (14%) | 4/50 (8%) | 5/50 (10%)
Adjusted rate | 18.1% | 16.7% | 9.8% | 11.4%
Terminal rate | 3/24 (13%) | 3/26 (12%) | 3/27 (11%) | 3/33 (9%)
First incidence (days) | 402 | 583 | 631 | 709
Poly-3 test | P = 0.204N | P = 0.551N | P = 0.224N | P = 0.292N
All Organs: Malignant Lymphoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.3% | 4.9% | 0.0%
Terminal rate | 0/24 (0%) | 2/26 (8%) | 2/27 (7%) | 0/33 (0%)
First incidence (days) | – | 621 | 730 (T) | –
Poly-3 test | P = 0.322N | P = 0.139 | P = 0.259 | –
All Organs: Benign Tumors
Overall rate | 36/50 (72%) | 44/50 (88%) | 44/50 (88%) | 43/50 (86%)
Adjusted rate | 82.1% | 89.7% | 91.8% | 90.3%
Terminal rate | 22/24 (92%) | 22/26 (85%) | 25/27 (93%) | 30/33 (91%)
First incidence (days) | 460 | 407 | 470 | 465
Poly-3 test | P = 0.178 | P = 0.201 | P = 0.112 | P = 0.177
All Organs: Malignant Tumors
Overall rate | 36/50 (72%) | 40/50 (80%) | 38/50 (76%) | 32/50 (64%)
Adjusted rate | 77.3% | 83.6% | 81.1% | 68.4%
Terminal rate | 16/24 (67%) | 19/26 (73%) | 21/27 (78%) | 20/33 (61%)
First incidence (days) | 402 | 512 | 456 | 534
Poly-3 test | P = 0.105N | P = 0.298 | P = 0.419 | P = 0.226N
All Organs: Benign or Malignant Tumors
Overall rate | 48/50 (96%) | 50/50 (100%) | 48/50 (96%) | 46/50 (92%)
Adjusted rate | 99.1% | 100% | 98.4% | 96.4%
Terminal rate | 24/24 (100%) | 26/26 (100%) | 27/27 (100%) | 32/33 (97%)
First incidence (days) | 402 | 407 | 456 | 465
Poly-3 test | P = 0.107N | P = 0.946 | P = 0.860N | P = 0.403N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, bone marrow, liver, and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table C-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Untreated Male B6C3F1/N Mice^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 6/50 | 9/50 | 14/50
Sodium dichromate dihydrate (September 2002) | 15/50 | 3/50 | 16/50
Total (%) | 21/100 (21.0%) | 12/100 (12.0%) | 30/100 (30.0%)
Mean ± standard deviation | 21.0% ± 12.7% | 12.0% ± 8.5% | 30.0% ± 2.8%
Range | 12%–30% | 6%–18% | 28%–32%
Overall Historical Incidence: All Routes
Total (%) | 172/1,150 (15.0%) | 144/1,150 (12.5%) | 301/1,150 (26.2%)
Mean ± standard deviation | 15.0% ± 6.9% | 12.5% ± 7.1% | 26.2% ± 6.3%
Range | 2%–30% | 4%–24% | 14%–40%

^a^ Data as of May 4, 2011.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 312.5 mg/L | 625 mg/L | 1,250 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 6 | 4 | 8 | 7
Natural deaths | 20 | 20 | 15 | 10
Survivors
Terminal kill | 24 | 26 | 27 | 33
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (36) | (33) | (39) | (42)
Degeneration, hyaline | – | 1 (3%) | – | –
Inflammation, chronic active | – | – | 1 (3%) | –
Intestine large, cecum | (35) | (34) | (36) | (40)
Intestine large, colon | (40) | (40) | (41) | (40)
Intestine large, rectum | (39) | (38) | (42) | (41)
Intestine small, duodenum | (36) | (31) | (35) | (40)
Intestine small, ileum | (36) | (35) | (39) | (40)
Intestine small, jejunum | (35) | (32) | (37) | (40)
Diverticulum | 1 (3%) | – | – | –
Peyer’s patch, hyperplasia, lymphoid | – | 1 (3%) | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 3 (6%) | 2 (4%) | 3 (6%)
Basophilic focus | 10 (20%) | 12 (24%) | 15 (30%) | 7 (14%)
Clear cell focus | 15 (30%) | 19 (38%) | 16 (32%) | 9 (18%)
Congestion | – | – | – | 1 (2%)
Cyst | – | – | – | 1 (2%)
Eosinophilic focus | 18 (36%) | 16 (32%) | 19 (38%) | 10 (20%)
Fatty change | – | 1 (2%) | – | –
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Inflammation, chronic | – | – | 2 (4%) | 1 (2%)
Inflammation, chronic active | – | – | – | 2 (4%)
Mineralization | – | – | 1 (2%) | –
Mixed cell focus | 5 (10%) | 4 (8%) | 5 (10%) | 4 (8%)
Necrosis | 5 (10%) | 6 (12%) | 6 (12%) | 4 (8%)
Mesentery | (7) | (1) | (1) | (1)
Inflammation, chronic active | 1 (14%) | – | – | –
Fat, necrosis | 5 (71%) | – | 1 (100%) | 1 (100%)
Pancreas | (49) | (48) | (48) | (49)
Atrophy | 1 (2%) | – | – | –
Necrosis | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (47) | (47) | (47) | (47)
Hyperplasia, squamous | 2 (4%) | 4 (9%) | 3 (6%) | 1 (2%)
Ulcer | 5 (11%) | 3 (6%) | 4 (9%) | 1 (2%)
Stomach, glandular | (42) | (45) | (43) | (45)
Mineralization | – | 2 (4%) | – | –
Necrosis | – | – | 1 (2%) | –
Ulcer | 1 (2%) | 2 (4%) | – | –
Tooth | (35) | (41) | (42) | (41)
Dysplasia | 35 (100%) | 41 (100%) | 42 (100%) | 41 (100%)
Cardiovascular System
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 12 (24%) | 17 (34%) | 7 (14%) | 4 (8%)
Inflammation, suppurative | 2 (4%) | – | – | –
Mineralization | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis | – | 1 (2%) | 1 (2%) | –
Thrombosis | 2 (4%) | 2 (4%) | 1 (2%) | –
Artery, inflammation, chronic active | – | – | 1 (2%) | 2 (4%)
Endocrine System
Adrenal cortex | (49) | (48) | (50) | (48)
Atrophy | – | 1 (2%) | – | –
Hyperplasia | 10 (20%) | 8 (17%) | 9 (18%) | 5 (10%)
Hypertrophy | 12 (24%) | 14 (29%) | 14 (28%) | 17 (35%)
Subcapsular, hyperplasia | – | 1 (2%) | – | –
Adrenal medulla | (49) | (47) | (50) | (48)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | –
Islets, pancreatic | (49) | (48) | (48) | (49)
Hyperplasia | – | 1 (2%) | 2 (4%) | –
Parathyroid gland | (37) | (39) | (44) | (31)
Pituitary gland | (47) | (49) | (49) | (49)
Thrombosis | 1 (2%) | – | – | –
Pars distalis, hyperplasia | 1 (2%) | – | 2 (4%) | –
Thyroid gland | (49) | (50) | (49) | (49)
General Body System
None | – | – | – | –
Genital System
Coagulating gland | (2) | (0) | (0) | (0)
Inflammation, suppurative | 1 (50%) | – | – | –
Epididymis | (50) | (50) | (50) | (49)
Granuloma sperm | – | 1 (2%) | – | 2 (4%)
Mineralization | – | – | – | 1 (2%)
Preputial gland | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Inflammation, chronic active | 3 (6%) | 3 (6%) | 4 (8%) | 1 (2%)
Prostate | (50) | (50) | (48) | (50)
Hyperplasia | – | 1 (2%) | – | –
Inflammation, suppurative | 4 (8%) | – | 2 (4%) | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Seminal vesicle | (47) | (48) | (49) | (47)
Amyloid deposition | – | – | 2 (4%) | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | – | 1 (2%) | 3 (6%) | 2 (4%)
Testes | (50) | (50) | (50) | (50)
Atrophy | 1 (2%) | 2 (4%) | 2 (4%) | –
Mineralization | – | – | 1 (2%) | 1 (2%)
Interstitial cell, hyperplasia | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (48) | (50)
Angiectasis | – | – | 1 (2%) | –
Lymph node | (2) | (1) | (0) | (2)
Renal, hyperplasia, lymphoid | 1 (50%) | – | – | –
Lymph node, mandibular | (50) | (49) | (49) | (50)
Infiltration cellular, plasma cell | – | – | 1 (2%) | –
Lymph node, mesenteric | (45) | (45) | (43) | (45)
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Inflammation, chronic | – | – | 1 (2%) | –
Spleen | (46) | (48) | (47) | (46)
Hematopoietic cell proliferation | 1 (2%) | 1 (2%) | – | –
Hyperplasia, lymphoid | 2 (4%) | – | – | –
Thymus | (41) | (42) | (48) | (47)
Integumentary System
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 1 (2%) | – | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Skeletal muscle | (1) | (0) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Glial cell, pigmentation | 1 (2%) | – | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Hemorrhage | 2 (4%) | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, granulomatous | 1 (2%) | 1 (2%) | – | –
Thrombosis | – | – | 1 (2%) | 2 (4%)
Alveolar epithelium, hyperplasia | 4 (8%) | 6 (12%) | 6 (12%) | 7 (14%)
Alveolus, infiltration cellular, histiocyte | 2 (4%) | 1 (2%) | 3 (6%) | 2 (4%)
Bronchiole, hyperplasia | 1 (2%) | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Inflammation, suppurative | 4 (8%) | 9 (18%) | 9 (18%) | 6 (12%)
Olfactory epithelium, atrophy | 3 (6%) | 4 (8%) | 8 (16%) | 7 (14%)
Olfactory epithelium, metaplasia, respiratory | 8 (16%) | 12 (24%) | 30 (60%) | 41 (82%)
Respiratory epithelium, hyperplasia | 18 (36%) | 23 (46%) | 23 (46%) | 17 (34%)
Pleura | (0) | (1) | (0) | (1)
Trachea | (47) | (49) | (45) | (49)
Special Senses System
Eye | (36) | (39) | (43) | (40)
Degeneration | 1 (3%) | 1 (3%) | 1 (2%) | 1 (3%)
Inflammation, suppurative | – | – | – | 1 (3%)
Cornea, inflammation, chronic active | – | – | 1 (2%) | –
Retina, hemorrhage, chronic | 1 (3%) | – | 1 (2%) | –
Harderian gland | (46) | (47) | (46) | (47)
Hyperplasia | 1 (2%) | 1 (2%) | – | 4 (9%)
Inflammation, chronic | – | – | 1 (2%) | –
Urinary System
Kidney | (50) | (50) | (50) | (49)
Amyloid deposition | – | – | 1 (2%) | –
Cyst | 1 (2%) | – | – | –
Hydronephrosis | 1 (2%) | 2 (4%) | 1 (2%) | 2 (4%)
Infarct | – | 1 (2%) | 1 (2%) | –
Inflammation, suppurative | 2 (4%) | – | – | 1 (2%)
Metaplasia, osseous | 4 (8%) | 4 (8%) | 1 (2%) | 4 (8%)
Mineralization | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Nephropathy | 43 (86%) | 49 (98%) | 49 (98%) | 49 (100%)
Thrombosis | 1 (2%) | – | – | –
Artery, inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Papilla, necrosis | 2 (4%) | – | 1 (2%) | 2 (4%)
Renal tubule, hyperplasia | – | – | 1 (2%) | –
Renal tubule, hypertrophy | – | 1 (2%) | – | –
Renal tubule, pigmentation | 1 (2%) | – | – | 1 (2%)
Urethra | (3) | (3) | (5) | (3)
Inflammation, suppurative | 1 (33%) | 3 (100%) | 3 (60%) | 1 (33%)
Urinary bladder | (45) | (45) | (45) | (46)
Hemorrhage | 1 (2%) | 1 (2%) | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic | – | – | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.