# Appendix B Summary of Lesions in Female Rats in the Two-year Drinking Water Study of β-Picoline

Table B-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 15 | 13 | 14 | 15
Natural deaths | 5 | 5 | 3 | 5
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 29 | 32 | 33 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (46) | (45) | (47) | (45)
Intestine large, colon | (47) | (48) | (50) | (49)
Intestine large, rectum | (47) | (48) | (50) | (49)
Leiomyosarcoma, metastatic, uterus | 1 (2%) | – | – | –
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Intestine small, duodenum | (50) | (47) | (50) | (50)
Intestine small, ileum | (47) | (46) | (49) | (50)
Intestine small, jejunum | (48) | (46) | (47) | (48)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | 2 (4%) | – | – | –
Mesentery | (4) | (7) | (7) | (8)
Sarcoma, metastatic, uncertain primary site | – | – | 1 (14%) | –
Oral mucosa | (0) | (0) | (1) | (2)
Squamous cell papilloma | – | – | 1 (100%) | 1 (50%)
Pancreas | (50) | (50) | (49) | (50)
Sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Salivary glands | (50) | (50) | (50) | (50)
Stomach, forestomach | (50) | (50) | (50) | (50)
Stomach, glandular | (50) | (50) | (49) | (50)
Tongue | (0) | (0) | (0) | (1)
Squamous cell papilloma | – | – | – | 1 (100%)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 2 (4%) | 4 (8%) | 2 (4%) | 3 (6%)
Adrenal medulla | (50) | (50) | (50) | (50)
Pheochromocytoma benign | 2 (4%) | – | 3 (6%) | –
Pheochromocytoma malignant | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (49) | (50) | (50)
Adenoma | – | 1 (2%) | – | 1 (2%)
Parathyroid gland | (47) | (49) | (48) | (48)
Pituitary gland | (50) | (49) | (49) | (50)
Pars distalis, adenoma | 30 (60%) | 27 (55%) | 29 (59%) | 26 (52%)
Pars nervosa, craniopharyngioma | – | – | – | 1 (2%)
Thyroid gland | (50) | (48) | (50) | (50)
Carcinoma | – | – | 1 (2%) | 1 (2%)
Bilateral, c-cell, adenoma | 1 (2%) | – | 2 (4%) | –
C-cell, adenoma | 9 (18%) | 3 (6%) | 1 (2%) | 6 (12%)
C-cell, carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Follicular cell, adenoma | – | – | – | 1 (2%)
General Body System
Peritoneum | (0) | (1) | (0) | (0)
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Adenoma | 7 (14%) | 7 (14%) | 12 (24%) | 8 (16%)
Carcinoma | – | 1 (2%) | 1 (2%) | 2 (4%)
Sarcoma | 1 (2%) | – | 1 (2%) | –
Bilateral, adenoma | – | 2 (4%) | – | –
Ovary | (50) | (50) | (50) | (50)
Granulosa cell tumor benign | – | – | 1 (2%) | –
Granulosa cell tumor malignant | – | 2 (4%) | – | –
Granulosa-theca tumor malignant | – | – | – | 1 (2%)
Schwannoma malignant | 1 (2%) | – | – | –
Uterus | (50) | (50) | (50) | (50)
Leiomyosarcoma | 1 (2%) | – | 1 (2%) | –
Polyp stromal | 8 (16%) | 13 (26%) | 13 (26%) | 6 (12%)
Cervix, sarcoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Endometrium, adenoma | – | – | 1 (2%) | –
Endometrium, carcinoma | 1 (2%) | – | – | –
Vagina | (1) | (1) | (0) | (2)
Polyp | 1 (100%) | 1 (100%) | – | 2 (100%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (5) | (7) | (5) | (2)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Spleen | (50) | (50) | (50) | (50)
Thymus | (49) | (50) | (50) | (47)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Adenoma | – | – | 2 (4%) | 1 (2%)
Carcinoma | 2 (4%) | – | 1 (2%) | –
Fibroadenoma | 22 (44%) | 15 (30%) | 17 (34%) | 17 (34%)
Fibroadenoma, multiple | 12 (24%) | 16 (32%) | 11 (22%) | 6 (12%)
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 1 (2%) | – | – | –
Keratoacanthoma | – | – | – | 1 (2%)
Subcutaneous tissue, fibroma | 2 (4%) | 2 (4%) | 1 (2%) | –
Subcutaneous tissue, fibrosarcoma | – | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, hemangiosarcoma | – | – | 1 (2%) | –
Subcutaneous tissue, lipoma | – | – | – | 1 (2%)
Subcutaneous tissue, sarcoma | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Osteosarcoma | – | – | – | 1 (2%)
Skeletal muscle | (0) | (1) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma benign | 1 (2%) | – | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 3 (6%) | 2 (4%) | 5 (10%)
Alveolar/bronchiolar carcinoma | – | 1 (2%) | – | –
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | 1 (2%) | 1 (2%)
Hemangiosarcoma, metastatic, skin | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Respiratory epithelium, adenoma | – | – | 1 (2%) | –
Trachea | (50) | (50) | (50) | (50)
Special Senses System
Eye | (50) | (48) | (48) | (50)
Harderian gland | (50) | (50) | (50) | (50)
Zymbal’s gland | (0) | (0) | (2) | (1)
Carcinoma | – | – | 2 (100%) | –
Urinary System
Kidney | (49) | (50) | (50) | (50)
Renal tubule, adenoma | – | 1 (2%) | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Leiomyosarcoma, metastatic, uterus | 1 (2%) | – | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 12 (24%) | 15 (30%) | 18 (36%) | 10 (20%)
Lymphoma malignant | – | – | – | 1 (2%)
Mesothelioma malignant | – | 1 (2%) | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 49 | 49 | 48 | 45
Total primary neoplasms | 119 | 117 | 130 | 107
Total animals with benign neoplasms | 47 | 45 | 44 | 43
Total benign neoplasms | 100 | 95 | 100 | 87
Total animals with malignant neoplasms | 17 | 18 | 26 | 18
Total malignant neoplasms | 19 | 22 | 30 | 20
Total animals with metastatic neoplasms | 2 | – | 3 | 2
Total metastatic neoplasms | 3 | – | 6 | 2
Total animals with malignant neoplasms of uncertain primary site | – | – | 1 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in Female Rats in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Adrenal Cortex: Adenoma
Overall rate^a^ | 2/50 (4%) | 4/50 (8%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate^b^ | 4.6% | 9.2% | 4.4% | 6.9%
Terminal rate^c^ | 1/30 (3%) | 4/32 (13%) | 1/33 (3%) | 2/30 (7%)
First incidence (days) | 691 | 727 (T) | 666 | 656
Poly-3 test^d^ | P = 0.518 | P = 0.334 | P = 0.681N | P = 0.495
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 4.6% | 0.0% | 6.6% | 0%
Terminal rate | 2/30 (7%) | 0/32 (0%) | 2/33 (6%) | 0/30 (0%)
First incidence (days) | 727 (T) | –^e^ | 683 | –
Poly-3 test | P = 0.299N | P = 0.237N | P = 0.518 | P = 0.240N
Adrenal Medulla: Benign or Malignant Pheochromocytoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.6% | 0.0% | 6.6% | 2.3%
Terminal rate | 2/30 (7%) | 0/32 (0%) | 2/33 (6%) | 1/30 (3%)
First incidence (days) | 727 (T) | – | 683 | 727 (T)
Poly-3 test | P = 0.560N | P = 0.237N | P = 0.518 | P = 0.505N
Clitoral Gland: Adenoma
Overall rate | 7/50 (14%) | 9/50 (18%) | 12/50 (24%) | 8/50 (16%)
Adjusted rate | 16.0% | 20.1% | 26.5% | 18.2%
Terminal rate | 6/30 (20%) | 7/32 (22%) | 11/33 (33%) | 5/30 (17%)
First incidence (days) | 691 | 474 | 721 | 515
Poly-3 test | P = 0.452 | P = 0.408 | P = 0.168 | P = 0.505
Clitoral Gland: Adenoma or Carcinoma
Overall rate | 7/50 (14%) | 10/50 (20%) | 12/50 (24%) | 10/50 (20%)
Adjusted rate | 16.0% | 22.4% | 26.5% | 22.7%
Terminal rate | 6/30 (20%) | 8/32 (25%) | 11/33 (33%) | 6/30 (20%)
First incidence (days) | 691 | 474 | 721 | 515
Poly-3 test | P = 0.283 | P = 0.311 | P = 0.168 | P = 0.299
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 0.0% | 6.7% | 4.4% | 11.5%
Terminal rate | 0/30 (0%) | 1/32 (3%) | 2/33 (6%) | 4/30 (13%)
First incidence (days) | – | 526 | 727 (T) | 638
Poly-3 test | P = 0.029 | P = 0.122 | P = 0.245 | P = 0.030
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 4/50 (8%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 0.0% | 9.0% | 4.4% | 11.5%
Terminal rate | 0/30 (0%) | 2/32 (6%) | 2/33 (6%) | 4/30 (13%)
First incidence (days) | – | 526 | 727 (T) | 638
Poly-3 test | P = 0.050 | P = 0.063 | P = 0.245 | P = 0.030
Mammary Gland: Fibroadenoma
Overall rate | 34/50 (68%) | 31/50 (62%) | 28/50 (56%) | 23/50 (46%)
Adjusted rate | 74.6% | 67.8% | 60.4% | 50.2%
Terminal rate | 23/30 (77%) | 23/32 (72%) | 22/33 (67%) | 13/30 (43%)
First incidence (days) | 579 | 526 | 642 | 540
Poly-3 test | P = 0.006N | P = 0.306N | P = 0.100N | P = 0.010N
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 34/50 (68%)^f^ | 31/50 (62%) | 29/50 (58%)^g^ | 24/50 (48%)
Adjusted rate | 74.6% | 67.8% | 62.4% | 51.6%
Terminal rate | 23/30 (77%) | 23/32 (72%) | 22/33 (67%) | 13/30 (43%)
First incidence (days) | 579 | 526 | 642 | 474
Poly-3 test | P = 0.009N | P = 0.306N | P = 0.140N | P = 0.014N
Mammary Gland: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 4.6% | 0.0% | 6.6% | 2.3%
Terminal rate | 2/30 (7%) | 0/32 (0%) | 1/33 (3%) | 0/30 (0%)
First incidence (days) | 727 (T) | – | 642 | 474
Poly-3 test | P = 0.553N | P = 0.237N | P = 0.521 | P = 0.499N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 30/50 (60%) | 27/49 (55%) | 29/49 (59%) | 26/50 (52%)
Adjusted rate | 62.1% | 59.6% | 63.0% | 55.8%
Terminal rate | 15/30 (50%) | 19/32 (59%) | 23/33 (70%) | 14/30 (47%)
First incidence (days) | 454 | 474 | 527 | 474
Poly-3 test | P = 0.316N | P = 0.488N | P = 0.546 | P = 0.339N
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, or Sarcoma
Overall rate | 2/50 (4%) | 3/50 (6%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 4.6% | 6.9% | 4.4% | 2.3%
Terminal rate | 1/30 (3%) | 3/32 (9%) | 1/33 (3%) | 1/30 (3%)
First incidence (days) | 712 | 727 (T) | 579 | 727 (T)
Poly-3 test | P = 0.316N | P = 0.498 | P = 0.678N | P = 0.505N
Thyroid Gland (C-Cell): Adenoma
Overall rate | 10/50 (20%) | 3/48 (6%) | 3/50 (6%) | 6/50 (12%)
Adjusted rate | 22.5% | 7.1% | 6.6% | 13.7%
Terminal rate | 9/30 (30%) | 3/32 (9%) | 2/33 (6%) | 4/30 (13%)
First incidence (days) | 488 | 727 (T) | 666 | 638
Poly-3 test | P = 0.236N | P = 0.040N | P = 0.030N | P = 0.213N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 11/50 (22%) | 4/48 (8%) | 5/50 (10%) | 7/50 (14%)
Adjusted rate | 24.8% | 9.4% | 11.0% | 16.0%
Terminal rate | 10/30 (33%) | 4/32 (13%) | 4/33 (12%) | 5/30 (17%)
First incidence (days) | 488 | 727 (T) | 666 | 638
Poly-3 test | P = 0.268N | P = 0.051N | P = 0.074N | P = 0.224N
Uterus: Stromal Polyp
Overall rate | 8/50 (16%) | 13/50 (26%) | 13/50 (26%) | 6/50 (12%)
Adjusted rate | 18.3% | 29.1% | 28.1% | 13.8%
Terminal rate | 8/30 (27%) | 10/32 (31%) | 8/33 (24%) | 5/30 (17%)
First incidence (days) | 727 (T) | 526 | 642 | 607
Poly-3 test | P = 0.235N | P = 0.173 | P = 0.199 | P = 0.388N
All Organs: Mononuclear Leukemia
Overall rate | 12/50 (24%) | 15/50 (30%) | 18/50 (36%) | 10/50 (20%)
Adjusted rate | 26.3% | 33.1% | 38.4% | 22.3%
Terminal rate | 5/30 (17%) | 7/32 (22%) | 10/33 (30%) | 6/30 (20%)
First incidence (days) | 454 | 614 | 527 | 515
Poly-3 test | P = 0.336N | P = 0.314 | P = 0.153 | P = 0.420N
All Organs: Benign Tumors
Overall rate | 47/50 (94%) | 45/50 (90%) | 44/50 (88%) | 43/50 (86%)
Adjusted rate | 96.0% | 93.9% | 91.4% | 88.2%
Terminal rate | 29/30 (97%) | 32/32 (100%) | 32/33 (97%) | 26/30 (87%)
First incidence (days) | 454 | 474 | 527 | 474
Poly-3 test | P = 0.067N | P = 0.487N | P = 0.278N | P = 0.125N
All Organs: Malignant Tumors
Overall rate | 17/50 (34%) | 18/50 (36%) | 27/50 (54%) | 18/50 (36%)
Adjusted rate | 36.5% | 39.2% | 56.1% | 39.4%
Terminal rate | 8/30 (27%) | 9/32 (28%) | 15/33 (46%) | 11/30 (37%)
First incidence (days) | 454 | 488 | 527 | 515
Poly-3 test | P = 0.354 | P = 0.478 | P = 0.040 | P = 0.470
All Organs: Benign or Malignant Tumors
Overall rate | 49/50 (98%) | 49/50 (98%) | 48/50 (96%) | 45/50 (90%)
Adjusted rate | 98.0% | 99.2% | 98.1% | 91.1%
Terminal rate | 29/30 (97%) | 32/32 (100%) | 33/33 (100%) | 27/30 (90%)
First incidence (days) | 454 | 474 | 527 | 474
Poly-3 test | P = 0.019N* | P = 0.644 | P = 0.787 | P = 0.132N

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, clitoral gland, lung, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ A single incidence of carcinoma occurred in each of two animals that also had fibroadenoma.

^g^ A single incidence of carcinoma occurred in an animal that also had fibroadenoma.

Table B-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Untreated Female F344/N Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 0/50 | 0/50 | 0/50
Sodium dichromate dihydrate (October 2002) | 4/50 | 0/50 | 4/50
Total (%) | 4/100 (4.0%) | 0/100 | 4/100 (4.0%)
Mean ± standard deviation | 4.0% ± 5.7% | – | 4.0% ± 5.7%
Range | 0%–8% | – | 0%–8%
Overall Historical Incidence: All Routes
Total (%) | 25/1,200 (2.1%) | 3/1,200 (0.3%) | 27/1,200 (2.3%)
Mean ± standard deviation | 2.1% ± 2.9% | 0.3% ± 0.7% | 2.3% ± 2.9%
Range | 0%–8% | 0%–2% | 0%–8%

^a^ Data as of May 18, 2011.

Table B-4 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 15 | 13 | 14 | 15
Natural deaths | 5 | 5 | 3 | 5
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 29 | 32 | 33 | 30
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (46) | (45) | (47) | (45)
Inflammation, chronic active | 1 (2%) | – | – | –
Intestine large, colon | (47) | (48) | (50) | (49)
Inflammation, chronic active | – | 1 (2%) | – | –
Parasite metazoan | 3 (6%) | 2 (4%) | 2 (4%) | 1 (2%)
Intestine large, rectum | (47) | (48) | (50) | (49)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Parasite metazoan | 3 (6%) | 8 (17%) | 1 (2%) | 7 (14%)
Intestine small, duodenum | (50) | (47) | (50) | (50)
Intestine small, ileum | (47) | (46) | (49) | (50)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | –
Parasite metazoan | – | – | – | 1 (2%)
Intestine small, jejunum | (48) | (46) | (47) | (48)
Inflammation, chronic active | 1 (2%) | – | 2 (4%) | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | 3 (6%) | 1 (2%) | –
Atypia cellular | – | – | 1 (2%) | –
Basophilic focus | 37 (74%) | 41 (82%) | 46 (92%) | 45 (90%)
Clear cell focus | 10 (20%) | 12 (24%) | 12 (24%) | 10 (20%)
Congestion | 1 (2%) | 1 (2%) | – | 1 (2%)
Degeneration, cystic | 1 (2%) | – | – | –
Eosinophilic focus | 12 (24%) | 14 (28%) | 12 (24%) | 13 (26%)
Fatty change | 8 (16%) | 7 (14%) | 8 (16%) | 11 (22%)
Fatty change, focal | 2 (4%) | 13 (26%) | 7 (14%) | 8 (16%)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hepatodiaphragmatic nodule | 2 (4%) | 7 (14%) | 3 (6%) | 1 (2%)
Inflammation, chronic active | 2 (4%) | 4 (8%) | 3 (6%) | –
Mixed cell focus | 1 (2%) | 2 (4%) | 1 (2%) | 3 (6%)
Necrosis | 1 (2%) | – | 2 (4%) | –
Regeneration | 1 (2%) | – | – | –
Vacuolization cytoplasmic | 4 (8%) | 1 (2%) | 2 (4%) | –
Bile duct, hyperplasia | 10 (20%) | 2 (4%) | 9 (18%) | 7 (14%)
Serosa, fibrosis | – | – | 1 (2%) | 2 (4%)
Vein, dilatation | 1 (2%) | – | – | 1 (2%)
Vein, infiltration cellular, mixed cell | – | 1 (2%) | – | –
Mesentery | (4) | (7) | (7) | (8)
Fibrosis | – | – | – | 1 (13%)
Fat, necrosis | 4 (100%) | 6 (86%) | 6 (86%) | 7 (88%)
Oral mucosa | (0) | (0) | (1) | (2)
Gingival, foreign body | – | – | 1 (100%) | 1 (50%)
Gingival, inflammation, chronic active | – | – | 1 (100%) | –
Pancreas | (50) | (50) | (49) | (50)
Atrophy | – | – | 1 (2%) | 1 (2%)
Basophilic focus | 1 (2%) | – | 2 (4%) | –
Cyst | 1 (2%) | 2 (4%) | – | –
Infiltration cellular | 2 (4%) | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | 1 (2%) | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Edema | – | – | 1 (2%) | –
Fibrosis | 4 (8%) | 1 (2%) | 4 (8%) | 1 (2%)
Hyperplasia, basal cell, focal | – | – | 1 (2%) | –
Hyperplasia, squamous | 7 (14%) | 5 (10%) | 6 (12%) | 7 (14%)
Inflammation | 1 (2%) | – | 1 (2%) | –
Ulcer | 1 (2%) | 2 (4%) | 3 (6%) | –
Stomach, glandular | (50) | (50) | (49) | (50)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Mineralization | – | – | – | 2 (4%)
Ulcer | 1 (2%) | – | – | –
Tongue | (0) | (0) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, mineralization | – | – | – | 1 (2%)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 48 (96%) | 50 (100%) | 50 (100%) | 49 (98%)
Mineralization | – | – | – | 2 (4%)
Artery, infiltration cellular, mononuclear cell | 1 (2%) | – | – | –
Atrium, thrombosis | 1 (2%) | 1 (2%) | – | –
Endocardium, hyperplasia | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 1 (2%) | 1 (2%) | – | 1 (2%)
Amyloid deposition | – | 1 (2%) | – | –
Hyperplasia | 26 (52%) | 25 (50%) | 34 (68%) | 22 (44%)
Necrosis | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Vacuolization cytoplasmic | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Adrenal medulla | (50) | (50) | (50) | (50)
Hyperplasia | 5 (10%) | 3 (6%) | 1 (2%) | 3 (6%)
Islets, pancreatic | (50) | (49) | (50) | (50)
Hyperplasia | – | – | – | 1 (2%)
Parathyroid gland | (47) | (49) | (48) | (48)
Hyperplasia | – | – | – | 1 (2%)
Pituitary gland | (50) | (49) | (49) | (50)
Angiectasis | – | 1 (2%) | – | –
Cyst | – | – | 1 (2%) | –
Pars distalis, cyst | 1 (2%) | 1 (2%) | – | 1 (2%)
Pars distalis, hyperplasia | 19 (38%) | 19 (39%) | 20 (41%) | 20 (40%)
Pars intermedia, hyperplasia | 1 (2%) | – | – | –
Thyroid gland | (50) | (48) | (50) | (50)
Mineralization | – | – | – | 1 (2%)
C-cell, hyperplasia | 8 (16%) | 6 (13%) | 5 (10%) | 7 (14%)
Follicle, cyst | – | 1 (2%) | 1 (2%) | –
General Body System
Peritoneum | (0) | (1) | (0) | (0)
Genital System
Clitoral gland | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Fibrosis | 1 (2%) | – | 1 (2%) | 1 (2%)
Hyperplasia | 2 (4%) | 4 (8%) | 3 (6%) | 4 (8%)
Inflammation | 9 (18%) | 5 (10%) | 6 (12%) | 6 (12%)
Duct, dilatation | – | 1 (2%) | – | –
Ovary | (50) | (50) | (50) | (50)
Atrophy | – | 1 (2%) | – | 1 (2%)
Cyst | 4 (8%) | 3 (6%) | – | 3 (6%)
Uterus | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Cervix, cyst | 4 (8%) | 2 (4%) | 3 (6%) | 3 (6%)
Endometrium, hyperplasia, cystic | 1 (2%) | 8 (16%) | 7 (14%) | 8 (16%)
Vagina | (1) | (1) | (0) | (2)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Fibrosis | – | 1 (2%) | – | –
Lymph node | (5) | (7) | (5) | (2)
Deep cervical, ectasia | – | – | 1 (20%) | –
Deep cervical, hemorrhage | – | 1 (14%) | – | –
Deep cervical, infiltration cellular, histiocyte | – | – | 1 (20%) | –
Mediastinal, ectasia | – | 1 (14%) | – | –
Mediastinal, hemorrhage | – | 1 (14%) | – | 1 (50%)
Mediastinal, hyperplasia | – | 1 (14%) | – | –
Mediastinal, infiltration cellular, histiocyte | – | – | – | 1 (50%)
Mediastinal, infiltration cellular, mixed cell | – | – | 1 (20%) | –
Pancreatic, ectasia | 1 (20%) | – | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Ectasia | – | – | 1 (2%) | –
Infiltration cellular, mast cell | – | – | 1 (2%) | –
Infiltration cellular, mononuclear cell | – | – | 1 (2%) | –
Infiltration cellular, plasma cell | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Atrophy | – | – | 1 (2%) | 2 (4%)
Degeneration, cystic, focal | – | – | 1 (2%) | –
Hyperplasia, lymphoid | 4 (8%) | 2 (4%) | 1 (2%) | –
Necrosis | – | 1 (2%) | – | 1 (2%)
Thymus | (49) | (50) | (50) | (47)
Cyst | 1 (2%) | – | – | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 12 (24%) | 8 (16%) | 3 (6%) | 4 (8%)
Hyperplasia | 4 (8%) | 4 (8%) | 6 (12%) | 4 (8%)
Inflammation | 1 (2%) | – | – | –
Skin | (50) | (50) | (50) | (50)
Fibrosis | 1 (2%) | – | 1 (2%) | –
Hyperplasia, squamous | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Ulcer | – | 2 (4%) | 2 (4%) | 1 (2%)
Lip, inflammation, suppurative | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Hyperostosis | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Skeletal muscle | (0) | (1) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 13 (26%) | 7 (14%) | 7 (14%) | 9 (18%)
Hemorrhage | – | 2 (4%) | – | 1 (2%)
Inflammation, chronic active | – | 1 (2%) | – | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Foreign body | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | 1 (2%) | –
Inflammation, granulomatous | 1 (2%) | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | –
Metaplasia, squamous | 1 (2%) | – | – | –
Pigmentation | 1 (2%) | – | – | –
Thrombosis | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 7 (14%) | 14 (28%) | 14 (28%) | 11 (22%)
Alveolar epithelium, metaplasia, squamous | – | 3 (6%) | 1 (2%) | 1 (2%)
Bronchiole, inflammation, suppurative | – | – | 1 (2%) | –
Bronchiole, inflammation, chronic active | – | – | 2 (4%) | –
Serosa, fibrosis | – | 1 (2%) | – | 2 (4%)
Serosa, inflammation, granulomatous | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (50)
Foreign body | 2 (4%) | 3 (6%) | 3 (6%) | 2 (4%)
Inflammation | 3 (6%) | 5 (10%) | 4 (8%) | 3 (6%)
Glands, hyperplasia | – | 1 (2%) | – | –
Nasolacrimal duct, foreign body | 1 (2%) | – | – | –
Nasolacrimal duct, inflammation | 2 (4%) | – | – | –
Olfactory epithelium, atrophy | – | 1 (2%) | – | –
Olfactory epithelium, metaplasia | – | 1 (2%) | – | –
Respiratory epithelium, hyperplasia | 3 (6%) | 1 (2%) | 1 (2%) | 2 (4%)
Turbinate, cyst | – | – | – | 2 (4%)
Trachea | (50) | (50) | (50) | (50)
Infiltration cellular, mixed cell | – | 1 (2%) | – | –
Special Senses System
Eye | (50) | (48) | (48) | (50)
Atrophy | 1 (2%) | – | – | –
Cataract | 8 (16%) | 13 (27%) | 14 (29%) | 10 (20%)
Anterior chamber, inflammation, suppurative | – | 1 (2%) | – | 1 (2%)
Cornea, edema | – | – | 1 (2%) | –
Cornea, hyperplasia | – | 1 (2%) | – | –
Cornea, inflammation, chronic active | 2 (4%) | – | 1 (2%) | –
Retina, degeneration | 1 (2%) | 2 (4%) | 4 (8%) | 3 (6%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | – | – | 2 (4%) | 1 (2%)
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic active | 2 (4%) | 1 (2%) | – | –
Zymbal’s gland | (0) | (0) | (2) | (1)
Urinary System
Kidney | (49) | (50) | (50) | (50)
Cyst | – | – | 2 (4%) | –
Degeneration, fatty | 1 (2%) | – | – | –
Dilatation | – | – | – | 1 (2%)
Fibrosis | 8 (16%) | 7 (14%) | 8 (16%) | 10 (20%)
Infarct | 7 (14%) | 8 (16%) | 4 (8%) | 5 (10%)
Mineralization | – | – | – | 2 (4%)
Nephropathy | 47 (96%) | 50 (100%) | 48 (96%) | 50 (100%)
Papilla, hemorrhage | 1 (2%) | – | 5 (10%) | 1 (2%)
Pelvis, inflammation, chronic active | 8 (16%) | 9 (18%) | 8 (16%) | 10 (20%)
Pelvis, metaplasia, squamous | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Infiltration cellular, chronic active | – | – | 1 (2%) | –
Transitional epithelium, hyperplasia | – | – | 1 (2%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.