# Appendix A Summary of Lesions in Male Rats in the Two-year Drinking Water Study of β-Picoline

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 9 | 12 | 15 | 23
Natural deaths | 8 | 7 | 3 | 3
Survivors
Terminal kill | 33 | 31 | 32 | 24
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (45) | (47) | (48) | (48)
Intestine large, colon | (47) | (49) | (49) | (49)
Adenoma | 1 (2%) | – | – | –
Intestine large, rectum | (47) | (49) | (49) | (50)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Intestine small, duodenum | (48) | (49) | (49) | (50)
Intestine small, ileum | (46) | (47) | (48) | (49)
Intestine small, jejunum | (45) | (47) | (48) | (49)
Leiomyoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Carcinoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Hepatocellular adenoma | 2 (4%) | 1 (2%) | – | 2 (4%)
Hepatocellular adenoma, multiple | 1 (2%) | – | – | –
Hepatocellular carcinoma | – | – | 1 (2%) | –
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Mesentery | (4) | (8) | (4) | (6)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (17%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (13%) | – | –
Pancreas | (49) | (50) | (50) | (48)
Adenoma, mixed cell | 1 (2%) | 1 (2%) | – | –
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Acinus, adenoma | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | – | 1 (2%) | 1 (2%) | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (0) | (0) | (2) | (1)
Squamous cell carcinoma | – | – | 1 (50%) | 1 (100%)
Squamous cell papilloma | – | – | 1 (50%) | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Carcinoma, metastatic, salivary glands | – | – | – | 1 (2%)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | 1 (2%) | 1 (2%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Adrenal medulla | (50) | (49) | (49) | (50)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Pheochromocytoma benign | 4 (8%) | 5 (10%) | 6 (12%) | 5 (10%)
Pheochromocytoma complex | 1 (2%) | – | – | –
Pheochromocytoma malignant | – | – | 2 (4%) | –
Bilateral, pheochromocytoma benign | 1 (2%) | – | – | –
Bilateral, pheochromocytoma malignant | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 4 (8%) | 1 (2%) | 3 (6%) | 2 (4%)
Parathyroid gland | (50) | (47) | (48) | (48)
Pituitary gland | (50) | (49) | (50) | (49)
Pars distalis, adenoma | 28 (56%) | 35 (71%) | 28 (56%) | 36 (73%)
Pars intermedia, adenoma | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, adenoma | 12 (24%) | 10 (20%) | 4 (8%) | 8 (16%)
C-cell, carcinoma | 1 (2%) | 3 (6%) | 1 (2%) | –
Follicular cell, adenoma | – | – | 1 (2%) | –
Follicular cell, carcinoma | 1 (2%) | 1 (2%) | – | –
General Body System
Peritoneum | (2) | (1) | (1) | (2)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (100%) | – | –
Genital System
Epididymis | (50) | (50) | (50) | (50)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Preputial gland | (50) | (50) | (50) | (50)
Adenoma | – | 1 (2%) | 2 (4%) | –
Carcinoma | 2 (4%) | 1 (2%) | 2 (4%) | –
Prostate | (49) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Seminal vesicle | (50) | (50) | (50) | (50)
Testes | (50) | (50) | (50) | (50)
Bilateral, interstitial cell, adenoma | 22 (44%) | 20 (40%) | 26 (52%) | 24 (48%)
Interstitial cell, adenoma | 13 (26%) | 18 (36%) | 16 (32%) | 18 (36%)
Tunic, leiomyosarcoma | – | – | 1 (2%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (9) | (11) | (11) | (8)
Deep cervical, carcinoma, metastatic, harderian gland | 1 (11%) | – | – | –
Iliac, chordoma, metastatic, uncertain primary site | – | – | – | 1 (13%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Carcinoma, metastatic, uncertain primary site | – | – | 1 (2%) | –
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Thymus | (49) | (49) | (45) | (50)
Alveolar/bronchiolar carcinoma, metastatic, lung | – | – | – | 1 (2%)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Carcinoma | – | 1 (2%) | – | –
Fibroadenoma | 1 (2%) | 1 (2%) | 2 (4%) | –
Skin | (50) | (50) | (50) | (50)
Basal cell adenoma | 1 (2%) | 2 (4%) | 2 (4%) | –
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Keratoacanthoma | 5 (10%) | 5 (10%) | 7 (14%) | 5 (10%)
Squamous cell carcinoma | – | 1 (2%) | – | –
Squamous cell papilloma | – | – | 1 (2%) | –
Subcutaneous tissue, fibroma | 3 (6%) | 4 (8%) | 2 (4%) | 5 (10%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | – | – | –
Subcutaneous tissue, hemangioma | – | 1 (2%) | – | –
Subcutaneous tissue, lipoma | – | – | 2 (4%) | –
Subcutaneous tissue, sarcoma | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Sarcoma | – | – | 1 (2%) | –
Skeletal muscle | (0) | (0) | (0) | (1)
Fibrous histiocytoma | – | – | – | 1 (100%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 5 (10%) | 1 (2%) | 2 (4%)
Alveolar/bronchiolar carcinoma | – | – | 3 (6%) | 2 (4%)
Alveolar/bronchiolar carcinoma, multiple | – | – | 1 (2%) | –
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Carcinoma, metastatic, preputial gland | 1 (2%) | – | – | –
Carcinoma, metastatic, thyroid gland | – | 1 (2%) | 1 (2%) | –
Carcinoma, metastatic, Zymbal’s gland | – | – | 1 (2%) | –
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | – | – | 1 (2%) | –
Rhabdomyosarcoma, metastatic, uncertain primary site | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Respiratory epithelium, adenoma | – | 1 (2%) | – | –
Trachea | (49) | (50) | (50) | (50)
Special Senses System
Ear | (2) | (0) | (0) | (0)
Neural crest tumor | 1 (50%) | – | – | –
Eye | (50) | (50) | (50) | (50)
Carcinoma, metastatic, harderian gland | 1 (2%) | – | – | –
Harderian gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Zymbal’s gland | (1) | (0) | (1) | (1)
Adenoma | – | – | – | 1 (100%)
Carcinoma | 1 (100%) | – | 1 (100%) | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Hemangiosarcoma | – | 1 (2%) | – | –
Capsule, osteosarcoma, metastatic, uncertain primary site | – | 1 (2%) | – | –
Renal tubule, adenoma | – | 1 (2%) | – | 1 (2%)
Renal tubule, adenoma, multiple | – | – | 1 (2%) | –
Urinary bladder | (50) | (50) | (50) | (50)
Fibrous histiocytoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Leiomyoma | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Leukemia mononuclear | 14 (28%) | 19 (38%) | 16 (32%) | 14 (28%)
Lymphoma malignant | – | – | 1 (2%) | –
Mesothelioma malignant | 4 (8%) | 2 (4%) | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 48 | 50 | 50 | 50
Total primary neoplasms | 130 | 142 | 144 | 132
Total animals with benign neoplasms | 45 | 48 | 49 | 50
Total benign neoplasms | 103 | 113 | 110 | 113
Total animals with malignant neoplasms | 22 | 25 | 30 | 19
Total malignant neoplasms | 26 | 29 | 34 | 19
Total animals with metastatic neoplasms | 3 | 2 | 5 | 4
Total metastatic neoplasms | 9 | 12 | 5 | 15
Total animals with malignant neoplasms of uncertain primary site | 1 | 1 | 2 | 1
Total animals with neoplasms uncertain- benign or malignant | 1 | – | – | –
Total uncertain neoplasms | 1 | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Drinking Water Study of β-Picoline

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 5/50 (10%) | 5/49 (10%) | 6/49 (12%) | 5/50 (10%)
Adjusted rate^b^ | 11.8% | 11.3% | 13.5% | 11.6%
Terminal rate^c^ | 5/33 (15%) | 5/31 (16%) | 5/31 (16%) | 3/24 (13%)
First incidence (days) | 726 (T) | 726 (T) | 657 | 586
Poly-3 test^d^ | P = 0.545 | P = 0.603N | P = 0.530 | P = 0.625N
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 0/50 (0%) | 0/49 (0%) | 3/49 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 0.0% | 6.8% | 0.0%
Terminal rate | 0/33 (0%) | 0/31 (0%) | 1/31 (3%) | 0/24 (0%)
First incidence (days) | –^e^ | – | 646 | –
Poly-3 test | P = 0.520 | –^f^ | P = 0.127 | –
Adrenal Medulla: Benign, Complex, or Malignant Pheochromocytoma
Overall rate | 6/50 (12%) | 5/49 (10%) | 9/49 (18%) | 5/50 (10%)
Adjusted rate | 14.0% | 11.3% | 20.1% | 11.6%
Terminal rate | 5/33 (15%) | 5/31 (16%) | 6/31 (19%) | 3/24 (13%)
First incidence (days) | 600 | 726 (T) | 646 | 586
Poly-3 test | P = 0.525N | P = 0.476N | P = 0.315 | P = 0.500N
Liver: Hepatocellular Adenoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate | 7.1% | 2.2% | 0.0% | 4.7%
Terminal rate | 3/33 (9%) | 0/31 (0%) | 0/32 (0%) | 1/24 (4%)
First incidence (days) | 726 (T) | 717 | – | 720
Poly-3 test | P = 0.450N | P = 0.282N | P = 0.108N | P = 0.502N
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 7.1% | 2.2% | 2.2% | 4.7%
Terminal rate | 3/33 (9%) | 0/31 (0%) | 1/32 (3%) | 1/24 (4%)
First incidence (days) | 726 (T) | 717 | 726 (T) | 720
Poly-3 test | P = 0.483N | P = 0.282N | P = 0.284N | P = 0.502N
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 7.0% | 11.0% | 2.2% | 4.7%
Terminal rate | 2/33 (6%) | 5/31 (16%) | 1/32 (3%) | 1/24 (4%)
First incidence (days) | 600 | 726 (T) | 726 (T) | 628
Poly-3 test | P = 0.247N | P = 0.387 | P = 0.288N | P = 0.503N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate | 0.0% | 0.0% | 8.8% | 4.7%
Terminal rate | 0/33 (0%) | 0/31 (0%) | 3/32 (9%) | 1/24 (4%)
First incidence (days) | – | – | 615 | 607
Poly-3 test | P = 0.095 | – | P = 0.069 | P = 0.238
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 5/50 (10%) | 5/50 (10%) | 4/50 (8%)
Adjusted rate | 7.0% | 11.0% | 11.0% | 9.3%
Terminal rate | 2/33 (6%) | 5/31 (16%) | 4/32 (13%) | 2/24 (8%)
First incidence (days) | 600 | 726 (T) | 615 | 607
Poly-3 test | P = 0.478 | P = 0.387 | P = 0.389 | P = 0.501
Mammary Gland: Fibroadenoma or Adenoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.4% | 2.2% | 6.7% | 0.0%
Terminal rate | 1/33 (3%) | 0/31 (0%) | 3/32 (9%) | 0/24 (0%)
First incidence (days) | 726 (T) | 684 | 726 (T) | –
Poly-3 test | P = 0.422N | P = 0.745N | P = 0.327 | P = 0.501N
Mammary Gland: Fibroadenoma, Adenoma, or Carcinoma
Overall rate | 1/50 (2%) | 2/50 (4%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.4% | 4.4% | 6.7% | 0.0%
Terminal rate | 1/33 (3%) | 1/31 (3%) | 3/32 (9%) | 0/24 (0%)
First incidence (days) | 726 (T) | 684 | 726 (T) | –
Poly-3 test | P = 0.345N | P = 0.524 | P = 0.327 | P = 0.501N
Pancreatic Islets: Adenoma
Overall rate | 4/50 (8%) | 1/50 (2%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 9.4% | 2.2% | 6.6% | 4.7%
Terminal rate | 4/33 (12%) | 0/31 (0%) | 2/32 (6%) | 1/24 (4%)
First incidence (days) | 726 (T) | 567 | 615 | 691
Poly-3 test | P = 0.388N | P = 0.156N | P = 0.463N | P = 0.337N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 28/50 (56%) | 35/49 (71%) | 28/50 (56%) | 36/49 (73%)
Adjusted rate | 61.4% | 73.7% | 59.6% | 79.5%
Terminal rate | 19/33 (58%) | 25/31 (81%) | 19/32 (59%) | 18/23 (78%)
First incidence (days) | 499 | 498 | 615 | 499
Poly-3 test | P = 0.078 | P = 0.144 | P = 0.513N | P = 0.041
Preputial Gland: Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 4.6% | 4.4% | 8.8% | 0.0%
Terminal rate | 0/33 (0%) | 2/31 (7%) | 3/32 (9%) | 0/24 (0%)
First incidence (days) | 600 | 726 (T) | 692 | –
Poly-3 test | P = 0.246N | P = 0.676N | P = 0.360 | P = 0.241N
Skin: Keratoacanthoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 11.7% | 10.9% | 15.4% | 11.7%
Terminal rate | 4/33 (12%) | 4/31 (13%) | 4/32 (13%) | 3/24 (13%)
First incidence (days) | 683 | 544 | 646 | 664
Poly-3 test | P = 0.512 | P = 0.583N | P = 0.424 | P = 0.631
Skin: Squamous Cell Papilloma or Keratoacanthoma
Overall rate | 5/50 (10%) | 5/50 (10%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 11.7% | 10.9% | 15.4% | 11.7%
Terminal rate | 4/33 (12%) | 4/31 (13%) | 4/32 (13%) | 3/24 (13%)
First incidence (days) | 683 | 544 | 646 | 664
Poly-3 test | P = 0.512 | P = 0.583N | P = 0.424 | P = 0.631
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Squamous Cell Carcinoma
Overall rate | 5/50 (10%) | 6/50 (12%) | 7/50 (14%) | 5/50 (10%)
Adjusted rate | 11.7% | 13.1% | 15.4% | 11.7%
Terminal rate | 4/33 (12%) | 5/31 (16%) | 4/32 (13%) | 3/24 (13%)
First incidence (days) | 683 | 544 | 646 | 664
Poly-3 test | P = 0.559 | P = 0.552 | P = 0.424 | P = 0.631
Skin: Squamous Cell Papilloma, Keratoacanthoma, Basal Cell Adenoma, or Squamous Cell Carcinoma
Overall rate | 6/50 (12%) | 8/50 (16%) | 9/50 (18%) | 5/50 (10%)
Adjusted rate | 13.9% | 17.4% | 19.8% | 11.7%
Terminal rate | 4/33 (12%) | 6/31 (19%) | 6/32 (19%) | 3/24 (13%)
First incidence (days) | 600 | 544 | 646 | 664
Poly-3 test | P = 0.414N | P = 0.439 | P = 0.325 | P = 0.508N
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 3/50 (6%) | 4/50 (8%) | 2/50 (4%) | 5/50 (10%)
Adjusted rate | 6.9% | 8.8% | 4.4% | 11.7%
Terminal rate | 2/33 (6%) | 3/31 (10%) | 0/32 (0%) | 4/24 (17%)
First incidence (days) | 391 | 684 | 646 | 618
Poly-3 test | P = 0.309 | P = 0.527 | P = 0.478N | P = 0.347
Skin (Subcutaneous Tissue): Fibroma, Fibrosarcoma, or Sarcoma
Overall rate | 4/50 (8%) | 4/50 (8%) | 3/50 (6%) | 5/50 (10%)
Adjusted rate | 9.2% | 8.8% | 6.6% | 11.7%
Terminal rate | 3/33 (9%) | 3/31 (10%) | 1/32 (3%) | 4/24 (17%)
First incidence (days) | 391 | 684 | 646 | 618
Poly-3 test | P = 0.415 | P = 0.616N | P = 0.474N | P = 0.490
Testes: Adenoma
Overall rate | 35/50 (70%) | 38/50 (76%) | 42/50 (84%) | 42/50 (84%)
Adjusted rate | 77.7% | 79.5% | 87.5% | 87.5%
Terminal rate | 27/33 (82%) | 25/31 (81%) | 31/32 (97%) | 23/24 (96%)
First incidence (days) | 504 | 589 | 569 | 543
Poly-3 test | P = 0.088 | P = 0.519 | P = 0.152 | P = 0.150
Thyroid Gland (C-Cell): Adenoma
Overall rate | 12/50 (24%) | 10/50 (20%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate | 28% | 21.7% | 8.8% | 18.7%
Terminal rate | 10/33 (30%) | 7/31 (23%) | 3/32 (9%) | 6/24 (25%)
First incidence (days) | 676 | 638 | 681 | 568
Poly-3 test | P = 0.141N | P = 0.328N | P = 0.018N | P = 0.220N
Thyroid Gland: (C-Cell): Carcinoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 2.4% | 6.5% | 2.2% | 0.0%
Terminal rate | 0/33 (0%) | 2/31 (7%) | 1/32 (3%) | 0/24 (0%)
First incidence (days) | 713 | 567 | 726 (T) | –
Poly-3 test | P = 0.197N | P = 0.333 | P = 0.748N | P = 0.501N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 13/50 (26%) | 12/50 (24%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate | 30.3% | 25.7% | 11.0% | 18.7%
Terminal rate | 10/33 (30%) | 8/31 (26%) | 4/32 (13%) | 6/24 (25%)
First incidence (days) | 676 | 567 | 681 | 568
Poly-3 test | P = 0.081N | P = 0.402N | P = 0.022N | P = 0.156N
All Organs: Mononuclear Leukemia
Overall rate | 14/50 (28%) | 19/50 (38%) | 16/50 (32%) | 14/50 (28%)
Adjusted rate | 31.4% | 39.3% | 33.7% | 30.5%
Terminal rate | 9/33 (27%) | 8/31 (26%) | 8/32 (25%) | 4/24 (17%)
First incidence (days) | 467 | 544 | 569 | 499
Poly-3 test | P = 0.388N | P = 0.280 | P = 0.492 | P = 0.554N
All Organs: Malignant Mesothelioma
Overall rate | 4/50 (8%) | 2/50 (4%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 9.0% | 4.4% | 2.2% | 0.0%
Terminal rate | 0/33 (0%) | 1/31 (3%) | 1/32 (3%) | 0/24 (0%)
First incidence (days) | 273 | 693 | 726 (T) | –
Poly-3 test | P = 0.031N | P = 0.325N | P = 0.173N | P = 0.066N
All Organs: Benign Tumors
Overall rate | 45/50 (90%) | 48/50 (96%) | 49/50 (98%) | 50/50 (100%)
Adjusted rate | 95.5% | 96.1% | 99.7% | 100.0%
Terminal rate | 32/33 (97%) | 30/31 (97%) | 32/32 (100%) | 24/24 (100%)
First incidence (days) | 391 | 498 | 569 | 499
Poly-3 test | P = 0.066 | P = 0.648 | P = 0.218 | P = 0.179
All Organs: Malignant Tumors
Overall rate | 23/50 (46%) | 26/50 (52%) | 30/50 (60%) | 19/50 (38%)
Adjusted rate | 49.3% | 53.5% | 60.9% | 40.1%
Terminal rate | 13/33 (39%) | 13/31 (42%) | 17/32 (53%) | 5/24 (21%)
First incidence (days) | 273 | 544 | 393 | 499
Poly-3 test | P = 0.187N | P = 0.420 | P = 0.173 | P = 0.243N
All Organs: Benign or Malignant Tumors
Overall rate | 48/50 (96%) | 50/50 (100%) | 50/50 (100%) | 50/50 (100%)
Adjusted rate | 98.0% | 100.0% | 100.0% | 100.0%
Terminal rate | 32/33 (97%) | 31/31 (100%) | 32/32 (100%) | 24/24 (100%)
First incidence (days) | 273 | 498 | 393 | 499
Poly-3 test | P = 0.309 | P = 0.496 | P = 0.496 | P = 0.496

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, liver, lung, pancreatic islets, pituitary gland, preputial gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the controls and that exposed group. The Poly-3 test accounts for the differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Alveolar/bronchiolar Neoplasms in Untreated Male F344/N Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Drinking Water Studies
β-Picoline (November 2004) | 3/50 | 0/50 | 3/50
Sodium dichromate dihydrate (October 2002) | 4/50 | 0/50 | 4/50
Total (%) | 7/100 (7.0%) | 0/100 | 7/100 (7.0%)
Mean ± standard deviation | 7.0% ± 1.4% | – | 7.0% ± 1.4%
Range | 6%–8% | – | 6%–8%
Overall Historical Incidence: All Routes
Total (%) | 31/1,249 (2.5%) | 15/1,249 (1.2%) | 45/1,249 (3.6%)
Mean ± standard deviation | 2.5% ± 2.6% | 1.2% ± 1.4% | 3.6% ± 2.8%
Range | 0%–8% | 0%–6% | 0%–10%

^a^ Data as of May 18, 2011.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Drinking Water Study of β-Picoline^a^

| 0 mg/L | 156.25 mg/L | 312.5 mg/L | 625 mg/L
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Moribund | 9 | 12 | 15 | 23
Natural deaths | 8 | 7 | 3 | 3
Survivors
Terminal kill | 33 | 31 | 32 | 24
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Hyperplasia, squamous | – | 1 (2%) | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Intestine large, cecum | (45) | (47) | (48) | (48)
Inflammation, chronic active | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Intestine large, colon | (47) | (49) | (49) | (49)
Parasite metazoan | 3 (6%) | 4 (8%) | 7 (14%) | 1 (2%)
Intestine large, rectum | (47) | (49) | (49) | (50)
Infiltration cellular, mixed cell | – | 1 (2%) | – | –
Parasite metazoan | 2 (4%) | 5 (10%) | 3 (6%) | 5 (10%)
Intestine small, duodenum | (48) | (49) | (49) | (50)
Intestine small, ileum | (46) | (47) | (48) | (49)
Inflammation, chronic active | – | 1 (2%) | – | –
Intestine small, jejunum | (45) | (47) | (48) | (49)
Inflammation, chronic active | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | 1 (2%) | –
Atrophy | – | – | 1 (2%) | –
Basophilic focus | 15 (30%) | 14 (28%) | 16 (32%) | 10 (20%)
Clear cell focus | 13 (26%) | 23 (46%) | 20 (40%) | 15 (30%)
Congestion | – | – | – | 1 (2%)
Degeneration, cystic | 3 (6%) | 6 (12%) | 7 (14%) | 2 (4%)
Eosinophilic focus | 7 (14%) | 1 (2%) | 2 (4%) | 5 (10%)
Fatty change | 7 (14%) | 6 (12%) | 7 (14%) | 9 (18%)
Fibrosis | – | – | 1 (2%) | –
Hepatodiaphragmatic nodule | 4 (8%) | 3 (6%) | 2 (4%) | 6 (12%)
Inflammation, chronic active | – | 3 (6%) | 3 (6%) | 1 (2%)
Mixed cell focus | 6 (12%) | 3 (6%) | 6 (12%) | 3 (6%)
Necrosis | 2 (4%) | 3 (6%) | – | 2 (4%)
Vacuolization cytoplasmic | 15 (30%) | 12 (24%) | 12 (24%) | 16 (32%)
Bile duct, hyperplasia | 40 (80%) | 36 (72%) | 44 (88%) | 42 (84%)
Centrilobular, atrophy | – | 1 (2%) | – | –
Centrilobular, necrosis | 1 (2%) | – | 1 (2%) | –
Periportal, fibrosis | – | 1 (2%) | – | –
Periportal, inflammation | 1 (2%) | – | 1 (2%) | –
Vein, dilatation | – | 1 (2%) | – | –
Mesentery | (4) | (8) | (4) | (6)
Fat, necrosis | 1 (25%) | 6 (75%) | 3 (75%) | 5 (83%)
Pancreas | (49) | (50) | (50) | (48)
Cyst | 1 (2%) | – | 2 (4%) | –
Hyperplasia | 2 (4%) | – | – | 1 (2%)
Infiltration cellular | – | 1 (2%) | 1 (2%) | –
Lipomatosis | – | – | – | 1 (2%)
Acinus, atrophy | 18 (37%) | 31 (62%) | 31 (62%) | 25 (52%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Infiltration cellular | – | 1 (2%) | – | –
Duct, inflammation | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Edema | – | – | 1 (2%) | –
Erosion | 1 (2%) | – | – | –
Fibrosis | 1 (2%) | 6 (12%) | 2 (4%) | 1 (2%)
Hyperplasia, squamous | 15 (30%) | 18 (36%) | 7 (14%) | 17 (34%)
Inflammation | – | 1 (2%) | – | 2 (4%)
Ulcer | 2 (4%) | 5 (10%) | 2 (4%) | 2 (4%)
Stomach, glandular | (50) | (50) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Erosion | 1 (2%) | 3 (6%) | – | –
Fibrosis | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | – | – | –
Inflammation, chronic active | 4 (8%) | 6 (12%) | 4 (8%) | 3 (6%)
Metaplasia, squamous | – | 1 (2%) | – | –
Ulcer | – | – | – | 2 (4%)
Tongue | (0) | (0) | (2) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (50)
Aorta, mineralization | – | 1 (2%) | – | –
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 49 (98%) | 50 (100%) | 50 (100%) | 49 (98%)
Mineralization | – | 1 (2%) | – | –
Atrium, thrombosis | 5 (10%) | 5 (10%) | – | –
Epicardium, inflammation, chronic active | – | – | – | 1 (2%)
Valve, inflammation, chronic active | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | 2 (4%) | – | – | 2 (4%)
Hyperplasia | 20 (40%) | 31 (62%) | 27 (54%) | 21 (42%)
Necrosis | 1 (2%) | – | 1 (2%) | –
Vacuolization cytoplasmic | 3 (6%) | – | – | 1 (2%)
Adrenal medulla | (50) | (49) | (49) | (50)
Hyperplasia | 12 (24%) | 18 (37%) | 13 (27%) | 7 (14%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Parathyroid gland | (50) | (47) | (48) | (48)
Hyperplasia | 1 (2%) | – | – | –
Pituitary gland | (50) | (49) | (50) | (49)
Cyst | 2 (4%) | – | 2 (4%) | –
Metaplasia, osseous | 1 (2%) | – | – | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Pars distalis, hyperplasia | 16 (32%) | 11 (22%) | 19 (38%) | 12 (24%)
Pars intermedia, hyperplasia | – | – | 1 (2%) | –
Pars nervosa, hyperplasia | – | – | 1 (2%) | –
Thyroid gland | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
C-cell, hyperplasia | 6 (12%) | 4 (8%) | 11 (22%) | 7 (14%)
Follicle, cyst | – | 1 (2%) | – | 1 (2%)
Follicular cell, hyperplasia | – | 1 (2%) | 1 (2%) | –
General Body System
Peritoneum | (2) | (1) | (1) | (2)
Inflammation, chronic active | – | – | – | 1 (50%)
Genital System
Epididymis | (50) | (50) | (50) | (50)
Degeneration, fatty | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 2 (4%) | 2 (4%)
Preputial gland | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | 1 (2%) | –
Hyperplasia, squamous | – | 1 (2%) | – | –
Inflammation | 15 (30%) | 10 (20%) | 10 (20%) | 13 (26%)
Prostate | (49) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Hyperplasia, adenomatous | 1 (2%) | – | – | 1 (2%)
Inflammation | 31 (63%) | 45 (90%) | 45 (90%) | 35 (70%)
Seminal vesicle | (50) | (50) | (50) | (50)
Dilatation | – | 1 (2%) | – | –
Inflammation | – | – | 2 (4%) | 1 (2%)
Testes | (50) | (50) | (50) | (50)
Atrophy | 3 (6%) | 9 (18%) | 5 (10%) | 3 (6%)
Inflammation, chronic active | 1 (2%) | – | – | –
Interstitial cell, hyperplasia | 12 (24%) | 18 (36%) | 17 (34%) | 13 (26%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (9) | (11) | (11) | (8)
Congestion | 1 (11%) | – | – | –
Hyperplasia, lymphoid | 1 (11%) | – | – | –
Deep cervical, ectasia | – | – | – | 1 (13%)
Deep cervical, hemorrhage | – | 1 (9%) | – | –
Deep cervical, infiltration cellular | – | – | – | 1 (13%)
Mediastinal, congestion | 1 (11%) | – | – | –
Mediastinal, ectasia | 1 (11%) | 1 (9%) | 4 (36%) | 3 (38%)
Mediastinal, hemorrhage | – | – | 1 (9%) | –
Mediastinal, hyperplasia | 1 (11%) | 1 (9%) | 1 (9%) | –
Mediastinal, infiltration cellular, mixed cell | – | 1 (9%) | – | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | –
Ectasia | – | 2 (4%) | 2 (4%) | –
Inflammation, granulomatous | – | – | 1 (2%) | –
Spleen | (50) | (50) | (50) | (50)
Hematopoietic cell proliferation | 1 (2%) | – | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Inflammation, granulomatous | – | – | 1 (2%) | –
Necrosis | – | – | – | 1 (2%)
Capsule, hemorrhage | – | – | 1 (2%) | –
Capsule, hyperplasia | – | – | – | 1 (2%)
Lymphoid follicle, depletion cellular | – | 1 (2%) | – | –
Lymphoid follicle, hyperplasia | 1 (2%) | – | – | –
Thymus | (49) | (49) | (45) | (50)
Integumentary System
Mammary gland | (50) | (49) | (50) | (50)
Galactocele | 12 (24%) | 7 (14%) | 9 (18%) | 12 (24%)
Hyperplasia | 3 (6%) | 6 (12%) | – | 5 (10%)
Inflammation | – | 1 (2%) | – | –
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | – | – | –
Hyperplasia, squamous | 2 (4%) | – | – | –
Inflammation, suppurative | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, infiltration cellular, mixed cell | – | 1 (2%) | – | –
Subcutaneous tissue, inflammation, chronic active | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Hyperostosis | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | – | 1 (2%) | – | –
Skeletal muscle | (0) | (0) | (0) | (1)
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 5 (10%) | 9 (18%) | 8 (16%) | 9 (18%)
Hemorrhage | 1 (2%) | – | 2 (4%) | 3 (6%)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | –
Inflammation, granulomatous | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 12 (24%) | 11 (22%) | 12 (24%) | 8 (16%)
Alveolar epithelium, metaplasia, squamous | – | 1 (2%) | – | –
Perivascular, hemorrhage | – | – | 1 (2%) | 1 (2%)
Perivascular, inflammation, chronic active | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (50)
Edema | – | – | – | 1 (2%)
Foreign body | 10 (20%) | 20 (40%) | 15 (30%) | 10 (20%)
Inflammation | 21 (42%) | 23 (46%) | 16 (32%) | 24 (48%)
Mineralization | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | –
Glands, cyst | – | – | – | 1 (2%)
Nasolacrimal duct, foreign body | – | – | 1 (2%) | –
Nasolacrimal duct, hyperplasia, squamous | – | – | 1 (2%) | –
Nasolacrimal duct, inflammation | 1 (2%) | – | 1 (2%) | –
Olfactory epithelium, atrophy | – | – | – | 1 (2%)
Olfactory epithelium, erosion | – | – | – | 1 (2%)
Olfactory epithelium, metaplasia | – | – | 1 (2%) | 1 (2%)
Olfactory epithelium, necrosis | – | – | – | 1 (2%)
Respiratory epithelium, degeneration, cystic | 1 (2%) | – | –
Respiratory epithelium, erosion | – | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | 14 (28%) | 20 (40%) | 15 (30%) | 17 (34%)
Respiratory epithelium, metaplasia, squamous | – | 1 (2%) | – | –
Respiratory epithelium, ulcer | 2 (4%) | – | – | –
Squamous epithelium, hyperplasia | – | 1 (2%) | 1 (2%)
Trachea | (49) | (50) | (50) | (50)
Amyloid deposition | 1 (2%) | – | –
Inflammation | – | – | – | 1 (2%)
Glands, cyst | 2 (4%) | – | – | –
Special Senses System
Ear | (2) | (0) | (0) | (0)
Cyst | 1 (50%) | – | – | –
Hyperplasia, squamous | 1 (50%) | – | – | –
Eye | (50) | (50) | (50) | (50)
Cataract | 2 (4%) | 3 (6%) | 1 (2%) | 3 (6%)
Cornea, hyperplasia, squamous | – | – | 2 (4%) | –
Cornea, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Retina, degeneration | – | 1 (2%) | 1 (2%) | 1 (2%)
Sclera, inflammation, chronic active | 1 (2%) | – | – | 1 (2%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | 2 (4%) | –
Zymbal’s gland | (1) | (0) | (1) | (1)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | – | – | 1 (2%)
Dilatation | – | 1 (2%) | – | –
Infarct, acute | – | 1 (2%) | 1 (2%) | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | – | –
Nephropathy | 48 (96%) | 50 (100%) | 50 (100%) | 50 (100%)
Medulla, renal tubule, necrosis | – | 1 (2%) | – | –
Pelvis, inflammation, chronic active | – | 1 (2%) | 2 (4%) | –
Renal tubule, hyperplasia | – | 1 (2%) | – | 1 (2%)
Urinary bladder | (50) | (50) | (50) | (50)
Hemorrhage | – | 1 (2%) | – | –
Infiltration cellular, mixed cell, chronic active | – | – | – | 1 (2%)
Inflammation, suppurative | – | 1 (2%) | – | –
Transitional epithelium, hyperplasia | – | 1 (2%) | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.