# References

1 U.S. FDA (U.S. Food and Drug Administration). 2014. Bisphenol A Joint Emerging Science Working Group: Final report for the review of literature and data on BPA (draft). h[underlined: ttps://www.fda.gov/downloads/Food/IngredientsPackagingLabeling/FoodAdditivesIngredients/UCM424011.pdf].
2 EFSA (European Food Safety Authority) Scientific Opinion on the risks to public health related to the presence of bisphenol A (BPA) in foodstuffs: PART II - Toxicological assessment and risk characterization. EFSA J. 2015;13(1):3978.h[underlined: ttp://dx.doi.org/10.2903/j.efsa.2015.3978]
3 Health Canada. 2012. Health Canada's updated assessment of bisphenol A (BPA) exposure from food sources. h[underlined: ttp://www.hc-sc.gc.ca/fn-an/alt_formats/pdf/securit/packag-emball/bpa/bpa_hra-ers-2012-09-eng.pdf].
4 U.S. FDA (U.S. Food and Drug Administration). 2014. Updated safety assessment of bisphenol A (BPA) for use in food contact applications. h[underlined: ttps://www.fda.gov/downloads/NewsEvents/PublicHealthFocus/UCM424266.pdf].
5 Zoeller RT Brown TR Doan LL Gore AC Skakkebaek NE Soto AM Woodruff TJ Vom Saal FS Endocrine-disrupting chemicals and public health protection: a statement of principles from The Endocrine Society. Endocrinology. 2012;153(9):4097–4110. h[underlined: ttp://dx.doi.org/10.1210/en.2012-1422] 22733974
6 Gore AC Chappell VA Fenton SE Flaws JA Nadal A Prins GS Toppari J Zoeller RT EDC-2: the Endocrine Society’s second scientific statement on endocrine-disrupting chemicals. Endocr Rev. 2015;36(6):E1–E150. h[underlined: ttp://dx.doi.org/10.1210/er.2015-1010] 26544531
7 Rochester JR Bisphenol A and human health: a review of the literature. Reprod Toxicol. 2013;42:132–155. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2013.08.008] 23994667
8 ANSES (Administración Nacional de la Seguridad Social). 2013. Opinion of the French Agency for Food, Environmental and Occupational Health & Safety on the assessment of the risks associated with bisphenol A for human health, and on toxicological data and data on the use of bisphenols S, F, M, B, AP, AF and BADGE. h[underlined: ttps://www.anses.fr/en/system/files/CHIM2009sa0331Ra-0EN.PDF].
9 Proposition 65: Bisphenol A listed as known to the state of California to cause reproductive toxicity. h[underlined: ttps://oehha.ca.gov/prop65/CRNR_notices/list_changes/051115listBPA.html;] 2015.
10 NTP (National Toxicology Program). 1982. Carcinogenesis bioassay of bisphenol A (CAS No. 80-05-7) in F344 rats and B6C3F1 mice (feed study). h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/12778220].
11 Schug TT Heindel JJ Camacho L Delclos KB Howard P Johnson AF Aungst J Keefe D Newbold R Walker NJ A new approach to synergize academic and guideline-compliant research: the CLARITY-BPA research program. Reprod Toxicol. 2013;40:35–40. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2013.05.010] 23747832
12 Heindel JJ Newbold RR Bucher JR Camacho L Delclos KB Lewis SM Vanlandingham M Churchwell MI Twaddle NC McLellen M NIEHS/FDA CLARITY-BPA research program update. Reprod Toxicol. 2015;58:33–44. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2015.07.075] 26232693
13 NTP (National Toxicology Program). 2008. Multigenerational reproductive study of genistein (Cas No. 446-72-0) in Sprague-Dawley rats (feed study). h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/18685713].
14 NTP (National Toxicology Program). 2008. Toxicology and carcinogenesis studies of genistein (Cas No. 446-72-0) in Sprague-Dawley rats (feed study). h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/18685716].
15 NTP (National Toxicology Program). 2010. Toxicology and carcinogenesis study of ethinyl estradiol (CAS No. 57-63-6) in Sprague-Dawley rats (feed study). h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/21031006].
16 NTP (National Toxicology Program). 2010. Multigenerational reproductive toxicology study of ethinyl estradiol (CAS No. 57-63-6) in Sprague-Dawley rats. h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/21031005].
17 Delclos KB Bucci TJ Lomax LG Latendresse JR Warbritton A Weis CC Newbold RR Effects of dietary genistein exposure during development on male and female CD (Sprague-Dawley) rats. Reprod Toxicol. 2001;15(6):647–663. h[underlined: ttp://dx.doi.org/10.1016/S0890-6238(01)00177-0] 11738518
18 Delclos KB Weis CC Bucci TJ Olson G Mellick P Sadovova N Latendresse JR Thorn B Newbold RR Overlapping but distinct effects of genistein and ethinyl estradiol (EE(2)) in female Sprague-Dawley rats in multigenerational reproductive and chronic toxicity studies. Reprod Toxicol. 2009;27(2):117–132. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2008.12.005] 19159674
19 Delclos KB Camacho L Lewis SM Vanlandingham MM Latendresse JR Olson GR Davis KJ Patton RE Gamboa da Costa G Woodling KA Toxicity evaluation of bisphenol A administered by gavage to Sprague Dawley rats from gestation day 6 through postnatal day 90. Toxicol Sci. 2014;139(1):174–197. h[underlined: ttp://dx.doi.org/10.1093/toxsci/kfu022] 24496637
20 Latendresse JR Bucci TJ Olson G Mellick P Weis CC Thorn B Newbold RR Delclos KB Genistein and ethinyl estradiol dietary exposure in multigenerational and chronic studies induce similar proliferative lesions in mammary gland of male Sprague-Dawley rats. Reprod Toxicol. 2009;28(3):342–353. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2009.04.006] 19383540
21 Doerge DR Twaddle NC Vanlandingham M Fisher JW Pharmacokinetics of bisphenol A in neonatal and adult Sprague-Dawley rats. Toxicol Appl Pharmacol. 2010;247(2):158–165. h[underlined: ttp://dx.doi.org/10.1016/j.taap.2010.06.008] 20600215
22 Doerge DR Twaddle NC Vanlandingham M Brown RP Fisher JW Distribution of bisphenol A into tissues of adult, neonatal, and fetal Sprague-Dawley rats. Toxicol Appl Pharmacol. 2011;255(3):261–270. h[underlined: ttp://dx.doi.org/10.1016/j.taap.2011.07.009] 21820460
23 Twaddle NC Churchwell MI Vanlandingham M Doerge DR Quantification of deuterated bisphenol A in serum, tissues, and excreta from adult Sprague-Dawley rats using liquid chromatography with tandem mass spectrometry. Rapid Commun Mass Spectrom. 2010;24(20):3011–3020. h[underlined: ttp://dx.doi.org/10.1002/rcm.4733] 20872634
24 Twaddle NC Churchwell MI Newbold RR Delclos KB Doerge DR Determination using liquid-chromatography-electrospray tandem mass spectroscopy of ethinylestradiol serum pharmacokinetics in adult Sprague-Dawley rats. J Chromatogr B Analyt Technol Biomed Life Sci. 2003;793(2):309–315. h[underlined: ttp://dx.doi.org/10.1016/S1570-0232(03)00331-3] 12906905
25 Churchwell MI Camacho L Vanlandingham MM Twaddle NC Sepehr E Delclos KB Fisher JW Doerge DR Comparison of life-stage-dependent internal dosimetry for bisphenol A, ethinyl estradiol, a reference estrogen, and endogenous estradiol to test an estrogenic mode of action in Sprague Dawley rats. Toxicol Sci. 2014;139(1):4–20. h[underlined: ttp://dx.doi.org/10.1093/toxsci/kfu021] 24496641
26 Tyl RW Myers CB Marr MC Sloan CS Castillo NP Veselica MM Seely JC Dimond SS Van Miller JP Shiotsuka RN Two-generation reproductive toxicity study of dietary bisphenol A in CD-1 (Swiss) mice. Toxicol Sci. 2008;104(2):362–384. h[underlined: ttp://dx.doi.org/10.1093/toxsci/kfn084] 18445619
27 Tyl RW Myers CB Marr MC Thomas BF Keimowitz AR Brine DR Veselica MM Fail PA Chang TY Seely JC Three-generation reproductive toxicity study of dietary bisphenol A in CD Sprague-Dawley rats. Toxicol Sci. 2002;68(1):121–146. h[underlined: ttp://dx.doi.org/10.1093/toxsci/68.1.121] 12075117
28 Doerge DR Vanlandingham M Twaddle NC Delclos KB Lactational transfer of bisphenol A in Sprague-Dawley rats. Toxicol Lett. 2010;199(3):372–376. h[underlined: ttp://dx.doi.org/10.1016/j.toxlet.2010.09.022] 20933065
29 Yang X Doerge DR Teeguarden JG Fisher JW Development of a physiologically based pharmacokinetic model for assessment of human exposure to bisphenol A. Toxicol Appl Pharmacol. 2015;289(3):442–456. h[underlined: ttp://dx.doi.org/10.1016/j.taap.2015.10.016] 26522835
30 Wetherill YB Akingbemi BT Kanno J McLachlan JA Nadal A Sonnenschein C Watson CS Zoeller RT Belcher SM In vitro molecular mechanisms of bisphenol A action. Reprod Toxicol. 2007;24(2):178–198. h[underlined: ttp://dx.doi.org/10.1016/j.reprotox.2007.05.010] 17628395
31 Acconcia F Pallottini V Marino M Molecular mechanisms of action of BPA. Dose Response. 2015;13(4):1559325815610582. h[underlined: ttp://dx.doi.org/10.1177/1559325815610582] 26740804
32 Nadal A Fuentes E Ripoll C Villar-Pazos S Castellano-Muñoz M Soriano S Martinez-Pinna J Quesada I Alonso-Magdalena P Extranuclear-initiated estrogenic actions of endocrine disrupting chemicals: is there toxicology beyond paracelsus? J Steroid Biochem Mol Biol. 2018;176:16–22. h[underlined: ttp://dx.doi.org/10.1016/j.jsbmb.2017.01.014] 28159674
33 Villar-Pazos S Martinez-Pinna J Castellano-Muñoz M Alonso-Magdalena P Marroqui L Quesada I Gustafsson JA Nadal A Molecular mechanisms involved in the non-monotonic effect of bisphenol-a on ca2+ entry in mouse pancreatic β-cells. Sci Rep. 2017;7(1):11770. h[underlined: ttp://dx.doi.org/10.1038/s41598-017-11995-3] 28924161
34 Conley JM Hannas BR Furr JR Wilson VS Gray LE Jr A demonstration of the uncertainty in predicting the estrogenic activity of individual chemicals and mixtures from an in vitro estrogen receptor transcriptional activation assay (T47D-KBluc) to the in vivo uterotrophic assay using oral exposure. Toxicol Sci. 2016;153(2):382–395. h[underlined: ttp://dx.doi.org/10.1093/toxsci/kfw134] 27473340
35 Lewis SM Lee FW Ali AA Allaben WT Weis CC Leakey JE Modifying a displacement pump for oral gavage dosing of solution and suspension preparations to adult and neonatal mice. Lab Anim (NY). 2010;39(5):149–154. h[underlined: ttp://dx.doi.org/10.1038/laban0510-149] 20410899
36 Camacho L Lewis SM Vanlandingham MM Juliar BE Olson GR Patton RE Gamboa da Costa G Woodling K Sepehr E Bryant MS Comparison of endpoints relevant to toxicity assessments in 3 generations of CD-1 mice fed irradiated natural and purified ingredient diets with varying soy protein and isoflavone contents. Food Chem Toxicol. 2016;94:39–56. h[underlined: ttp://dx.doi.org/10.1016/j.fct.2016.05.014] 27234134
37 Brown NM Setchell KDR Animal models impacted by phytoestrogens in commercial chow: implications for pathways influenced by hormones. Lab Invest. 2001;81(5):735–747. h[underlined: ttp://dx.doi.org/10.1038/labinvest.3780282] 11351045
38 Thigpen JE Setchell KD Padilla-Banks E Haseman JK Saunders HE Caviness GF Kissling GE Grant MG Forsythe DB Variations in phytoestrogen content between different mill dates of the same diet produces significant differences in the time of vaginal opening in CD-1 mice and F344 rats but not in CD Sprague-Dawley rats. Environ Health Perspect. 2007;115(12):1717–1726. h[underlined: ttp://dx.doi.org/10.1289/ehp.10165] 18087589
39 Thigpen JE Setchell KDR Kissling GE Locklear J Caviness GF Whiteside T Belcher SM Brown NM Collins BJ Lih FB The estrogenic content of rodent diets, bedding, cages, and water bottles and its effect on bisphenol A studies. J Am Assoc Lab Anim Sci. 2013;52(2):130–141. 23562095
40 Thigpen JE Setchell KDR Saunders HE Haseman JK Grant MG Forsythe DB Selecting the appropriate rodent diet for endocrine disruptor research and testing studies. ILAR J. 2004;45(4):401–416. h[underlined: ttp://dx.doi.org/10.1093/ilar.45.4.401] 15454679
41 Butchbach ME Edwards JD Schussler KR Burghes AH A novel method for oral delivery of drug compounds to the neonatal SMNDelta7 mouse model of spinal muscular atrophy. J Neurosci Methods. 2007;161(2):285–290. h[underlined: ttp://dx.doi.org/10.1016/j.jneumeth.2006.11.002] 17161463
42 Dixon D, Alison R, Bach U, Colman K, Foley GL, Harleman JH, Haworth R, Herbert R, Heuser A, Long G, et al. Nonproliferative and proliferative lesions of the rat and mouse female reproductive system. J Toxicol Pathol. 2014; 27(3-4 Suppl):1S-107S. h (http://dx.doi.org/10.1293/tox.27.1S)
43 Rudmann D, Cardiff R, Chouinard L, Goodman D, Kuttler K, Marxfeld H, Molinolo A, Treumann S, Yoshizawa K. Inhand Mammary ZsP et al. Proliferative and nonproliferative lesions of the rat and mouse mammary, Zymbal's, preputial, and clitoral glands. Toxicol Pathol. 2012; 40(6 Suppl):7S-39S. h (http://dx.doi.org/10.1177/0192623312454242)
44 Creasy D, Bube A, de Rijk E, Kandori H, Kuwahara M, Masson R, Nolte T, Reams R, Regan K, Rehm S, et al. Proliferative and nonproliferative lesions of the rat and mouse male reproductive system. Toxicol Pathol. 2012; 40(6_suppl):40S-121S. h (http://dx.doi.org/10.1177/0192623312454337)
45 Brunner E Domhof S Langer F Nonparametric Analysis of Longitudinal Data in Factorial Experiments. New York, New York: John Wiley and Sons; 2002.
46 Kenward MG Roger JH Small sample inference for fixed effects from restricted maximum likelihood. Biometrics. 1997;53(3):983–997. h[underlined: ttp://dx.doi.org/10.2307/2533558] 9333350
47 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. h[underlined: ttp://dx.doi.org/10.2307/2531856] 3390507
48 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. h[underlined: ttp://dx.doi.org/10.2307/2532200] 8241374
49 Peddada SD Kissling GE A survival-adjusted quantal-response test for analysis of tumor incidence rates in animal carcinogenicity studies. Environ Health Perspect. 2006;114(4):537–541. h[underlined: ttp://dx.doi.org/10.1289/ehp.8590] 16581542
50 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.h[underlined: ttp://dx.doi.org/]1[underlined: 0.1093/biomet/41.1-2.133] (https://doi.org/10.1093/biomet/41.1-2.133) (http://dx.doi.org/10.1093/toxsci/kfm306)
51 Terpstra TJ. The asymptotic normality and consistency of Kendall’s test against trend when ties are present in one ranking. Indagationes Mathematicae (Proceedings). 1952; 55:327-333. 10.1016/S1385-7258(52)50043-X 10.1016/S1385-7258(52)50043-X
52 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
53 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
54 Tennekes H Gembardt C Dammann M van Ravenzwaay B The stability of historical control data for common neoplasms in laboratory rats: adrenal gland (medulla), mammary gland, liver, endocrine pancreas, and pituitary gland. Regul Toxicol Pharmacol. 2004;40(1):18–27. 10.1016/j.yrtph.2004.04.003 15265603
55 Tennekes H Kaufmann W Dammann M van Ravenzwaay B The stability of historical control data for common neoplasms in laboratory rats and the implications for carcinogenic risk assessment. Regul Toxicol Pharmacol. 2004;40(3):293–304. 10.1016/j.yrtph.2004.07.007 15546683
56 Peretz J Vrooman L Ricke WA Hunt PA Ehrlich S Hauser R Padmanabhan V Taylor HS Swan SH VandeVoort CA Bisphenol a and reproductive health: update of experimental and human evidence, 2007-2013. Environ Health Perspect. 2014;122(8):775–786. 10.1289/ehp.1307728 24896072
57 Le Corre L Besnard P Chagnon MC BPA, an energy balance disruptor. Crit Rev Food Sci Nutr. 2015;55(6):769–777. 10.1080/10408398.2012.678421 24915348
58 Seachrist DD Bonk KW Ho SM Prins GS Soto AM Keri RA A review of the carcinogenic potential of bisphenol A. Reprod Toxicol. 2016;59:167–182. 10.1016/j.reprotox.2015.09.006 26493093
59 Braun JM Early-life exposure to EDCs: role in childhood obesity and neurodevelopment. Nat Rev Endocrinol. 2017;13(3):161–173. 10.1038/nrendo.2016.186 27857130
60 Yoshida M Shimomoto T Katashima S Watanabe G Taya K Maekawa A Maternal exposure to low doses of bisphenol a has no effects on development of female reproductive tract and uterine carcinogenesis in Donryu rats. J Reprod Dev. 2004;50(3):349–360. 10.1262/jrd.50.349 15226600
61 Haseman JK. Use of statistical decision rules for evaluating laboratory animal carcinogenicity studies. Fund Appl Toxicol. 1990; 14(637-648). 10.1016/0272-0590(90)90289-V 10.1016/0272-0590(90)90289-V
62 Kissling GE Haseman JK Zeiger E Proper interpretation of chronic toxicity studies and their statistics: A critique of “Which level of evidence does the US National Toxicology Program provide? Statistical considerations using the Technical Report 578 on Ginkgo biloba as an example”. Toxicol Lett. 2015;237(2):161–164. 10.1016/j.toxlet.2014.09.016 25261588
63 Yoshizawa K Brix AE Sells DM Jokinen MP Wyde M Orzech DP Kissling GE Walker NJ Nyska A Reproductive lesions in female Harlan Sprague-Dawley rats following two-year oral treatment with dioxin and dioxin-like compounds. Toxicol Pathol. 2009;37(7):921–937. 10.1177/0192623309351721 19843953
64 Sarkar DK Gottschall PE Meites J Damage to hypothalamic dopaminergic neurons is associated with development of prolactin-secreting pituitary tumors. Science. 1982;218(4573):684–686. 10.1126/science.7134966 7134966
65 Blankenstein MA Broerse JJ van Zwieten MJ van der Molen HJ Prolactin concentration in plasma and susceptibility to mammary tumors in female rats from different strains treated chronically with estradiol-17 beta. Breast Cancer Res Treat. 1984;4(2):137–141. 10.1007/BF01806396 6743839
66 Ferguson SA Law CD Kissling GE Developmental treatment with ethinyl estradiol, but not bisphenol A, causes alterations in sexually dimorphic behaviors in male and female Sprague Dawley rats. Toxicol Sci. 2014;140(2):374–392. 10.1093/toxsci/kfu077 24798382
67 Zaccaroni M Massolo A Della Seta D Farabollini F Giannelli G Fusani L Dessì-Fulgheri F Developmental exposure to low levels of ethinylestradiol affects play behavior in juvenile female rats. Neurotox Res. 2018;33(4):876–886. 10.1007/s12640-017-9852-4 29260494
68 Shirota M Kawashima J Nakamura T Kamiie J Shirota K Yoshida M Dose-dependent acceleration in the delayed effects of neonatal oral exposure to low-dose 17α-ethynylestradiol on reproductive functions in female Sprague-Dawley rats. J Toxicol Sci. 2015;40(6):727–738. 10.2131/jts.40.727 26558453
69 Howdeshell KL Furr J Lambright CR Wilson VS Ryan BC Gray LE Jr Gestational and lactational exposure to ethinyl estradiol, but not bisphenol A, decreases androgen-dependent reproductive organ weights and epididymal sperm abundance in the male long evans hooded rat. Toxicol Sci. 2008;102(2):371–382. 10.1016/j.reprotox.2015.07.075 18096570
70 Ryan BC Hotchkiss AK Crofton KM Gray LE Jr In utero and lactational exposure to bisphenol A, in contrast to ethinyl estradiol, does not alter sexually dimorphic behavior, puberty, fertility, and anatomy of female LE rats. Toxicol Sci. 2010;114(1):133–148. 10.1093/toxsci/kfp266 19864446
71 Delclos KB Doerge DR Response to Hunt et al., invalid controls undermine conclusions of FDA studies. Toxicol Sci. 2014;141(1):3. 10.1093/toxsci/kfu102 24863966