# Foreword

This study was carried out under the auspices of the National Toxicology Program (NTP) as part of the Consortium Linking Academic and Regulatory Insights on Bisphenol A Toxicity (CLARITY-BPA), a consortium-based research program between the National Institute of Environmental Health Sciences (NIEHS) of the National Institutes of Health (NIH) and the National Center for Toxicological Research (NCTR) of the US Food and Drug Administration (FDA).

The aim of the CLARITY-BPA program was to bridge guideline-compliant research conducted at the FDA with hypothesis-based research investigations conducted by academia on the toxicity of bisphenol A (BPA). A detailed description of the CLARITY-BPA program is covered in Heindel and co-authors (h[underlined: ttps://www.ncbi.nlm.nih.gov/pubmed/26232693]).

The CLARITY-BPA research program has two components: 1) A “core” guideline-compliant chronic study conducted at NCTR according to FDA Good Laboratory Practice (GLP) regulations (two-year perinatal only or chronic BPA exposure, including perinatal), and 2) CLARITY-BPA grantee studies of various health endpoints, conducted by NIEHS-funded researchers at academic institutions using animals born to the same exposed pregnant rats as the core GLP study.

This NTP Research Report only covers the core study and includes the narrative, tables, and figures reported in the GLP report. The core study GLP report had 34 appendices, which are listed in Appendix A and referred to as Supplemental Appendices throughout this report. The original GLP report for the core study is on file at NCTR.

The interpretation of biological and toxicological responses described in this report is based only on the results of the core GLP study. Integration of these data with other data from the grantee studies conducted as part of the CLARITY-BPA research program or extrapolation of the results to other species, including characterization of hazards and risks to humans, is outside of the scope of this report.

The core GLP study was designed to characterize and evaluate the toxicologic potential of BPA following perinatal only or chronic exposure in rats under the conditions of a chronic, extended-dose response design. The core GLP study was designed by NCTR and NIEHS scientists with substantial input from the CLARITY-BPA consortium members.

This study was funded via an interagency agreement between FDA and NIEHS. The study’s conduct and progress were monitored by the Toxicology Study Selection and Review Committee (composed of representatives from NCTR, other FDA product centers, and NIEHS, ad hoc members of other federal government agencies, and academia), the CLARITY-BPA Steering Committee, and the CLARITY-BPA External Scientific Panel.

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. The core GLP study is subjected to retrospective quality assurance audits before being presented for public review.