# Peer Review

NTP convened an expert panel on April 26, 2018, to peer review the NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats. The panel members are listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, the panel provided input on the scientific and technical elements of the CLARITY-BPA Core Study and ensured that this NTP Research Report presented the experimental results and conclusions fully and clearly.

Meeting materials, the peer review report, and presentation recordings can be found on the NTP website: h[underlined: ttps://ntp.niehs.nih.gov/events/past/index.html].

## Peer Reviewers

- David Dorman, D.V.M., Ph.D. (Chair)
  Professor of Toxicology, Department of Molecular Biomedical Sciences
  College of Veterinary Medicine
  North Carolina State University
  Raleigh, NC
- Tracie Bunton, D.V.M., Ph.D.
  Founder
  Eicarte LLC
  Gettysburg, PA
- Michael Conner, D.V.M.
  Vice President, Toxicology
  Global Blood Therapeutics, Inc.
  San Francisco, CA
- Thomas Rosol, D.V.M., Ph.D.
  Professor and Chair, Department of Biomedical Sciences, Heritage College of Osteopathic Medicine, Ohio University
  Adjunct Professor, Division of Urology, Department of Medicine, The Ohio State University
  Marietta, OH
- Janet Tooze, Ph.D.
  Professor, Department of Biostatistical Sciences
  Wake Forest School of Medicine
  Wake Forest University
  Winston-Salem, NC
- Kimberley Treinen, Ph.D.
  Executive Director, Discovery and Preclinical Research
  Sunovion Pharmaceuticals, Inc.
  Hopkinton, MA