# Collaborators

- U.S. Food and Drug Administration, National Center for Toxicological Research, Jefferson, Arkansas, USA
  Study conduct, evaluation, and reporting of findings
  Frederick A. Beland, Ph.D.
  Matthew S. Bryant, Ph.D.
  Kathy A. Carroll
  Luísa Camacho, Ph.D., Co-Principal Investigator
  K. Barry Delclos, Ph.D., Principal Investigator
  Robert P. Felton, M.S.
  Gonҫalo Gamboa da Costa, Ph.D.
  Paul C. Howard, Ph.D. (now retired)
  Sherry M. Lewis, Ph.D., Co-Principal Investigator (now retired)
  Michelle M. Vanlandingham, Co-Principal Investigator
- Toxicologic Pathology Associates, Frederick, Maryland, USA
  Study conduct, evaluation and reporting of findings
  Greg R. Olson, D.V.M., Ph.D., Study Pathologist
  Ralph Patton, B.S.
- National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Study conduct, evaluation and reporting of findings
  Nigel J. Walker, Ph.D.
  Nira Ben-Jonathan, Ph.D., University of Cincinnati