# Discussion

BPA is a high-production-volume chemical to which there is ubiquitous sub-microgram/kg bw/day human exposure, primarily through the diet. A large body of data has been published on the effects of BPA in in vitro and in vivo systems, including epidemiological studies investigating the association of early life exposures to BPA with a variety of diseases.^7,56-59^ After considering these data, the levels of exposure, and the extent of metabolic inactivation of BPA upon ingestion, most international regulatory agencies have concluded that current non-occupational BPA exposures do not pose a credible risk to humans. However, this conclusion is not without controversy. Given the large body of data available on BPA and the level of human exposure that is prompting the debate, the present study was designed not as a high dose hazard identification study, but rather to examine a broad dose range from reasonably close to human dietary exposure levels to levels >25,000-fold higher than current estimated aggregate non-occupational exposure. The dose spacing of 10-fold used over the broad dose range in the study is typically the maximum dose range covered in a bioassay.

Yoshida et al.^60^ originally raised the issue of the presence of BPA in commercial rodent diets when they reported approximately 40 ppb in the diet as measured by an HPLC-fluorescence method. The background diet analyses that were conducted for this study and for previous studies using a more specific HPLC-MS/MS method^19,36^ confirmed that commercial rodent diets contain trace levels (low ppb) of BPA. The ingested levels resulting from this dietary background did not lead to measurable levels of BPA or its metabolites in blood or tissues, but the presence of this background places a lower limit on the dose of BPA that can be tested. For the present study, a rejection level of 5 ppb BPA in the diet was established. This level of dietary BPA would have resulted in ingestion of approximately 0.25 μg/kg bw/day, a 10-fold lower exposure, on a μg/kg bw/day basis, over the course of the study than the exposure in the lowest chosen BPA dose group of 2.5 μg/kg bw/day. None of the lots of diet used in the study had a background level of BPA >3 ppb.

Survival of the interim sacrifice animals was 82–100%, and there were no effects of BPA on survival of the interim or terminal sacrifice animals. However, ≥60% of the terminal sacrifice animals did not survive to the scheduled sacrifice. Most were removed as moribund for animal welfare considerations and provided a full set of data for evaluation. The Poly-3 test applied for the analysis of the two-year pathology data is adjusted for mortality.

Female body weights in the continuous 250 μg BPA/kg bw/day dose group were significantly higher than the mean vehicle control body weights in the final weeks of the study (weeks 96–104). There were no other statistically significant body weight differences in pairwise comparisons of BPA dose groups to the vehicle controls. There were few statistically significant effects of BPA treatment, in either the continuous- or stop-dose arms, on clinical pathology endpoints or organ weights, and these effects could not be clearly defined as treatment-related as they were observed only in single-dose groups, in several cases differed from the vehicle control by less than 10%, and, in the case of organ weights, were not significant when adjusted for body weight.

The approach used by the NTP to determine if neoplasms are likely related to treatment has always focused on a weight-of-evidence approach, encompassing a range of factors, including statistical analysis, consideration of consistency of responses within the study, and historical controls.^61,62^ This approach was followed in the present study to evaluate the histopathology data for the neoplastic and non-neoplastic lesions. There were relatively few neoplastic lesions that showed potential treatment effects. There were many non-neoplastic lesions in both males and females that were variable across control and BPA treatment levels. One issue that contributed to the challenge of clearly establishing effects as treatment related was that most diagnosed lesions, whether neoplastic or non-neoplastic, were not rare lesions, but rather common lesions associated with aging. To assess these lesions for any potential treatment effects, the CAFE test was applied for lesion incidence in the one-year study, and the survival-adjusted Poly-3 test was used for lesion incidence in the two-year study. The pairwise comparisons conducted as part of these analyses do not assume a monotonic dose response, but do not incorporate the severity scores assigned to many of the non-neoplastic lesions during the microscopic evaluation. The JT/SW test, which assumes monotonicity across dose levels, was applied to incorporate severity scores along with the incidence data. Because non-monotonic dose responses have been central to the discussion of the effects of BPA and other potential hormonally active agents, another test was applied that incorporates both incidence and severity scores and does not assume monotonicity.^45^ This test (RTE) has not been widely used in toxicology studies, although it was used in the previous BPA subchronic study conducted at NCTR.^19^ Neither the JT/SW nor the RTE tests adjust for survival. Although the use of multiple statistical tests coupled with the multitude of endpoints examined and lack of correction for multiple comparisons can lead to erroneous inferences in the interpretation of histopathology data based on p-values alone, the results of all statistical tests are presented in the Results section and Supplemental Appendices XXXIII and XXXIV, primarily to guide the selection of histopathological lesions that required evaluation.

At the terminal sacrifice of females in the stop-dose BPA study arm, there was a statistically significant increase in the incidence of mammary gland adenocarcinoma (22% versus 6%, p = 0.016) and the combination of adenoma/adenocarcinoma (24% versus 8%, p = 0.018) in the 2.5 μg BPA/kg bw/day dose group. This incidence is higher than the limited data available for historical controls of this rat strain at NCTR utilizing the same diet,^14,15^ which indicate a background rate of 11–16% for mammary gland adenocarcinoma in two-year-old control females. In the continuous-dose BPA study arm, the incidence of female mammary gland adenocarcinoma and the combination of adenoma/adenocarcinoma was 8% and 12%, respectively, in the control group. The incidence in each of the BPA continuous-dose groups varied between 6 and 18% for adenocarcinoma and between 9 and 20% for combined adenoma/adenocarcinoma, none of which was significant.

There were no treatment-related non-neoplastic changes in the mammary gland of interim or terminal sacrifice female stop-dose animals. In the interim and terminal continuous-dose arm, there were some differences in incidence and severity between BPA groups and the vehicle control group indicated by the secondary RTE statistical test. There was an increase in atypical foci in the mammary gland at 2.5 μg BPA/kg bw/day (14% versus 0% and 15% versus 4% for the interim and terminal dose group animals, respectively). There was also an increase in ductal dilatation at the interim sacrifice in animals continuously administered 25 μg BPA/kg bw/day (32% versus 9%).

Evaluation of the totality of the evidence regarding the elevated incidence of mammary adenocarcinomas or combined adenomas and adenocarcinomas in the stop-dose females exposed to 2.5 μg BPA/kg bw/day makes it unlikely that this is a plausible BPA treatment-related lesion. The elevated incidence occurs in a single dose group of the stop-dose arm and was not observed in the continuous-dose arm. In addition, there were no treatment-related non-neoplastic lesions in the mammary gland of interim or terminal sacrifice stop-dose animals. Comparison of the incidences of mammary gland adenoma/adenocarcinoma in control and treatment groups to the limited historical control data for this strain of rats further questions the biological plausibility of this lesion as a treatment-related effect. In the continuous-dose, but not stop-dose, arm animals, there was an elevation of atypical foci in the 2.5 μg BPA/kg bw/day group in interim and terminal sacrifice animals, but no increase in adenomas or adenocarcinomas. It is difficult to envision a mechanism whereby the stop-dose animals would develop mammary adenocarcinomas, while continuous-dose animals would not. Yoshizawa et al.^63^ reported a gavage study of 2, 3′, 4, 4′, 5-pentachlorobiphenyl (PCB 118) in rats where the highest dose group was either exposed from 8 weeks of age through two years (continuous exposure group), or from 8 weeks of age through 32 weeks and then dosed with vehicle on the same schedule as the continuously exposed animals through two years (stop exposure group). Uterine carcinoma was elevated only in the stop exposure group. A plausible hypothesis proposed by the authors was that the body weight depression of greater than 10% in the continuously exposed group may have suppressed development of the uterine carcinomas, and cited that mammary fibroadenomas, a spontaneous neoplasm known to be suppressed by decreased body weight gain, was also lower in the continuously dosed animals. In the present study, although there were no statistical comparisons conducted across dosing arms, there was an apparently higher body weight in the stop-dose females (average 7% and 5% higher than continuous-dose females for vehicle control and 2.5 μg BPA/kg bw/day groups, respectively). The development of spontaneous mammary gland fibroadenomas, however, was not suppressed in the BPA continuous-dose females nor was the development of mammary gland adenocarcinomas in high dose EE_2_ animals (discussed below).

In contrast to BPA treatments, the reference estrogen EE_2_ had a clearly interpretable impact on the female mammary gland. As indicated earlier, although targets for BPA other than classical estrogen receptors have been proposed,^30-33^ many of the reported effects of BPA involve estrogen signaling pathways. Thus, sensitivity of the animal model to exogenous estrogen was considered important, and EE_2_ was included for this purpose rather than necessarily to compare effects of the two agents. The high dose (0.5 μg EE_2_/kg bw/day) induced an increased incidence of adenocarcinoma (38% versus 8% in controls) and dilatation of ducts and alveoli in the mammary glands of terminal animals. In the mammary glands of interim females, the incidences of lobular hyperplasia and dilatation of ducts were increased in the high EE_2_ dose group. In addition, increased incidence of combined adenomas and carcinomas in the pituitary pars distalis at 0.5 μg EE_2_/kg bw/day may be related to increased mammary neoplasm incidence. Exogenous estrogen exposure in the rat can lead to decreased activity of dopaminergic neurons in the hypothalamus leading to prolactinomas in the pituitary that contribute to mammary adenocarcinoma development.^64,65^ The production of prolactin from the pituitary neoplasms was not investigated in this study, although serum prolactin was reported to be elevated in adult rats at 0.5 μg EE_2_/kg bw/day in the previous NCTR subchronic BPA study.^19^

The only other statistically significant neoplastic lesion in BPA-treated females was a significant trend (p = 0.037) for uterine stromal polyps in the interim continuous-dose arm animals. This trend was driven by incidences of 3/20 (15%) and 3/24 (12%) in the 2,500 and 25,000 μg BPA/kg bw/day dose groups, respectively, which were not statistically different in pairwise comparisons with the control incidence of 1/23 (4%). No trend toward higher incidences in the higher BPA dose groups was evident in the terminal sacrifice continuous-dose animals, nor were there any significant pairwise comparisons between any BPA dose group and controls in the terminal sacrifice animals. Likewise, stromal polyps were not induced in the stop-dose BPA or in the interim or terminal sacrifice EE_2_ animals. The relatively small increased incidences leading to the significant trend in the interim sacrifice animals together with the lack of any effects in the terminal sacrifice animals indicate that uterine stromal polyps are not likely to be a consequence of BPA treatment.

In the uterus, cystic endometrial hyperplasia was elevated in interim and terminal sacrifice animals in the stop-dose study arm at 25,000 μg BPA/kg bw/day (interim) and at 2,500 and 25,000 μg BPA/kg bw/day (terminal). The incidence in the terminal stop-dose vehicle control was low compared to all other terminal sacrifice groups. An increase in this lesion was not observed in the continuous-dose BPA animals, but did occur at the interim sacrifice with the high dose EE_2_ animals. Uterine squamous metaplasia was also increased in interim stop-dose animals at 25,000 μg BPA/kg bw/day. None of these uterine BPA effects were significant using the CAFE or Poly-3 tests that were considered the primary statistical tests in the study and, in the case of the cystic endometrial hyperplasia, severity was not increased in the treated groups relative to the vehicle control. An increase in squamous metaplasia of the uterus also occurred at the interim sacrifice with the high dose EE_2_ animals. In interim continuous-dose females, there were significant trends for increased apoptosis in luminal epithelial cells of the endometrium and squamous metaplasia, with a statistically significant elevation of the apoptosis at 25,000 μg BPA/kg bw/day. Apoptosis of the endometrial luminal epithelial cells also was significantly increased by the high EE_2_ dose in interim sacrifice animals. Taken together, these data, particularly at the interim sacrifice, suggest that the 25,000 μg BPA/kg bw/day dose may exert weak estrogen-like effects on the uterus.

In the ovary, there were trends in interim sacrifice animals for depletion of corpora lutea and interstitial cell hypertrophy in the continuous-dose arm and a trend and increase in follicular cysts at 25,000 μg BPA/kg bw/day in stop-dose BPA groups. The magnitude of the increase in follicular cysts at the high BPA dose and the trend evident in the two highest BPA groups suggests that this is a treatment-related effect, although the lack of effect on this endpoint in the continuous-dose animals cannot be readily explained. In the ovaries of interim sacrifice high dose EE_2_ females, there was a 100% incidence of cystic follicles.

There was an increasing trend for vaginal epithelial hyperplasia in interim sacrifice continuous BPA dose females with an increased incidence at 25,000 μg BPA/kg bw/day, although not in the primary CAFE test pairwise comparison. Vaginal epithelial hyperplasia was increased to nearly the same magnitude at all doses from 25–25,000 μg BPA/kg bw/day in terminal continuous-dose BPA animals. There were no significant BPA effects on vaginal epithelial hyperplasia in stop-dose animals. A more pronounced increased incidence of vaginal epithelial hyperplasia was also indicated by primary and secondary statistical tests with the interim sacrifice 0.5 μg EE_2_/kg bw/day dose group. This was accompanied by an increased incidence of epithelial mucification in the EE_2_ animals. When considered together with the observations mentioned above on the uterus in continuous-dose animals, the increased vaginal epithelial hyperplasia observed at 25,000 μg BPA/kg bw/day may be a plausible estrogenic effect. The sporadic and inconsistent responses observed at lower BPA doses in the female reproductive tract suggest that they are not of toxicological relevance.

BPA treatment did not have adverse effects on the estrous cycle. In the high dose EE_2_ females, the estrous cycle was disrupted by the time of evaluation at approximately 16-weeks of age and the one-year sacrifice animals showed multiple organ weight changes and histological changes expected of estrogenic stimulation in the ovary, uterus, and vagina. We did not observe an effect of EE_2_ on the time of vaginal opening in the present study. In the previous BPA subchronic study conducted at NCTR,^19^ a delay in the time of vaginal opening was observed with 0.5 μg EE_2_/kg bw/day, with a more pronounced effect at 5 μg EE_2_/kg bw/day. Variable effects on this endpoint depending on timing and dose have been reported in the literature.^66,67^ Disruption of the estrous cycle, as observed in the present study, may be a more sensitive response to early estrogen treatment, as has been reported with a different exposure regimen. Shirota et al.^68^ administered five consecutive daily subcutaneous doses of EE_2_ (0.4 and 2.0 μg/kg bw/day) to female Sprague-Dawley rat pups starting on PND 1 and found no effect on vaginal opening at either dose level, but a disruption of the estrous cycle at later times.

By the secondary statistical tests that include severity scores and incidence, but do not adjust for survival, cardiomyopathy was increased in the stop-dose BPA terminal sacrifice females at 2.5, 250, 2,500, and 25,000 μg BPA/kg bw/day, although background incidence was high at this age. Mean severity scores in the higher treated groups varied from 1.5–1.7, while the vehicle control severity score was 1.3. The percentage of lesions evaluated as mild rather than minimal in these BPA stop-dose groups relative to the controls appears to account for the modest difference in scores, and the percentage of mild diagnoses in the terminal stop-dose controls is lower than the continuous-dose controls or any other terminal sacrifice group. Cardiomyopathy was also increased in the high dose EE_2_ females at both the interim and terminal sacrifices, with all statistical tests indicating a significant increase in the interim sacrifice animals (65% versus 30%, with mean severity of 1.2 versus 1.1). The high background incidence of this lesion at terminal sacrifice and variability in incidence and severity scores across groups make the toxicological significance of these results questionable, with the possible exception of the acceleration of development of the lesion by high dose EE_2_.

For males, there were no significant differences in the incidences of neoplasms in treatment groups versus vehicle controls in any organ in stop-dose or continuous-dose interim or terminal sacrifice males. There were also no treatment-related non-neoplastic effects in stop-dose interim or terminal sacrifice males. An increase in exfoliated germ cells and lymphocyte cellular infiltration in the epididymis at one year in the continuous-dose study arm and hyperplasia in the pars distalis of the pituitary at two years in both continuous- and stop-dose study arms at 25,000 μg BPA/kg bw/day were notable effects in males. Hyperplasia of the pituitary pars distalis was also observed in 0.5 μg EE_2_/kg bw/day terminal sacrifice males. For the epididymal lesions, there were no potentially related lesions noted in the testes to increase confidence in this observation as an effect of toxicological significance.

Other non-neoplastic lesions in males showed variable increases in some dose groups without a pattern in dose response. In the thyroid gland of continuous-dose BPA males at terminal sacrifice, an increase in C-cell hyperplasia was noted at 2,500 μg BPA/kg bw/day, with high variability across dose groups for this endpoint. In addition, TSH levels were not elevated in any BPA dose group. Multiple step sections of the prostate lobes were examined in this study, since prostate has been a target organ identified in the BPA literature. Increases in dorsal/lateral prostate inflammation were variable across a high background in both interim and terminal sacrifice animals. Inflammation in the aging rat prostate is common and has been associated with increasing prolactin levels^44^ and there were no differences between treated groups and vehicle control for hyperplasia or other non-neoplastic lesions observed in the prostate lobes.

As expected from the previous NCTR BPA subchronic study conducted under identical conditions to those reported here,^19^ males were less responsive to EE_2_ than the females. This is consistent with other rat studies (e.g., Howdeshell et al., 2008; Ryan et al., 2010, and references therein).^69,70^ The only significant effect observed in males in the NCTR BPA subchronic study at 0.5 μg EE_2_/kg bw/day was an increase in mammary gland hyperplasia at 90 days of age.^19^ Our previous work with EE_2_ administered in the diet indicated increased mammary gland hyperplasia in young male animals (140 days of age) that ingested a dose approximating the low dose in this study (estimated between 0.5 and 1.0 μg/kg bw/day). An attenuated response was observed in two-year-old animals.^20^ Hence, the lack of an increase of male mammary hyperplasia by EE_2_ in the current study is likely due to the advanced age of animals at examination. In addition, measurements of serum EE_2_ levels at approximate maximum concentration (C_max_) were made at various ages in animals from the NCTR BPA subchronic study.^25^ Like BPA, serum levels of EE_2_ at a given dose level declined with age; that is, peak serum levels after an oral dose of 0.5 μg EE_2_/kg bw were ~500 pM, ~10 pM, and below the LOD of 5 pM on PND 4, 21, and 80, respectively.^25^ Thus, in the present study, although the EE_2_ dosing was continuous throughout the study, the highest internal exposures occurred in preweaning animals. In the case of the low dose, 0.05 μg EE_2_/kg bw/day, serum levels would be expected to be less than 1 pM by the time of weaning.

After the present study began, analysis of samples from a separate study conducted under identical conditions (NCTR BPA subchronic study)^19^ indicated that vehicle controls housed in the same room as animals dosed with ≥100,000 μg BPA/kg bw/day had blood levels of BPA-glucuronide consistent with the lowest exposure dose in the study, which was 2.5 μg/kg bw/day.^25^ Thus, evaluation of treatment effects observed in the subchronic study needed to consider the background exposure to BPA above the dietary exposure of ≤0.25 μg/kg bw/day. Since clear adverse effects occurred only at BPA doses ≥100,000 μg /kg bw/day and there were robust effects of the reference estrogen EE_2_ at doses of 0.5 and 5 μg/kg bw/day, the background BPA exposure was considered to have no impact on the study.^19,71^ It should also be noted that given the presence of variable levels of BPA in commercial diets as discussed earlier, all BPA studies should account for the margin of exposure between the BPA dose levels showing effects and the background level of BPA exposure from the diet.

In the present study, a subset of the animals was housed for a short period early in the study in the same room as animals dosed with 250,000 μg BPA/kg bw/day for a CLARITY-BPA academic grantee study. As discussed in the Statistical Methods section, a conservative approach was taken in this study that assumed all animals that were housed for any period of their lives in the same rooms as the animals dosed with 250,000 μg BPA/kg bw/day were potentially exposed to low levels of BPA above the dietary exposure. An additional statistical analysis excluding these animals, referred to throughout the text as a sensitivity analysis, was conducted for each endpoint. It was reasoned that if inadvertent exposure of vehicle controls to environmental BPA approximately 10-fold higher (i.e., 2.5 μg BPA/kg bw/day) than had been anticipated was masking robust effects of BPA at the lower end of the dose range, this would be detected with the sensitivity analysis. The results of the sensitivity analyses did not show any consistency with respect to tissues or doses in revealing treatment effects not evident in the inclusive analysis and indicated that any inadvertent BPA exposure early in the study had minimal impact on the conclusions derived from the statistical tests.

In conclusion, in the CLARITY-BPA core study, differences between BPA treatment groups, particularly below 25,000 μg BPA/kg bw/day, and the vehicle control group detected by the low-stringency statistical tests applied to histopathology lesions, were not dose responsive, sometimes occurring in only one low or intermediate dose group, and did not demonstrate a clear pattern of consistent responses within or across organs within the stop- and continuous-dose arms and the interim and terminal sacrifices. In contrast, the high EE_2_ dose elicited several strong effects in females in a clearly interpretable and biologically plausible as estrogenic effects. At 25,000 μg BPA/kg bw/day, several observations may be treatment related, including the effects mentioned above in the female reproductive tract (ovary, uterus, and vagina) and in the male pituitary.