# Results

## Gestational Body Weight, Fetal Implantation, and Litter Parameters

Dam body weights during pregnancy were not affected by BPA or EE_2_ treatment (Table 10). The number of implantation sites in mated dams did not differ across BPA or EE_2_ treatment groups and control groups as expected given that treatment did not begin until after implantation. There were no treatment effects on litter size, sex ratio, litter weight by sex, or mean pup weight at birth by sex (Table 11).

Table 10 Dam Body Weights from Time of Mating to Parturition in Vehicle, BPA, and EE_2_ Dose Groups (Mean ± S.E.M.)^a^

Body Weight | Vehicle n = 72 | 2.5 BPA n = 65 | 25 BPA n = 61 | 250 BPA n = 63 | 2500 BPA n = 63 | 25000 BPA n = 64 | 0.05 EE_2_ n = 41 | 0.5 EE_2_ n = 51
Baseline (GD 0/ GD 1), g | 244 ± 3 | 248 ± 3 | 248 ± 4 | 244 ± 3 | 246 ± 3 | 252 ± 4 | 247 ± 4 | 253 ± 4
GD 6, g | 275 ± 3 | 281 ± 4 | 278 ± 4 | 274 ± 4 | 278 ± 3 | 283 ± 4 | 278 ± 5 | 284 ± 4
Parturition, g | 393 ± 4 | 406 ± 5 | 397 ± 6 | 394 ± 5 | 402 ± 5 | 396 ± 5 | 398 ± 6 | 402 ± 6

^a^ Number of dams producing litters given under dose group column headings. Doses of BPA and EE_2_ are μg/kg bw/day.

Gestational weight at parturition was analyzed separately for the BPA and EE_2_ dose groups using ANOCOVA, with terms for treatment group, dam weight at baseline as a covariate, litter size as a covariate, and the interaction between treatment and litter size. Data were collected at baseline on GD 0 or GD 1 and daily from GD 6 to parturition. Gestational weight at parturition was defined as the last dam body weight prior to delivery. Pairwise comparisons of treatment means to the control group were performed using contrasts with Dunnett’s adjustment for multiple comparisons. Tests of trend, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups only. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant results. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). Full results of the statistical analyses are found in Supplemental Appendix XVII.

Table 11 Implantation Sites And Litter Parameters For Vehicle, BPA, And EE_2_ Dose Groups (Mean ± S.E.M)^a^

Endpoint | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
Implantation sites | 12.8 ± 0.5 (78) | 12.4 ± 0.6 (74) | 11.2 ± 0.7 (74) | 11.2 ± 0.6 (78) | 11.6 ± 0.6 (74) | 12.2 ± 0.6 (70) | 11.7 ± 0.8 (49) | 12.1 ± 0.7 (59)
Litter size^b^ | 11.8 ± 0.4 (73) | 12.6 ± 0.3 (65) | 11.9 ± 0.5 (61) | 11.6 ± 0.5 (64) | 12.3 ± 0.4 (64) | 11.5 ± 0.4 (64) | 11.8 ± 0.6 (41) | 12.2 ± 0.4 (51)
Males^b^ | 5.8 ± 0.2 (73) | 6.4 ± 0.3 (65) | 6.2 ± 0.3 (61) | 5.7 ± 0.2 (64) | 6.2 ± 0.3 (64) | 5.5 ± 0.3 (64) | 6.1 ± 0.4 (41) | 5.8 ± 0.3 (51)
Females^b^ | 5.8 ± 0.2 (73) | 6.0 ± 0.3 (65) | 5.6 ± 0.3 (61) | 5.7 ± 0.4 (64) | 5.8 ± 0.3 (64) | 5.8 ± 0.3 (64) | 5.4 ± 0.4 (41) | 6.1 ± 0.3 (51)
Unsexed^c^ | 0.2 ± 0.1 (73) | 0.2 ± 0.1 (65) | 0.1 ± 0 (61) | 0.2 ± 0.1 (64) | 0.3 ± 0.1 (64) | 0.2 ± 0.1 (64) | 0.3 ± 0.2 (41) | 0.3 ± 0.1 (51)
Born dead | 0 ± 0 (73) | 0.08 ± 0.05 (65) | 0.02 ± 0.02 (61) | 0 ± 0 (64) | 0.02 ± 0.02 (64) | 0.02 ± 0.02 (64) | 0 ± 0 (41) | 0.04 ± 0.04 (51)
% Males^d^ | 49.4 ± 1.5 (73) | 51.5 ± 2.3 (65) | 52.2 ± 2.2 (61) | 50.6 ± 2.0 (64) | 50.9 ± 1.8 (64) | 47.3 ± 2.3 (64) | 53.2 ± 2.4 (41) | 48.0 ± 2.1 (51)
% Females^d^ | 49.5 ± 1.5 (73) | 47.0 ± 2.3 (65) | 47.0 ± 2.2 (61) | 47.9 ± 2.1 (64) | 46.7 ± 1.7 (64) | 51.5 ± 2.3 (64) | 44.8 ± 2.2 (41) | 49.6 ± 2.1 (51)
% Unsexed | 1.1 ± 0.4 (73) | 1.6 ± 0.6 (65) | 0.8 ± 0.3 (61) | 1.5 ± 0.7 (64) | 2.3 ± 0.9 (64) | 1.1 ± 0.6 (64) | 1.9 ± 1.1 (41) | 2.4 ± 1.0 (51)
Litter weight, total^e^ | 78.6 ± 2.3 (73) | 80.7 ± 2.6 (62) | 80.2 ± 2.8 (61) | 75.6 ± 2.9 (64) | 78.7 ± 2.4 (63) | 75.3 ± 2.6 (64) | 76.7 ± 3.9 (39) | 78.6 ± 2.9 (50)
Litter weight, males^e^ | 40.1 ± 1.7 (73) | 43.6 ± 2.3 (62) | 43.5 ± 2.2 (61) | 39.1 ± 1.6 (64) | 41.6 ± 1.8 (63) | 38.1 ± 2.0 (64) | 41.8 ± 2.9 (39) | 38.6 ± 2.0 (50)
Litter weight, females^e^ | 38.5 ± 1.6 (73) | 37.2 ± 2.3 (62) | 36.7 ± 2.0 (61) | 36.4 ± 2.2 (64) | 37.0 ± 1.7 (63) | 37.2 ± 1.7 (64) | 34.9 ± 2.4 (39) | 40 ± 2.3 (50)
Mean pup weight^f^ | 7.0 ± 0.1 (73) | 6.8 ± 0.1 (62) | 7.0 ± 0.1 (61) | 6.9 ± 0.1 (64) | 6.9 ± 0.1 (63) | 7.0 ± 0.1 (64) | 6.8 ± 0.1 (39) | 7.0 ± 0.1 (50)
Mean male pup weight^f^ | 7.1 ± 0.1 (73) | 7.0 ± 0.1 (62) | 7.2 ± 0.1 (61) | 7.1 ± 0.1 (64) | 7.0 ± 0.1 (63) | 7.2 ± 0.1 (64) | 7.1 ± 0.1 (39) | 7.2 ± 0.1 (50)
Mean female pup weight^f^ | 6.8 ± 0.1 (73) | 6.6 ± 0.1 (62) | 6.8 ± 0.1 (61) | 6.8 ± 0.1 (64) | 6.7 ± 0.1 (63) | 6.9 ± 0.1 (64) | 6.6 ± 0.1 (39) | 6.9 ± 0.1 (50)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers in parentheses are numbers of dams (for implantation sites) or litters from which data were collected. All analyses and adjustments for multiple comparisons were performed separately for the BPA and EE_2_ treatments. Dunnett’s method was used to adjust for multiple comparisons. Tests of trend, for increasing treatment effect with increasing dose, were performed for the vehicle and BPA groups. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects for any endpoint. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). Full results of the analyses are found in Supplemental Appendices XVIII (implantation sites) and XIX (all other endpoints).

^b^ Litter size (number alive) and numbers of males and females were analyzed using Poisson regression.

^c^ Unsexed pups (i.e., pups that could not be definitively assigned as male or female) were assigned as males for analysis of sex proportions and of female and male counts.

^d^ Sex proportions were analyzed using logistic regression.

^e^ Litter weight data (g), across and by sex, were analyzed using contrasts within a one-way ANOVA to test for treatment effects.

^f^ Litter mean pup weights (g) were analyzed using ANOCOVA, with litter size as a covariate, to test for treatment effects.

## Survival, Preweaning and Postweaning Study Phases

### Preweaning Survival

#### Females

The survival of female pups between PND 1 and PND 21 ranged from 91–95% in vehicle control and BPA dose groups (Table 12). There were no significant BPA treatment effects. The survival of female pups in the 0.05 and 0.5 μg EE_2_/kg bw/day groups was 85% and 91%, respectively. Survival in the lower EE_2_ group was significantly lower than that in the vehicle control group. The study protocol did not call for detailed evaluation of the cause of morbidity/death in pups removed from the study prior to weaning.

Table 12 Survival of Female Pups from PND 1 to Weaning in the Vehicle, BPA, and EE_2_ Dose Groups^a^

Preweaning Females | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
Number of female pups after PND 1 culling | 311 | 266 | 259 | 250 | 260 | 244 | 153 | 180
Dead | 5 | 11 | 7 | 6 | 2 | 3 | 8 | 5
Missing | 3 | 5 | 2 | 5 | 13 | 6 | 5 | 3
Moribund | 1 | 1 | 5 | 4 | 1 | 2 | 2 | 0
Reallocated^b^ | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Pups surviving to weaning | 294 | 241 | 237 | 227 | 236 | 225 | 130 | 164
Percent survival at weaning | 95 | 91 | 92 | 91 | 91 | 92 | 85 | 91
Survival analysis, p-value | 0.361^c^ | 0.245 | 0.280 | 0.245 | 0.245 | 0.313 | 0.005** | 0.369

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups. Female pups removed as dead or moribund were considered uncensored, while pups surviving to weaning were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. Statistically significant effects are indicated by asterisks (**, p < 0.01). There were no additional significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XX.

^b^ The reallocated pups were removed by design on PND 15 for the associated CLARITY-BPA study that will be reported separately.

^c^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

#### Males

The survival of male pups between PND 1 and PND 21 ranged from 91–95% in vehicle control and BPA dose groups (Table 13). There were no significant BPA treatment effects. The survival of male pups in the 0.05 and 0.5 μg EE_2_/kg bw/day groups was 85% and 91%, respectively, and did not differ significantly from the vehicle control. The study protocol did not call for detailed evaluation of the cause of morbidity/death in pups removed from the study prior to weaning.

Table 13 Survival of Male Pups from PND 1 to Weaning in the Vehicle, BPA, and EE_2_ Dose Groups^a^

Preweaning Males | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
Number of male pups after PND 1 culling | 338 | 300 | 281 | 292 | 292 | 275 | 156 | 208
Dead | 5 | 1 | 4 | 8 | 4 | 2 | 8 | 5
Missing | 9 | 14 | 5 | 9 | 6 | 1 | 5 | 6
Moribund | 1 | 3 | 1 | 0 | 1 | 4 | 2 | 0
Reallocated^b^ | 8 | 8 | 8 | 8 | 8 | 8 | 8 | 8
Pups surviving to weaning | 315 | 274 | 263 | 267 | 273 | 260 | 133 | 189
Percent survival at weaning | 93 | 91 | 94 | 91 | 93 | 95 | 85 | 91
Survival analysis, p-value | 0.143^c^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000 | 0.062 | 0.656

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups. Male pups removed as dead or moribund were considered uncensored, while pups surviving to weaning were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XX.

^b^ The reallocated pups were removed by design on PND 15 for the associated CLARITY-BPA study that will be reported separately.

^c^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

### Postweaning Survival in Interim Sacrifice Animals

#### Females, Continuous-Dose Arm

The survival of females dosed daily with vehicle or BPA until the scheduled one-year sacrifice ranged from 91–100% and there were no treatment effects (Table 14). Over the same period, the survival of females in the low and high EE_2_ dose groups was 92 and 100%, respectively, and did not differ from vehicle controls. Causes of morbidity/death in animals that did not survive to the interim sacrifice, when known, are noted in footnotes to Table 14.

Table 14 Survival of Female Pups from Weaning to Interim (1 Year) Sacrifice in the Continuous Vehicle, BPA, and EE_2_ Dose Groups^a^

Interim Sacrifice Females | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_
Females initially allocated for interim evaluation | 23 | 22 | 22 | 24 | 20 | 24 | 26 | 26
Moribund | 1^b^ | 0 | 0 | 2^d^ | 0 | 0 | 1^e^ | 0
Natural deaths | 1^b^ | 0 | 1^c^ | 0 | 0 | 0 | 1^e^ | 0
Animals surviving to scheduled termination | 21 | 22 | 21 | 22 | 20 | 24 | 24 | 26
Percent survival at end of study | 91 | 100 | 95 | 92 | 100 | 100 | 92 | 100
Survival analysis, p-value | 0.470^f^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000 | 0.921 | 0.605

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups for all female pups assigned to the continuously dosed interim sacrifice group at weaning. Female pups removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Since there was 100% survival in both BPA and EE_2_ dose groups, a modified analysis in which one was added to the number of all uncensored observations was conducted to allow estimability. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXI.

^b^ One animal had nephropathy, while the cause of death/morbidity of the second animal was uncertain (Subappendix VI in Supplemental Appendix XXXII).

^c^ Nephropathy was the cause of death (Subappendix VI in Supplemental Appendix XXXII).

^d^ Nephropathy was the cause of death/morbidity in one animal and a mammary fibroadenoma in the second animal (Subappendix VI in Supplemental Appendix XXXII).

^e^ One animal had a mammary adenocarcinoma, while the cause of death/morbidity in the second animal was uncertain (Subappendix VI in Supplemental Appendix XXXII).

^f^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

#### Females, Stop-Dose Arm

In the stop-dose study arm, there was 100% survival in all dose groups of females scheduled for sacrifice at one year, except for the 25,000 μg BPA/kg bw/day dose group where survival was 91% (Table 15). There was no treatment effect. Causes of morbidity/death in animals that did not survive to the interim sacrifice, when known, are noted in footnotes to Table 15.

Table 15 Survival of Female Pups from Weaning to Interim (1 Year) Sacrifice in the Stop-Dose Vehicle and BPA Groups^a^

Interim Sacrifice Females | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Females initially allocated for interim evaluation | 20 | 22 | 20 | 22 | 20 | 22
Moribund | 0 | 0 | 0 | 0 | 0 | 2^b^
Natural deaths | 0 | 0 | 0 | 0 | 0 | 0
Animals surviving to scheduled termination | 20 | 22 | 20 | 22 | 20 | 20
Percent survival at end of study | 100 | 100 | 100 | 100 | 100 | 91
Survival analysis, p-value | 0.455^c^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000

^a^ BPA doses are μg/kg bw/day. Cox proportional hazard analyses were performed for the BPA dose groups for all female pups assigned to the stop-dose interim sacrifice group at weaning. Female pups removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Since there was 100% survival in most dose groups, a modified analysis in which one was added to the number of all uncensored observations was conducted to allow estimability. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXI.

^b^ One animal had nephropathy and the second animal had a malignant meningioma of the cerebellum as the primary cause of morbidity/death (Subappendix VI in Supplemental Appendix XXXII).

^c^ A test of dose trend, increasing treatment effect with increasing dose, was performed and the p-value for the trend analysis is given in the vehicle column; p-values in BPA columns are for pairwise comparisons to the vehicle control.

#### Males, Continuous-Dose Arm

Survival of males dosed daily with vehicle or various BPA doses until the scheduled one-year sacrifice ranged from 82–100%, with the lowest percent survival seen in the vehicle control group (Table 16). There were no significant treatment effects on survival after this one-year exposure. Over the same period, the survival of males in the low and high EE_2_ dose groups was 85 and 88%, respectively, and did not differ significantly from vehicle controls. Causes of morbidity/death in animals that did not survive to the interim sacrifice, when known, are noted in footnotes to Table 16.

Table 16 Survival of Male Pups from Weaning to Interim (1 Year) Sacrifice in the Continuous Vehicle, BPA, and EE_2_ Dose Groups^a^

Interim Sacrifice Males | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
Males initially allocated for interim evaluation | 22 | 22 | 20 | 24 | 20 | 22 | 26 | 26
Moribund | 4^b^ | 0 | 1^c^ | 0 | 0 | 0 | 2^e^ | 0
Natural deaths | 0 | 0 | 1^c^ | 0 | 2^d^ | 1^d^ | 2^e^ | 3^d^
Animals surviving to scheduled termination | 18 | 22 | 18 | 24 | 18 | 21 | 22 | 23
Percent survival at end of study | 82 | 100 | 90 | 100 | 90 | 95 | 85 | 88
Survival analysis, p-value | 0.666^f^ | 0.597 | 1.000 | 0.597 | 1.000 | 0.789 | 1.000 | 1.000

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups for all male pups assigned to the continuously dosed interim sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Since there was 100% survival in some of the BPA dose groups, a modified analysis in which one was added to the number of all uncensored observations was conducted to allow estimability. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXI.

^b^ Two animals had malignant lymphomas in their spleens, while the cause of death could not be determined for 2 animals (Subappendix VI in Supplemental Appendix XXXII).

^c^ One animal had a perforated esophagus and another had a hemorrhaged lung (Subappendix VI in Supplemental Appendix XXXII).

^d^ Cause of death/morbidity was uncertain (Subappendix VI in Supplemental Appendix XXXII).

^e^ One animal had nephropathy, one animal was removed due to an abscessed skin wound, and the cause of death/morbidity for two animals was uncertain (Subappendix VI in Supplemental Appendix XXXII).

^f^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

#### Males, Stop-Dose Arm

In the stop-dose study arm, there was 100% survival in males of all BPA dose groups sacrificed at one year, except for the 25 μg BPA/kg bw/day dose group where survival was 95% (Table 17). There was no treatment effect. The cause of death in the one animal in the 25 μg BPA/kg bw/day dose group that died early was uncertain (Supplemental Appendix XXXII, Subappendix VI).

Table 17 Survival of Male Pups from Weaning to Interim (1 Year) Sacrifice in the Stop-Dose Vehicle and BPA Groups^a^

Interim Sacrifice Males | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Males initially allocated for interim evaluation | 20 | 20 | 20 | 19 | 20 | 22
Moribund | 0 | 0 | 0 | 0 | 0 | 0
Natural deaths | 0 | 0 | 1^b^ | 0 | 0 | 0
Animals surviving to scheduled termination | 20 | 20 | 19 | 19 | 20 | 22
Percent survival at end of study | 100 | 100 | 95 | 100 | 100 | 100
Survival analysis, p-value | 0.927^c^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000

^a^ BPA doses are μg/kg bw/day. Cox proportional hazard analyses were performed for the BPA dose groups for all male pups assigned to the stop-dose interim sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Since there was 100% survival in some dose groups, a modified analysis in which one was added to the number of all uncensored observations was conducted to allow estimability. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXI.

^b^ Cause of death/morbidity was uncertain (Subappendix VI in Supplemental Appendix XXXII).

^c^ A test of dose trend, increasing treatment effect with increasing dose, was performed and the p-value for the trend analysis is given in the vehicle column; p-values in BPA columns are for pairwise comparisons to the vehicle control.

### Postweaning Survival in Terminal Sacrifice Animals

#### Females, Continuous-Dose Arm

The Kaplan-Meier survival curves for females dosed daily with the vehicle or BPA, or with the vehicle or EE_2_, until sacrifice at two years are shown in Figure 2 and Figure 3, respectively. Data and analysis results are shown in Table 18. Survival at the end of the study in the BPA dose groups ranged from 17–40%. Survival in the low and high EE_2_ dose groups was 27 and 15%, respectively. No significant treatment effects were seen for this chronic exposure to BPA or EE_2_ at the doses administered. Most of the animals that did not survive until the terminal sacrifice were removed as moribund between one and two years of age. Causes of death/morbidity are listed in an appendix to the pathology report (Supplemental Appendix XXXII, Subappendix VI); mammary gland fibroadenomas and pituitary adenomas accounted for most of the early removals.

Figure 2

Kaplan-Meier Survival Curve for Terminal Sacrifice Female BPA Continuous-Dose Arm (Weeks 4–104)

See Table 18 for data analysis results.

Figure 3

Kaplan-Meier Survival Curve for Terminal Sacrifice Female EE2 Continuous-Dose Arm (Weeks 4–104)

See Table 18 for data analysis results.

Table 18 Survival of Female Pups from Weaning to Terminal (2 Year) Sacrifice in the Continuous Vehicle, BPA, and EE_2_ Dose Groups^a^

Terminal Sacrifice Females | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_
Females initially allocated for terminal evaluation | 50 | 48 | 46 | 49 | 50 | 46 | 26 | 26
Moribund | 28 | 28 | 31 | 31 | 33 | 35 | 18 | 18
Natural deaths | 6 | 1 | 1 | 5 | 7 | 3 | 1 | 4
Animals surviving to scheduled termination | 16 | 19 | 14 | 13 | 10 | 8 | 7 | 4
Percent survival at end of study | 32 | 40 | 30 | 27 | 20 | 17 | 27 | 15
Survival analysis, p-value | 0.071^b^ | 1.000 | 1.000 | 1.000 | 0.502 | 1.000 | 0.396 | 0.188

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups for all female pups assigned to the continuously dosed terminal sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXII.

^b^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

#### Females, Stop-Dose Arm

The Kaplan-Meier survival curves for females in the vehicle control or BPA two-year stop-dose arm are shown in Figure 4. Data and analysis results are shown in Table 19. Survival at the end of the study in the BPA dose groups ranged from 24-34%; survival in the vehicle control group was 22%. There were no significant treatment effects in female rats after only gestational and preweaning exposure to BPA. Most animals that did not survive until the terminal sacrifice were removed as moribund between one and two years of age. Causes of death/morbidity are listed in an appendix to the pathology report (Supplemental Appendix XXXII, Subappendix VI); as was the case in the two-year continuous-dose arm females, mammary gland fibroadenomas and pituitary adenomas accounted for most of the early removals.

Figure 4

Kaplan-Meier Survival Curve for Terminal Sacrifice Female BPA Stop-Dose Arm (Week 4–104)

See Table 19 for data analysis results.

Table 19 Survival of Female Pups from Weaning to Terminal (2 Year) Sacrifice in the Stop-Dose Vehicle and BPA Groups^a^

Terminal Sacrifice Females | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Females initially allocated for terminal evaluation | 50 | 50 | 48 | 50 | 50 | 46
Moribund | 36 | 32 | 32 | 35 | 30 | 31
Natural deaths | 3 | 6 | 3 | 2 | 3 | 2
Animals surviving to scheduled termination | 11 | 12 | 13 | 13 | 17 | 13
Percent survival at end of study | 22 | 24 | 27 | 26 | 34 | 28
Survival analysis, p-value | 0.203^b^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000

^a^ BPA doses are μg/kg bw/day. Cox proportional hazard analyses were performed for the BPA dose groups for all female pups assigned to the stop-dose interim sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXII.

^b^ A test of dose trend, increasing treatment effect with increasing dose, was performed and the p-value for the trend analysis is given in the vehicle column; p-values in BPA columns are for pairwise comparisons to the vehicle control.

#### Males, Continuous-Dose Arm

The Kaplan-Meier survival curves for males dosed daily with vehicle or BPA, or with vehicle or EE_2_, until sacrifice at two years are shown in Figure 5 and Figure 6, respectively. Data and analysis results are shown in Table 20. Survival at the end of the study in the BPA dose groups ranged from 24–35%. Survival in the low and high EE_2_ dose groups was 35 and 46%, respectively. There were no significant treatment effects. Most animals that did not survive until the terminal sacrifice were removed as moribund between one and two years of age. Causes of death/morbidity are listed in an appendix to the pathology report (Supplemental Appendix XXXII, Subappendix VI). Many primary and contributory conditions in various organs were diagnosed, with pituitary adenomas, nephropathy, preputial gland carcinoma, and malignant lymphoma indicated as primary causes of death/morbidity in multiple animals across all dose groups.

Figure 5

Kaplan-Meier Survival Curve for Terminal Sacrifice Male BPA Continuous-Dose Arm (Weeks 4–104)

See Table 20 for data analysis results.

Figure 6

Kaplan-Meier Survival Curve for Terminal Sacrifice Male EE_2_ Continuous-Dose Arm (Weeks 4–104)

See Table 20 for data analysis results.

Table 20 Survival of Male Pups from Weaning to Terminal (2 Year) Sacrifice in the Continuous Vehicle, BPA, and EE_2_ Dose Groups^a^

Terminal Sacrifice Males | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_
Males initially allocated for terminal evaluation | 50 | 48 | 48 | 50 | 50 | 46 | 26 | 26
Moribund | 24 | 16 | 27 | 21 | 24 | 27 | 14 | 10
Natural deaths | 11 | 16 | 4 | 15 | 10 | 8 | 3 | 4
Animals surviving to scheduled termination | 15 | 16 | 17 | 14 | 16 | 11 | 9 | 12
Percent survival at end of study | 30 | 33 | 35 | 28 | 32 | 24 | 35 | 46
Survival analysis, p-value | 0.327^b^ | 1.000 | 1.000 | 1.000 | 1.000 | 1.000 | 0.879 | 0.419

^a^ BPA and EE_2_ doses are μg/kg bw/day. Cox proportional hazard analyses were performed separately for the BPA and EE_2_ dose groups for all male pups assigned to the continuously dosed terminal sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint, including is found in Supplemental Appendix XXII.

^b^ A test of dose trend, increasing treatment effect with increasing dose, was performed for vehicle and BPA groups only. The p-value for the trend analysis is given in the vehicle column; p-values in BPA and EE_2_ columns are for pairwise comparisons to the vehicle control.

#### Males, Stop-Dose Arm

The Kaplan-Meier survival curves for males in the vehicle control or BPA two-year stop-dose arm are shown in Figure 7. Data and analysis results are shown in Table 21. Survival at the end of the study in the BPA dose groups ranged from 20–33% in comparison to the 34% survival seen in the vehicle controls. There were no significant treatment effects. Most animals that did not survive until the terminal sacrifice were removed as moribund between one and two years of age. Causes of death/morbidity are listed in an appendix to the pathology report (Supplemental Appendix XXXII, Subappendix VI) and were similar to those diagnosed for the continuous-dose arm males.

Figure 7

Kaplan-Meier Survival Curve for Terminal Sacrifice Male BPA Stop-Dose Arm (Week 4–104)

See Table 21 for data analysis results.

Table 21 Survival of Male Pups from Weaning to Terminal (2 Year) Sacrifice in the Stop-Dose Vehicle and BPA Groups^a^

Terminal Sacrifice Males | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Males initially allocated for terminal evaluation | 50 | 48 | 48 | 50 | 50 | 46
Moribund | 20 | 20 | 24 | 29 | 27 | 29
Natural deaths | 13 | 12 | 8 | 8 | 8 | 8
Animals surviving to scheduled termination | 17 | 16 | 16 | 13 | 15 | 9
Percent survival at end of study | 34 | 33 | 33 | 26 | 30 | 20
Survival analysis, p-value | 0.053^b^ | 1.000 | 1.000 | 0.424 | 1.000 | 0.209

^a^ BPA doses are μg/kg bw/day. Cox proportional hazard analyses were performed for the BPA dose groups for all male pups assigned to the stop-dose interim sacrifice group at weaning. Animals removed as dead or moribund were considered uncensored, while animals surviving to scheduled removal were considered censored. Multiple comparisons of treatments to the vehicle control were adjusted using Holm’s method. All tests were performed as two-sided tests at the 0.05 significance level. There were no statistically significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods). The full statistical report for this endpoint is found in Supplemental Appendix XXII.

^b^ A test of dose trend, increasing treatment effect with increasing dose, was performed and the p-value for the trend analysis is given in the vehicle column; p-values in BPA columns are for pairwise comparisons to the vehicle control.

## Body Weights

### Body Weights in Preweaning Animals

#### Females

Body weights on PNDs 1, 4, 7, 14, and 21 in female pups treated daily with vehicle, BPA, or EE_2_ are shown in Table 22. There were no BPA treatment-related effects on female pup body weights at these time points. On PNDs 4 and 7, the low EE_2_ dose group females had significantly lower mean body weight than vehicle controls, with body weights in the treated animals approximately 5% lower than controls on both days. At PND 4, both the 2.5 μg BPA/kg bw/day and the 0.05 μg EE_2_/bw/day dose groups had identical means and standard errors, but only the latter was statistically significant, suggesting that the smaller sample size in that group contributed to this marginal difference.

Table 22 Prewean Body Weights (g) of Female Pups in the Vehicle, BPA, and EE_2_ Dose Groups (Mean ± S.E.M.)^a^

Postnatal Day | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
1 | 6.8 ± 0.1 (71) | 6.7 ± 0.1 (60) | 6.8 ± 0.1 (57) | 6.8 ± 0.1 (58) | 6.7 ± 0.1 (59) | 6.8 ± 0.1 (59) | 6.6 ± 0.1 (34) | 6.9 ± 0.1 (47)
4 | 10.6 ± 0.1 (71) | 10.1 ± 0.2 (59) | 10.5 ± 0.2 (57) | 10.4 ± 0.1 (58) | 10.3 ± 0.2 (58) | 10.4 ± 0.2 (59) | 10.1 ± 0.2* (34) | 10.9 ± 0.2 (47)
7 | 15.8 ± 0.2 (71) | 15.2 ± 0.2 (59) | 15.6 ± 0.2 (57) | 15.3 ± 0.2 (58) | 15.1 ± 0.3 (58) | 15.4 ± 0.2 (59) | 15.0 ± 0.3* (34) | 16.0 ± 0.3 (47)
14 | 30.6 ± 0.4 (71) | 30.1 ± 0.4 (59) | 30.9 ± 0.4 (57) | 30.0 ± 0.4 (58) | 29.6 ± 0.4 (58) | 29.9 ± 0.4 (59) | 29.9 ± 0.6 (34) | 31.4 ± 0.4 (47)
21 | 50.1 ± 0.6 (70) | 49.5 ± 0.7 (56) | 50.6 ± 0.6 (55) | 49.2 ± 0.7 (56) | 48.6 ± 0.7 (56) | 49.1 ± 0.6 (57) | 50.2 ± 0.9 (33) | 51.9 ± 0.7 (47)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Analysis was performed using contrasts within sex- and PND-stratified one-way repeated measures, mixed model ANOVA to test for treatment effects accounting for litter correlation assuming a compound symmetric correlation structure. Pairwise comparisons of treatment group means to the vehicle control group mean were performed using contrasts with Dunnett’s method of adjustment for multiple comparisons separately for BPA and EE_2_ groups. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and control groups. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIII. Values that are significantly different from the vehicle control are indicated with an asterisk (*, p < 0.05). There were no additional significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

#### Males

Body weights on PNDs 1, 4, 7, 14, and 21 in male pups treated daily with vehicle, BPA, or EE_2_ are shown in Table 23. There were no BPA or EE_2_ treatment-related effects on male pup body weights at these time points.

Table 23 Prewean Body Weights (g) of Male Pups in the Vehicle, BPA, and EE_2_ Dose Groups (Mean ± S.E.M.)^a^

Postnatal Day | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
1 | 7.2 ± 0.1 (71) | 7.1 ± 0.1 (60) | 7.3 ± 0.1 (57) | 7.2 ± 0.1 (59) | 7.1 ± 0.1 (60) | 7.3 ± 0.1 (60) | 7.0 ± 0.1 (32) | 7.2 ± 0.1 (49)
4 | 11.4 ± 0.2 (71) | 11 ± 0.1 (59) | 11.4 ± 0.2 (57) | 11.2 ± 0.2 (58) | 10.9 ± 0.2 (59) | 11.4 ± 0.2 (60) | 10.8 ± 0.2 (32) | 11.3 ± 0.2 (48)
7 | 16.9 ± 0.2 (71) | 16.4 ± 0.2 (59) | 16.8 ± 0.3 (57) | 16.4 ± 0.2 (58) | 16.2 ± 0.3 (59) | 16.7 ± 0.2 (60) | 16.1 ± 0.4 (32) | 16.6 ± 0.3 (48)
14 | 32.3 ± 0.4 (71) | 31.7 ± 0.4 (59) | 32.4 ± 0.4 (57) | 31.5 ± 0.4 (58) | 31.3 ± 0.4 (59) | 31.7 ± 0.4 (60) | 31.8 ± 0.6 (32) | 32.5 ±0.5 (48)
21 | 53.0 ± 0.6 (70) | 52.2 ± 0.6 (58) | 53.6 ± 0.6 (56) | 51.8 ± 0.7 (58) | 51.5 ± 0.7 (59) | 52.4 ± 0.7 (59) | 53.0 ± 1.0 (32) | 54.0 ± 0.8 (47)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Analysis was performed using contrasts within sex- and PND-stratified one-way repeated measures, mixed model ANOVA to test for treatment effects accounting for litter correlation assuming a compound symmetric correlation structure. Pairwise comparisons of treatment group means to the vehicle control group mean were performed using contrasts with Dunnett’s method of adjustment for multiple comparisons separately for BPA and EE_2_ groups. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and control groups. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIII. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

### Body Weights in Interim and Terminal Sacrifice Animals

#### Females, Continuous-Dose Arm

Body weights of females in the continuous vehicle control and BPA groups scheduled for the interim sacrifice are shown in Figure 8 and Table 24. The data for the EE_2_ groups are also tabulated in Table 24 and are shown graphically in Figure 9. There were no significant differences from the vehicle controls in any of the BPA or EE_2_ dose groups. The mean body weights in the 2.5 μg BPA/kg bw/day group in weeks 36–52 were 10–13% higher than vehicle control means; however, these differences were not statistically significant.

Figure 8

Body Weight for Interim Sacrifice Female BPA Continuous-Dose Arm

Data tabulated in Table 24.

Figure 9

Body Weight for Interim Sacrifice Female EE_2_ Continuous-Dose Arm

Data tabulated in Table 24.

Body weights of females in the continuous vehicle control, BPA, and EE_2_ dose groups scheduled for the terminal sacrifice are shown in Table 25 and in Figure 10 and Figure 11 for BPA and EE_2_, respectively. Mean body weights of females in the 250 μg BPA/kg bw/day dose group were significantly higher by 16−18% than those of the vehicle control group for weeks 96–104. In this same period, the mean body weights of females in the 2.5 and 25 μg BPA/kg bw/day dose groups were 11–16% higher than those of vehicle controls, but these differences were not significant. Animals in the 2.5 μg BPA/kg bw/day dose group did not have higher mean body weights than vehicle controls in the earlier weeks noted above for interim sacrifice animals. In the terminal sacrifice high EE_2_ dose group, transiently higher mean body weights were observed at 4 and 8 weeks (7% and 8%, respectively). The same tendency in the high EE_2_ dose group was seen in the interim sacrifice animals at 4 and 8 weeks, although the differences in mean body weights were not statistically significant.

Figure 10

Body Weight for Terminal Sacrifice Female BPA Continuous-Dose Arm

Data tabulated in Table 25.

Figure 11

Body Weight for Terminal Sacrifice Female EE_2_ Continuous-Dose Arm

Data tabulated in Table 25.

#### Females, Stop-Dose Arm

Body weights of females in the vehicle control and BPA stop-dose groups scheduled for the interim sacrifice are shown in Table 26 and Figure 12. There were no significant treatment effects. In the stop-dose females scheduled for terminal sacrifice (Table 27 and Figure 13), there was a significant decreasing trend at week 4, but no other treatment effects. Although statistical comparisons were not conducted between continuous- and stop-dose arms, the stop-dose arm females had higher mean weights over the course of the study (vehicle controls, mean stop-dose compared to continuous-dose: interim, 104%, range 98–109% from weeks 8–52; terminal, 107%, range 97–114% from weeks 8–104).

Figure 12

Body Weight for Interim Sacrifice Female BPA Stop-Dose Arm

Data tabulated in Table 26.

Figure 13

Body Weight for Terminal Sacrifice Female BPA Stop-Dose Arm

Data tabulated in Table 27.

#### Males, Continuous-Dose Arm

Body weights of the continuously dosed males in the vehicle control, BPA, and EE_2_ groups for interim and terminal sacrifices are shown in Table 28 and Table 29, respectively. The growth curves for interim BPA and EE_2_ dose groups are shown in Figure 14 and Figure 15, respectively, and the growth curves for terminal BPA and EE_2_ dose groups are shown in Figure 16 and Figure 17, respectively. There were no significant treatment effects for either compound, although means were 10–16% higher than vehicle control means in the 250 μg BPA/kg bw/day dose group from weeks 92 through 104.

Figure 14

Body Weight for Interim Sacrifice Male BPA Continuous-Dose Arm

Data tabulated in Table 28.

Figure 15

Body Weight for Interim Sacrifice Male EE_2_ Continuous-Dose Arm

Data tabulated in Table 28.

Figure 16

Body Weight for Terminal Sacrifice Male BPA Continuous-Dose Arm

Data tabulated in Table 29.

Figure 17

Body Weight for Terminal Sacrifice Male EE_2_ Continuous-Dose Arm

Data tabulated in Table 29.

#### Males, Stop-Dose Arm

Mean body weights of the stop-dose arm vehicle control and BPA groups of male rats for interim and terminal sacrifices are shown in Table 30 and Table 31 and graphically depicted in Figure 18 and Figure 19, respectively. The sole statistically significant treatment effect was a decreasing dose trend at week 4 in the terminal sacrifice animals (Table 31). Although statistical comparisons were not conducted between continuous- and stop-dose arms, the stop-dose arm males had higher mean weights over the course of the study (vehicle controls, mean stop-dose compared to continuous-dose: interim, 102%, range 92–105% from weeks 8–52; terminal, 107%, range 92–113% from weeks 8–104).

Figure 18

Body Weight for Interim Sacrifice Male BPA Stop-Dose Arm

Data tabulated in Table 30.

Figure 19

Body Weight for Terminal Sacrifice Male BPA Stop-Dose Arm

Data tabulated in Table 31.

## Vaginal Opening

Female pups were evaluated for vaginal opening starting on PND 22. Mean age and body weight at vaginal opening for continuous-dose vehicle control, BPA, and EE_2_ dose groups are shown in Table 32. There were no treatment-related effects on these endpoints for any dose of either compound. For stop-dose vehicle control and BPA groups, mean age at vaginal opening is shown in Table 33. No treatment effects were observed in the stop-dose BPA groups. Body weight at vaginal opening could not be analyzed for the stop-dose animals because weight at vaginal opening was not recorded for many of the animals due to a technical error (Supplemental Appendix II, deviations 72–74). While no formal analysis was conducted comparing vehicle controls in the continuous- and stop-dose arms, the mean vaginal opening date appears to be later regardless of BPA treatment in the stop-dose groups.

Table 32 Vaginal Opening, Age and Body Weight (Means ± S.E.M.) at Occurrence, Vehicle, BPA, and EE_2_ Continuous-Dose^a^

Endpoint | Vehicle (26)^b^ | 2.5 BPA (25) | 25 BPA (24) | 250 BPA (25) | 2500 BPA (25) | 25000 BPA (24) | 0.05 EE_2_ (25) | 0.5 EE_2_ (21)
Age, days | 35.9 ± 1.1 | 35.2 ± 0.7 | 36.5 ± 0.8 | 37.8 ± 1.4 | 34.1 ± 0.5 | 35.4 ± 0.6 | 35.5 ± 0.7 | 34.8 ± 2.8
Body weight, g | 120.5 ± 4.6 | 117.1 ± 5.0 | 128.6 ± 4.6 | 131.1 ± 5.8 | 109.6 ± 2.6 | 121.0 ± 4.3 | 123.0 ± 4.8 | 117.1 ± 11.8

^a^ BPA and EE_2_ doses are μg/kg bw/day. Twenty-six females (13 cages) from the 2-year continuous-dose groups were scheduled to be assessed for age and weight at vaginal opening and undergo vaginal cytology later in the study to evaluate estrous cyclicity. There were no litter mates among these animals. Several dose groups have less than 26 animals due to either failure to record the information or delayed start of monitoring for vaginal opening. These incidents were documented in protocol deviations. BPA and EE_2_ dose groups were analyzed separately. Analyses were performed using contrasts within a one-way ANOVA to test for treatment effect. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Comparisons of dosed groups to vehicle control for age and body weight were performed with Dunnett’s method for adjusted contrasts. All tests were performed as two-sided tests at the 0.05 significance level. The full statistical report is found in Supplemental Appendix XXVI. There were no statistically significant treatment effects. There were no additional significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

^b^ Numbers in parentheses are the number of animals examined.

Table 33 Vaginal Opening, Age and Body Weight (Means ± S.E.M.) at Occurrence, Vehicle and BPA Stop-Dose^a^

Endpoint | Vehicle (26)^b^ | 2.5 BPA (26) | 25 BPA (25) | 250 BPA (26) | 2500 BPA (26) | 25000 BPA (26)
Age, days | 41.1 ± 1.8 | 42.1 ± 2.5 | 40.0 ± 1.5 | 39.6 ± 1.2 | 42.4 ± 1.2 | 38.0 ± 1.3
Body weight, g | – | – | – | – | – | –

^a^ BPA doses are μg/kg bw/day. Twenty-six females (13 cages) from the 2-year stop-dose groups were scheduled to be assessed for age and weight at vaginal opening and undergo vaginal cytology later in the study to evaluate estrous cyclicity. There were no litter mates among these animals. The 25 μg BPA/kg bw/day dose group had one animal for which the date of vaginal opening was not recorded. Due to a technical error, 31 animals in the stop-dose arm did not have body weights recorded on the day of vaginal opening and thus this endpoint was not analyzed (Supplemental Appendix II, protocol deviations #72–74). Analysis was performed using contrasts within a one-way ANOVA to test for treatment effect. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Comparisons of dosed groups to vehicle control for age and body weight were performed with Dunnett’s method for adjusted contrasts. All tests were performed as two-sided tests at the 0.05 significance level. The full statistical report is found in Supplemental Appendix XXVI. There were no statistically significant treatment effects. There were no additional significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

^b^ Numbers in parentheses are the number of animals examined.

## Vaginal Cytology – Estrous Cycle Analysis at Approximately 16 Weeks of Age

### Continuous-Dose Arm

Data and results of analysis of the 14 consecutive daily vaginal smears collected from animals in the continuous-dose arm at 16 ± 2 weeks of age are summarized in Table 34. The individual animal data are found in the statistical report in Supplemental Appendix XXVII. There were no significant differences from the vehicle control among the continuous BPA dose groups. The high EE_2_ dose had a highly significant effect on the estrous cycle, with 96% of the animals showing extended estrus as compared to 12% of the vehicle controls (Table 34). When all types of abnormal cycles were considered, 100% of the high EE_2_ dose group animals showed abnormal cycles compared to 27% of the vehicle controls.

Table 34 Estrous Cycle Analysis, Vehicle, BPA, and EE_2_ Continuous-Dose^a^

Endpoint | Vehicle (26)^b^ | 2.5 BPA (25) | 25 BPA (26) | 250 BPA (25) | 2500 BPA (26) | 25000 BPA (25) | 0.05 EE_2_ (26) | 0.5 EE_2_ (26)
# readable smears | 362 | 348 | 359 | 348 | 362 | 348 | 363 | 361
% Diestrus | 57.7 | 54.0 | 55.2 | 49.4 | 59.9 | 55.7 | 54.3 | 15.5
% Proestrus | 13.8 | 14.9 | 11.1 | 17.2 | 13.8 | 12.6 | 11.0 | 0.8
% Estrus | 28.5 | 31.0 | 33.7 | 33.3 | 26.2 | 31.6 | 34.7 | 83.7
Cycle length, days^c^ | 4.37 ± 0.18^d^ | 4.56 ± 0.29^d^ | 4.47 ± 0.21^e^ | 5.20 ± 0.51^e^ | 4.33 ± 0.15^e^ | 4.84 ± 0.31^f^ | 4.72 ± 0.33^d^ | 5.58 ± 0.64^g^
Abnormal Diestrus^h^
Abnormal | 4 | 2 | 4 | 1 | 4 | 5 | 6 | 2
Normal | 22 | 23 | 22 | 24 | 22 | 20 | 20 | 24
% Abnormal | 15.4 | 8.0 | 15.4 | 4.0 | 15.4 | 20.0 | 23.1 | 7.7
Abnormal Estrus^h^
Abnormal | 3 | 3 | 4 | 4 | 2 | 4 | 4 | 25
Normal | 23 | 22 | 22 | 21 | 24 | 21 | 22 | 1
% Abnormal | 11.5 | 12.0 | 15.4 | 16.0 | 7.7 | 16.0 | 15.4 | 96.2***
Abnormal Proestrus^h^
Abnormal | 0 | 0 | 0 | 1 | 1 | 1 | 0 | 0
Normal | 26 | 25 | 26 | 24 | 25 | 24 | 26 | 26
% Abnormal | 0 | 0 | 0 | 4.0 | 3.8 | 4.0 | 0 | 0
Combined Abnormal
Abnormal | 7 | 5 | 8 | 5 | 7 | 9 | 10 | 26
Normal | 19 | 20 | 18 | 20 | 19 | 16 | 16 | 0
% Abnormal | 26.9 | 20.0 | 30.8 | 20.0 | 26.9 | 36.0 | 38.5 | 100***

^a^ BPA and EE_2_ doses are μg/kg bw/day. At 16 ± 2 weeks, daily vaginal smears were collected for 14 consecutive days from 26 animals (13 cages) assigned to the continuous-dose study arm, two-year sacrifice. There were no litter mates among the animals.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ Cycle length: first day of estrus in one sequence of contiguous days to the first day of estrus in the following sequence of stages. For cycle length, cycle days were defined from the first day of estrus in one sequence of contiguous days to the first day of estrus in the following sequence of stages. Cycles were considered censored if the last stage of data collection was either diestrus or proestrus. The number of animals, n, for this endpoint includes all animals with at least one uncensored cycle.

^d^ n = 23.

^e^ n = 24.

^f^ n = 22.

^g^ n = 12.

^h^ Abnormal (extended) diestrus was defined as four or more consecutive days of diestrus; abnormal estrus was defined as three or more consecutive days of estrus; and extended proestrus was defined as two or more consecutive days of proestrus. The Cochran-Armitage trend test (one-sided) was performed, and Fisher’s exact test (two-sided) was conducted for comparisons of dosed groups to control. P-values for pairwise comparisons were corrected using Holm’s method, and unadjusted p-values are also presented in the full statistical report (Supplemental Appendix XXVII). BPA and EE_2_ dose groups were analyzed separately. Statistically significant treatment effects are shown with asterisks and were confined to the high EE_2_ dose group; ***, p < 0.001. There were no additional significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

### Stop-Dose Arm

There were no BPA treatment-related effects on the estrous cycle in the stop-dose animals (Table 35). The individual animal data are found in the statistical report in Supplemental Appendix XXVII.

Table 35 Estrous Cycle Analysis, Vehicle and BPA Stop-Dose^a^

Endpoint | Vehicle (26)^b^ | 2.5 BPA (26) | 25 BPA (26) | 250 BPA (26) | 2500 BPA (26) | 25000 BPA (26)
# readable smears | 360 | 360 | 361 | 363 | 362 | 359
% Diestrus | 56.4 | 60.3 | 52.4 | 51.2 | 58.3 | 58.8
% Proestrus | 13.1 | 9.2 | 14.4 | 15.2 | 13.8 | 10.3
% Estrus | 30.6 | 30.6 | 33.2 | 33.6 | 27.9 | 30.9
Cycle length, days^c^ | 4.08 ± 0.12^d^ | 4.23 ± 0.13^e^ | 4.17 ± 0.12^f^ | 4.47 ± 0.23^g^ | 4.42 ± 0.15 | 4.38 ± 0.17^h^
Abnormal Diestrus^i^
Abnormal | 5 | 5 | 2 | 1 | 4 | 5
Normal | 21 | 21 | 24 | 25 | 22 | 21
% Abnormal | 19.2 | 19.2 | 7.7 | 3.8 | 15.4 | 19.2
Abnormal Estrus^i^
Abnormal | 5 | 2 | 3 | 5 | 2 | 3
Normal | 21 | 24 | 23 | 21 | 24 | 23
% Abnormal | 19.2 | 7.7 | 11.5 | 19.2 | 7.7 | 11.5
Abnormal Proestrus^i^
Abnormal | 2 | 1 | 1 | 0 | 0 | 0
Normal | 24 | 25 | 25 | 26 | 26 | 26
% Abnormal | 7.7 | 3.8 | 3.8 | 0 | 0 | 0
Combined Abnormal
Abnormal | 10 | 7 | 5 | 6 | 6 | 8
Normal | 16 | 19 | 21 | 20 | 20 | 18
% Abnormal | 38.5 | 26.9 | 19.2^j^ | 23.1 | 23.1 | 30.8

^a^ BPA doses are μg/kg bw/day. At 16 ± 2 weeks, daily vaginal smears were collected for 14 consecutive days from 26 animals (13 cages) assigned to the stop-dose study arm, two-year sacrifice. There were no litter mates among the animals.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ Cycle length: first day of estrus in one sequence of contiguous days to the first day of estrus in the following sequence of stages. For cycle length, cycle days were defined from the first day of estrus in one sequence of contiguous days to the first day of estrus in the following sequence of stages. Cycles were considered censored if the last stage of data collection was either diestrus or proestrus. The number of animals, n, for this endpoint includes all animals with at least one uncensored cycle.

^d^ n = 20.

^e^ n = 22.

^f^ n = 23.

^g^ n = 25.

^h^ n = 24.

^i^ Abnormal (extended) diestrus was defined as four or more consecutive days of diestrus; abnormal estrus was defined as three or more consecutive days of estrus; and extended proestrus was defined as two or more consecutive days of proestrus. The Cochran-Armitage trend test (one-sided) was performed, and Fisher’s exact test (two-sided) was conducted for comparisons of dosed groups to control. P-values for pairwise comparisons were corrected using Holm’s method, and unadjusted p-values are also presented in the full statistical report (Supplemental Appendix XXVII). There were no statistically significant treatment effects.

^j^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods), there was a significant difference for combined abnormal for BPA stop-dose 25 μg/kg bw/day compared to the vehicle control group (p = 0.038). The proportion of total % abnormal in the 25 μg BPA/kg bw/day stop-dose group was lower than in the vehicle control (5.0% abnormal in the dosed group compared to 33.3% abnormal in the control).

## Vaginal Cytology – Onset of Aberrant Estrous Cycles in Aging Animals

### Continuous-Dose Arm

The time of onset of aberrant estrous cycles in aging females was estimated by evaluating five consecutive vaginal smears every month (see Materials and Methods and legend to Table 36). The data for the animals in the continuous-dose arm are summarized in Table 36, and the complete statistical report is found in Supplemental Appendix XXVIII. The Kaplan-Meier survival curves related to the onset of aberrant cycles for the continuous vehicle control and BPA and vehicle control and EE_2_ groups are shown in Figure 20 and Figure 21, respectively. There was no treatment effect of BPA in the continuous-dose arm. None of the dose groups differed significantly in the median onset time of 56.8 weeks in the vehicle control group. As expected based on the previously mentioned analysis of estrous cycle data at 16 weeks, the onset of aberrant cycles occurred significantly earlier in the 0.5 μg EE_2_/kg bw/day dose group.

Table 36 Time to Onset of Aberrant Estrous Cycles in Vehicle, BPA, and EE_2_ Continuous-Dose Groups^a^

Statistic | Vehicle (26)^b^ | 2.5 BPA (25) | 25 BPA (25) | 250 BPA (25) | 2500 BPA (26) | 25000 BPA (25) | 0.05 EE_2_ (26) | 0.5 EE_2_ (26)
% uncensored | 88 | 96 | 100 | 84 | 81 | 96 | 88 | 23
% aberrant at start (left censored) | 4 | 0 | 0 | 8 | 4 | 4 | 4 | 77
% with normal cycles at removal (right censored) | 8 | 4 | 0 | 8 | 15 | 0 | 8 | 0
Median onset of aberrant cycles, weeks (lower and upper 95% confidence intervals) | 56.8 (42.0, 66.9) | 47.0 (36.9, 52.0) | 51.9 (42.1, 56.9) | 56.9 (46.9, 61.9) | 52.0 (46.9, 56.7) | 46.9 (41.7, 56.9) | 51.8 (37, 62.1) | 21.9*** (21.7, 22)
p-value | - | 0.74 | 0.80 | 0.79 | 0.80 | 0.79 | 0.36 | <0.001***

^a^ BPA and EE_2_ doses are μg/kg bw/day. One month after the collection of the 14 consecutive vaginal smears to evaluate the estrous cycle (Table 34), the same animals from the continuous-dose, two-year study arm were monitored monthly for cycling status with five consecutive daily vaginal smears. The criteria for declaring an animal as having an aberrant estrous cycle were 3 or more consecutive days of estrus (E, E/D, or P/E) or five consecutive days that did not include an estrus. The animal was no longer monitored after two consecutive months with an aberrant cycle, and the time of onset of aberrant cycling was defined as having occurred at the first swab date of two consecutive months of aberrant estrous cycle data. Separate analyses were conducted for the BPA and EE_2_ dose groups. An accelerated failure time model assuming a lognormal distribution was used for analysis, and multiple comparisons were adjusted using Holm's method for treatment comparisons to the control. All tests were performed as two-sided tests at the 0.05 significance level. The full statistical report is found in Supplemental Appendix XXVIII. Statistically significant results are marked with asterisks (***, p < 0.001). There were no additional significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

^b^ Numbers in parentheses are the number of animals examined.

Figure 20

Kaplan-Meier Time to Aberrant Cycling Curve for BPA Continuous-Dose Arm

See Table 36 for data analysis results.

Figure 21

Kaplan-Meier Time to Aberrant Cycling Curve for EE_2_ Continuous-Dose Arm

See Table 36 for data analysis results.

### Stop-Dose Arm

The time of onset of aberrant estrous cycles in the stop-dose BPA females is shown in Table 37. The Kaplan-Meier survival curves related to the onset of aberrant cycles for the stop-dose vehicle control and BPA groups are shown in Figure 22, and the complete statistical report is found in Supplemental Appendix XXVIII. The sole significant effect was a delay in the median time of onset in the 2,500 μg BPA/kg bw/day dose group (57 weeks versus 42 weeks in vehicle controls). While no formal analysis was conducted to compare the continuous-dose vehicle control group with the stop-dose vehicle control group, the estimated median time of onset of aberrant cycling appeared shorter in the stop-dose vehicle control group.

Table 37 Time to Onset of Aberrant Estrous Cycles in Vehicle and BPA Stop-Dose Groups^a^

Statistic | Vehicle (26)^b^ | 2.5 BPA (26) | 25 BPA (26) | 250 BPA (26) | 2500 BPA (25) | 25000 BPA (26)
% uncensored | 88 | 77 | 96 | 88 | 80 | 92
% aberrant at start (left censored) | 0 | 8 | 0 | 8 | 4 | 0
% with normal cycles at removal (right censored) | 12 | 15 | 4 | 4 | 16 | 8
Median onset of aberrant cycles, weeks (lower and upper 95% confidence intervals) | 41.9 (41.3, 51.7) | 51.7 (36.9, 57.0) | 46.8 (41.9, 56.9) | 51.9 (41.9, 56.9) | 56.9* (51.7, 66.6) | 52.1 (41.9, 61.9)
p-value | - | 1.00 | 0.83 | 1.00 | 0.03* | 0.52

^a^ BPA doses are μg/kg bw/day. One month after the collection of the 14 consecutive vaginal smears to evaluate the estrous cycle (Table 35), the same animals from the stop-dose two-year study arm were monitored monthly for cycling status with five consecutive daily vaginal smears. The criteria for declaring an animal as having an aberrant estrous cycle were 3 or more consecutive days of estrus (E, E/D, or P/E) or five consecutive days that did not include an estrus. The animal was no longer monitored after two consecutive months with an aberrant cycle, and the time of onset of aberrant cycling was defined as having occurred at the first swab date of two consecutive months of aberrant estrous cycle data. An accelerated failure time model assuming a lognormal distribution was used for analysis, and multiple comparisons were adjusted using Holm's method for treatment comparisons to the control. All tests were performed as two-sided tests at the 0.05 significance level. The full statistical report is found in Supplemental Appendix XXVIII. Statistically significant results are marked with an asterisk (*, p < 0.05). There were no additional significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

^b^ Number in parentheses are the number of animals examined.

Figure 22

Kaplan-Meier Time to Aberrant Cycling Curve for BPA Stop-Dose Arm

See Table 37 for data analysis results.

## Hematology Endpoints in Interim Sacrifice Animals

### Females, Continuous-Dose Arm

Hematology endpoints examined at the interim sacrifice in females dosed continuously with BPA or EE_2_ are shown in Table 38. Platelet counts were significantly lower (~10%) than vehicle controls in the 25,000 μg BPA/kg bw/day dose group. Eosinophils were decreased (~25%) in the 250 μg BPA/kg bw/day dose group relative to the vehicle control group, and mean corpuscular hemoglobin concentration was significantly higher (~1.4%) than vehicle controls in the 25 μg BPA/kg bw/day dose group. There were significant trends over increasing levels of BPA dose concentrations for hemoglobin concentration (p = 0.023), monocytes (p = 0.045), and platelet counts (p = 0.008). In female rats continuously dosed with 0.5 μg EE_2_/kg bw/day, lower eosinophil counts (~25%), % eosinophils (~ 21%), and platelet counts (~8%) were observed.

Table 38 Female Hematology, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (21)^b^ | 2.5 BPA (22) | 25 BPA (21) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (24) | 0.05 EE_2_ (24) | 0.5 EE_2_ (26)
Hematocrit, % | 47.3 ± 0.4 | 46.0 ± 0.4 | 45.7 ± 0.5 | 47.4 ± 0.5 | 46.8 ± 0.5 | 47.5 ± 0.3 | 47.1 ± 0.5 | 46.7 ± 0.8
Hemoglobin, g/dL | 16.4 ± 0.1* | 16.0 ± 0.1 | 16.0 ± 0.2 | 16.5 ± 0.2 | 16.3 ± 0.2 | 16.5 ± 0.1 | 16.4 ± 0.2 | 16.3 ± 0.2
Red Blood Cells, 10^6^/mm^3^ | 8.3 ± 0.1 | 8.2 ± 0.1 | 8.1 ± 0.1 | 8.5 ± 0.1 | 8.3 ± 0.1 | 8.4 ± 0.1 | 8.3 ± 0.1 | 8.2 ± 0.1
% Reticulocytes | 1.3 ± 0.1 | 1.3 ± 0 | 1.2 ± 0 | 1.4 ± 0.1 | 1.3 ± 0.1 | 1.2 ± 0.0 | 1.2 ± 0.0 | 1.2 ± 0.1
Packed Cell Volume, % | 47.3 ± 0.4 | 46.0 ± 0.4 | 45.9 ± 0.5 | 47.4 ± 0.5 | 46.9 ± 0.5 | 47.5 ± 0.3 | 47.2 ± 0.5 | 46.9 ± 0.7
Mean Corpuscular Volume, µm^3^ | 57.0 ± 0.4 | 56.5 ± 0.3 | 56.9 ± 0.4 | 56.0 ± 0.5 | 56.4 ± 0.4 | 56.6 ± 0.3 | 56.5 ± 0.3 | 56.8 ± 0.3
Mean Corpuscular Hemoglobin, pg | 19.7 ± 0.2 | 19.6 ± 0.1 | 19.9 ± 0.2 | 19.4 ± 0.2 | 19.6 ± 0.1 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.8 ± 0.1
Mean Corpuscular Hemoglobin Concentration, g/dL | 34.6 ± 0.1 | 34.8 ± 0.1 | 35.1 ± 0.2** | 34.8 ± 0.1 | 34.7 ± 0.1 | 34.9 ± 0.1 | 34.8 ± 0.1 | 34.9 ± 0.1
Platelets, 10^3^/mm^3^ | 650.4 ± 21.3** | 651.5 ± 28.5 | 651.0 ± 22.8 | 635.1 ± 21.5 | 633.1 ± 16.2 | 585.9 ± 20.5* | 598.1 ± 17.4^c^ | 597.7 ± 18.9*
White Blood Cells, 10^3^/mm^3^ | 8.4 ± 0.3 | 7.5 ± 0.3 | 7.9 ± 0.4 | 7.8 ± 0.4 | 8.1 ± 0.4 | 7.6 ± 0.3 | 8.0 ± 0.4 | 7.8 ± 0.4
Neutrophils, 10^3^/mm^3^ | 2.1 ± 0.2 | 2.1 ± 0.1 | 2.1 ± 0.2 | 2.0 ± 0.2 | 2.1 ± 0.2 | 1.8 ± 0.2 | 2.1 ± 0.2 | 2.0 ± 0.1
% Neutrophils | 24.9 ± 2.3 | 29.6 ± 2.6 | 26.0 ± 1.4 | 25.6 ± 1.7 | 26.1 ± 1.6 | 23.8 ± 1.2 | 25.7 ± 1.5 | 25.6 ± 1.0
Lymphocytes, 10^3^/mm^3^ | 5.5 ± 0.3 | 4.6 ± 0.3 | 4.9 ± 0.3 | 5.0 ± 0.3 | 5.2 ± 0.3 | 5.1 ± 0.2 | 5.2 ± 0.3 | 5.1 ± 0.2
% Lymphocytes | 66.1 ± 2.2 | 61.0 ± 2.5 | 62.9 ± 1.8 | 64.7 ± 1.8 | 64.6 ± 1.5 | 67.6 ± 1.5 | 65.4 ± 1.6 | 66.5 ± 1.0
Monocytes, 10^3^/mm^3^ | 0.6 ± 0.1* | 0.6 ± 0.1 | 0.8 ± 0.1 | 0.7 ± 0.1 | 0.7 ± 0.1 | 0.6 ± 0.1 | 0.6 ± 0 | 0.5 ± 0
% Monocytes | 7.4 ± 0.4 | 7.9 ± 0.6 | 9.5 ± 0.9^d^ | 8.4 ± 0.8 | 8.0 ± 0.6 | 7.1 ± 0.5 | 7.2 ± 0.4 | 6.6 ± 0.4
Basophils, 10^3^/mm^3^ | 0.01 ± 0 | 0.01 ± 0 | 0.02 ± 0 | 0.01 ± 0 | 0.01 ± 0 | 0.01 ± 0 | 0.01 ± 0 | 0.01 ± 0
% Basophils | 0.2 ± 0 | 0.2 ± 0 | 0.3 ± 0.1 | 0.2 ± 0 | 0.1 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0
Eosinophils, 10^3^/mm^3^ | 0.12 ± 01 | 0.09 ± 0.01 | 0.11 ± 0.01 | 0.09 ± 0.01* | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.12 ± 0.01 | 0.09 ± 0.01*
% Eosinophils | 1.4 ± 0.1 | 1.3 ± 0.1 | 1.4 ± 0.1 | 1.1 ± 0.1 | 1.2 ± 0.1 | 1.3 ± 0.1 | 1.5 ± 0.2 | 1.1 ± 0.1*

^a^ BPA and EE_2_ doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The average of the left and right ranks was used for ties. The five BPA treatments were compared to the vehicle control within each sex and dosing regimen. Similarly, the EE_2_ reference estrogen control treatments were compared to the vehicle control. Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Statistically significant effects are indicated by asterisks (*, p < 0.05; **, p < 0.01). Asterisks in the vehicle column indicate a significant trend in the BPA dose groups versus the vehicle control group. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

^c^ Platelet numbers in 0.05 EE_2_ dose group significantly different from vehicle control (p = 0.002) in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

^d^ % monocytes in 25 BPA dose group significantly different from vehicle control (p = 0.033) in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

### Females, Stop-Dose Arm

Hematology endpoints examined at the interim sacrifice in stop-dose BPA female rats are shown in Table 39. No statistically significant differences in values were observed in pairwise comparisons between BPA dose groups and vehicle controls. Significant trends were noted for % basophils (p = 0.031), mean corpuscular hemoglobin (p = 0.013), and red blood cells (p = 0.044).

Table 39 Female Hematology, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (22) | 25 BPA (20) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (19)
Hematocrit, % | 46.9 ± 0.4 | 47.1 ± 0.4 | 47.3 ± 0.6 | 46.9 ± 0.5 | 46.6 ± 0.7 | 47.4 ± 0.4
Hemoglobin, g/dL | 16.2 ± 0.1 | 16.4 ± 0.1 | 16.4 ± 0.2 | 16.2 ± 0.2 | 16.1 ± 0.2 | 16.3 ± 0.2
Red Blood Cells, 10^6^/mm^3^ | 8.3 ± 0.1* | 8.3 ± 0.1 | 8.4 ± 0.1 | 8.4 ± 0.1 | 8.4 ± 0.1 | 8.5 ± 0.1
% Reticulocytes | 1.3 ± 0.1 | 1.3 ± 0.1 | 1.2 ± 0.1 | 1.3 ± 0.1 | 1.3 ± 0.1 | 1.4 ± 0.1
Packed Cell Volume, % | 47.0 ± 0.4 | 47.2 ± 0.4 | 47.3 ± 0.6 | 47.0 ± 0.5 | 46.6 ± 0.7 | 47.4 ± 0.4
Mean Corpuscular Volume, µm^3^ | 56.2 ± 0.3 | 57.0 ± 0.4 | 56.3 ± 0.4 | 55.7 ± 0.5 | 55.7 ± 0.4 | 55.6 ± 0.3
Mean Corpuscular Hemoglobin, pg | 19.5 ± 0.1* | 19.9 ± 0.1 | 19.5 ± 0.2 | 19.3 ± 0.2 | 19.2 ± 0.2 | 19.1 ± 0.1
Mean Corpuscular Hemoglobin Concentration, g/dL | 34.6 ± 0.1 | 34.8 ± 0.1 | 34.6 ± 0.1 | 34.6 ± 0.1 | 34.5 ± 0.1 | 34.4 ± 0.1
Platelets, 10^3^/mm^3^ | 645.1 ± 32.6 | 586.7 ± 21.6 | 592.6 ± 29.1 | 594.0 ± 26.2 | 646.1 ± 36.2 | 621.1 ± 19.5
White Blood Cells, 10^3^/mm^3^ | 8.0 ± 0.4 | 7.3 ± 0.4 | 8.2 ± 0.5 | 8.3 ± 0.4 | 8.7 ± 1.2 | 7.1 ± 0.4
Neutrophils, 10^3^/mm^3^ | 2.0 ± 0.1 | 1.7 ± 0.2 | 1.9 ± 0.2 | 2.1 ± 0.2 | 2.5 ± 0.7 | 1.7 ± 0.1
% Neutrophils | 24.8 ± 1.1 | 23.5 ± 1.3 | 23.4 ± 1.2 | 25.1 ± 1.8 | 25.5 ± 1.7 | 24.1 ± 1.3
Lymphocytes, 10^3^/mm^3^ | 5.3 ± 0.3 | 4.9 ± 0.3 | 5.4 ± 0.3 | 5.3 ± 0.3 | 5.4 ± 0.4 | 4.6 ± 0.3
% Lymphocytes | 66.3 ± 1.3 | 67.0 ± 1.6 | 66.3 ± 1.3 | 64.9 ± 1.8 | 65.6 ± 2.1 | 66.1 ± 1.7
Monocytes, 10^3^/mm^3^ | 0.6 ± 0 | 0.6 ± 0 | 0.7 ± 0.1 | 0.7 ± 0.1 | 0.8 ± 0.2 | 0.6 ± 0.1
% Monocytes | 7.4 ± 0.5 | 8.0 ± 0.6 | 8.8 ± 0.8 | 8.4 ± 0.8 | 7.6 ± 0.8 | 8.5 ± 0.7
Basophils, 10^3^/mm^3^ | 0.01 ± 0 | 0.01 ± 0 | 0.02 ± 0 | 0.02 ± 0.01 | 0.01 ± 0 | 0.01 ± 0
% Basophils | 0.1 ± 0* | 0.2 ± 0 | 0.2 ± 0 | 0.3 ± 0.1 | 0.1 ± 0 | 0.1 ± 0
Eosinophils, 10^3^/mm^3^ | 0.11 ± 0.01 | 0.1 ± 0.01 | 0.1 ± 0.01 | 0.12 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
% Eosinophils | 1.35 ± 0.11 | 1.34 ± 0.13 | 1.28 ± 0.08 | 1.37 ± 0.09 | 1.17 ± 0.12 | 1.27 ± 0.1

^a^ BPA doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The five BPA treatments were compared to the vehicle control, and Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Asterisks in the vehicle column indicate a significant trend (*, p < 0.05). Statistical significance was assessed at the 0.05 level. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

### Males, Continuous-Dose Arm

Hematology endpoints examined at the interim sacrifice in males dosed continuously with BPA or EE_2_ are shown in Table 40. Hemoglobin levels were significantly higher (~4%) in the 25,000 μg BPA/kg bw/day group and the percentage of eosinophils lower (~28%) in the 250 μg BPA/kg bw/day group relative to vehicle controls. Significant trends were observed for hematocrit (p = 0.006), hemoglobin concentration (p = 0.016), PCV (p = 0.008), mean corpuscular hemoglobin (p = 0.018), mean corpuscular hemoglobin volume (p = 0.016), and platelet counts (p = 0.011). The sole observed statistically significant effect in the EE_2_ groups was an elevated hemoglobin concentration (~3%) relative to the vehicle control level in the 0.05 μg EE_2_/kg bw/day group.

Table 40 Male Hematology, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (18)^b^ | 2.5 BPA (22) | 25 BPA (18) | 250 BPA (24) | 2500 BPA (18) | 25000 BPA (21) | 0.05 EE_2_ (22) | 0.5 EE_2_ (23)
Hematocrit, % | 47.7 ± 0.4** | 47.7 ± 0.5 | 46.9 ± 0.6 | 47.9 ± 0.4 | 47.8 ± 0.5 | 49.0 ± 0.5 | 48.8 ± 0.4 | 48.6 ± 0.3
Hemoglobin, g/dL | 16.1 ± 0.1* | 16.3 ± 0.2 | 16.0 ± 0.2 | 16.3 ± 0.1 | 16.3 ± 0.2 | 16.7 ± 0.2* | 16.6 ± 0.1* | 16.5 ± 0.1
Red Blood Cells, 10^6^/mm^3^ | 9.3 ± 0.1 | 9.3 ± 0.1 | 9.3 ± 0.1 | 9.4 ± 0.1 | 9.4 ± 0.1 | 9.4 ± 0.1 | 9.4 ± 0.1 | 9.5 ± 0.1
% Reticulocytes | 1.3 ± 0.1 | 1.3 ± 0.1 | 1.3 ± 0.1 | 1.3 ± 0 | 1.3 ± 0.1 | 1.3 ± 0.1 | 1.2 ± 0.1 | 1.2 ± 0.1
Packed Cell Volume, % | 47.7 ± 0.4** | 47.7 ± 0.5 | 47.1 ± 0.6 | 47.9 ± 0.4 | 47.8 ± 0.5 | 49.0 ± 0.5 | 48.7 ± 0.4 | 48.6 ± 0.3
Mean Corpuscular Volume, µm^3^ | 51.2 ± 0.2* | 51.5 ± 0.3 | 50.5 ± 0.3 | 51.1 ± 0.3 | 51.0 ± 0.4 | 52.3 ± 0.5 | 51.7 ± 0.3 | 51.4 ± 0.3
Mean Corpuscular Hemoglobin, pg | 17.3 ± 0.1* | 17.6 ± 0.1 | 17.2 ± 0.1 | 17.4 ± 0.1 | 17.5 ± 0.2 | 17.8 ± 0.2 | 17.6 ± 0.1 | 17.4 ± 0.1
Mean Corpuscular Hemoglobin Concentration, g/dL | 33.9 ± 0.1 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.2 ± 0.1 | 34.0 ± 0.1 | 34.0 ± 0.1 | 34.0 ± 0.1
Platelets, 10^3^/mm^3^ | 751.3 ± 32.6* | 716.2 ± 25.1^c^ | 749.1 ± 45.3^d^ | 702.3 ± 37.3 | 754.3 ± 18.1 | 671 ± 28.4 | 709.7 ± 26.7 | 740.6 ± 22.3
White Blood Cells, 10^3^/mm^3^ | 9.8 ± 0.5 | 10.3 ± 0.3 | 9.8 ± 0.4 | 10.5 ± 0.3 | 9.9 ± 0.6 | 9.4 ± 0.5 | 10.5 ± 0.5 | 11.1 ± 0.5
Neutrophils, 10^3^/mm^3^ | 2.3 ± 0.2 | 2.4 ± 0.2 | 2.2 ± 0.2 | 2.5 ± 0.2 | 2.1 ± 0.2 | 2.2 ± 0.2 | 2.2 ± 0.2 | 2.5 ± 0.1
% Neutrophils | 22.9 ± 0.8 | 23.4 ± 1.4 | 22.5 ± 1.2 | 23.5 ± 1.0 | 22.1 ± 1.8 | 23.3 ± 1.2 | 21.4 ± 1.2 | 22.4 ± 0.9
Lymphocytes, 10^3^/mm^3^ | 6.6 ± 0.4 | 6.8 ± 0.3 | 6.5 ± 0.3 | 6.9 ± 0.2 | 6.9 ± 0.5 | 6.2 ± 0.4 | 7.1 ± 0.4 | 7.5 ± 0.4
% Lymphocytes | 67.0 ± 1.1 | 66.0 ± 1.5 | 66.4 ± 1.8 | 66.0 ± 1.5 | 69.0 ± 1.8 | 65.9 ± 1.3 | 67.8 ± 1.4 | 67.5 ± 1.3
Monocytes, 10^3^/mm^3^ | 0.8 ± 0.1 | 0.9 ± 0.1 | 0.9 ± 0.1 | 1.0 ± 0.1 | 0.7 ± 0.1 | 0.9 ± 0.1 | 1.0 ± 0.1 | 1.0 ± 0.1
% Monocytes | 8.2 ± 0.9 | 8.6 ± 0.7 | 9.5 ± 0.9 | 9.0 ± 0.8 | 7.5 ± 0.7 | 9.1 ± 0.6 | 9.3 ± 0.7 | 8.6 ± 0.6
Basophils, 10^3^/mm^3^ | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.01 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.03 ± 0.01
% Basophils | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.1 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0.1
Eosinophils, 10^3^/mm^3^ | 0.17 ± 0.02 | 0.18 ± 0.02 | 0.15 ± 0.01 | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.14 ± 0.01 | 0.15 ± 0.01
% Eosinophils | 1.71 ± 0.14 | 1.74 ± 0.23 | 1.53 ± 0.13 | 1.23 ± 0.1* | 1.29 ± 0.09 | 1.44 ± 0.16 | 1.37 ± 0.11 | 1.33 ± 0.1

^a^ BPA and EE_2_ doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The average of the left and right ranks was used for ties. The five BPA treatments were compared to the vehicle control within each sex and dosing regimen. Similarly, the EE_2_ reference estrogen control treatments were compared to the vehicle control. Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Statistically significant effects are indicated by asterisks (*, p < 0.05; **, p < 0.01). Asterisks in the vehicle column indicate a significant trend. Asterisks in the BPA or EE_2_ dose group columns indicate significant differences in pairwise comparisons to the vehicle group. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions or missing data are indicated by footnotes.

^c^ n = 21 in 2.5 μg BPA/kg bw/day platelet count due to missing data (no result reported) for one animal.

^d^ n = 17 in 25 μg BPA/kg bw/day platelet count due to missing data (no result reported) for one animal.

### Males, Stop-Dose Arm

Hematology endpoints examined at the interim sacrifice in stop-dose BPA male rats are shown in Table 41. No statistically significant effects were observed in pairwise comparisons between BPA dose groups and vehicle controls. A significant trend for % neutrophils (p = 0.045) was noted over the levels of BPA dose concentrations in the stop-dose arm.

Table 41 Male Hematology, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (19)^b^ | 2.5 BPA (20) | 25 BPA (19) | 250 BPA (19) | 2500 BPA (20) | 25000 BPA (22)
Hematocrit, % | 48.5 ± 0.5 | 48.2 ± 0.4 | 47.5 ± 0.6 | 48.0 ± 0.6 | 47.0 ± 0.8 | 46.8 ± 1.0
Hemoglobin, g/dL | 16.4 ± 0.2 | 16.3 ± 0.1 | 16.1 ± 0.2 | 16.2 ± 0.2 | 15.8 ± 0.3 | 15.9 ± 0.3
Red Blood Cells, 10^6^/mm^3^ | 9.5 ± 0.1 | 9.4 ± 0.1 | 9.3 ± 0.13 | 9.5 ± 0.1 | 9.2 ± 0.2 | 9.1 ± 0.2
% Reticulocytes | 1.3 ± 0.1 | 1.2 ± 0.1 | 1.3 ± 0.1 | 1.2 ± 0.1 | 1.2 ± 0.1 | 1.2 ± 0.1
Packed Cell Volume, % | 48.5 ± 0.5 | 48.2 ± 0.4 | 47.6 ± 0.6 | 48.0 ± 0.6 | 46.9 ± 0.8 | 46.8 ± 1.0
Mean Corpuscular Volume, µm^3^ | 51.3 ± 0.3 | 51.2 ± 0.4 | 51.2 ± 0.3 | 50.7 ± 0.4 | 51.7 ± 1.0 | 51.4 ± 0.5
Mean Corpuscular Hemoglobin, pg | 17.3 ± 0.1 | 17.3 ± 0.1 | 17.4 ± 0.1 | 17.1 ± 0.2 | 17.4 ± 0.3 | 17.5 ± 0.2
Mean Corpuscular Hemoglobin Concentration, g/dL | 33.7 ± 0.1^c^ | 33.8 ± 0.1 | 33.9 ± 0.1 | 33.6 ± 0.1 | 33.7 ± 0.1 | 33.9 ± 0.1
Platelets, 10^3^/mm^3^ | 753.5 ± 24.6 | 785.7 ± 24.1 | 769.0 ± 37.7 | 712.8 ± 35.2 | 742.3 ± 12.2 | 764.3 ± 30.3
White Blood Cells, 10^3^/mm^3^ | 10.5 ± 0.4 | 11.7 ± 1.0 | 10.3 ± 0.4 | 10.9 ± 0.6 | 10.8 ± 0.5 | 11.4 ± 0.8
Neutrophils, 10^3^/mm^3^ | 2.4 ± 0.2 | 3.5 ± 0.6 | 2.7 ± 0.3 | 2.8 ± 0.3 | 2.3 ± 0.1 | 2.4 ± 0.2
% Neutrophils | 23.9 ± 2.0* | 28.4 ± 2.3 | 25.9 ± 2.2 | 25.2 ± 2.1 | 21.0 ± 0.8 | 21.8 ± 1.6
Lymphocytes, 10^3^/mm^3^ | 7.1 ± 0.45 | 6.9 ± 0.4 | 6.4 ± 0.3 | 7.0 ± 0.5 | 7.5 ± 0.35 | 7.7 ± 0.6
% Lymphocytes | 66.2 ± 2.2 | 60.9 ± 2.3 | 62.7 ± 2.2 | 63.5 ± 2.1 | 69.5 ± 0.9 | 67.5 ± 1.7
Monocytes, 10^3^/mm^3^ | 0.9 ± 0.1 | 1.1 ± 0.1 | 1.0 ± 0.1 | 1.0 ± 0.1 | 0.9 ± 0.1 | 1.1 ± 0.2
% Monocytes | 8.3 ± 1.0 | 9.1 ± 0.8 | 9.6 ± 0.7 | 9.8 ± 1.0 | 8.1 ± 0.6 | 8.9 ± 0.9
Basophils, 10^3^/mm^3^ | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0
% Basophils | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0 | 0.2 ± 0
Eosinophils, 10^3^/mm^3^ | 0.15 ± 0.01 | 0.16 ± 0.01 | 0.16 ± 0.02 | 0.15 ± 0.02 | 0.13 ± 0.01 | 0.17 ± 0.01
% Eosinophils | 1.46 ± 0.12 | 1.42 ± 0.09 | 1.58 ± 0.13 | 1.39 ± 0.13 | 1.23 ± 0.12 | 1.54 ± 0.11

^a^ BPA doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The five BPA treatments were compared to the vehicle control, and Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. An asterisk in the vehicle column indicates a significant trend (*, p < 0.05) versus the vehicle control. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

^c^ Significant trend (p = 0.04) for mean corpuscular hemoglobin concentration in sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

## Serum Clinical Chemistry Endpoints in Interim Sacrifice Animals

### Females, Continuous-Dose Arm

Clinical chemistry endpoints examined at the interim sacrifice in females dosed continuously with BPA or EE_2_ are shown in Table 42. Alkaline phosphatase levels were significantly higher (~31%) in the 250 μg BPA/kg bw/day group than levels in the vehicle control group. Although mean levels of alkaline phosphatase were higher than controls in most of the BPA groups, none of the others were statistically significant. There were no other statistically significant treatment effects on clinical chemistry endpoints in any continuous BPA dose group. The female rats in the continuous 0.5 μg EE_2_/kg bw/day dose group had higher (~38%) mean levels of TSH, while rats in the 0.05 μg EE_2_/kg bw/day dose group had higher (~24%) mean levels of alkaline phosphatase than the vehicle control group. There were no EE_2_ treatment effects on T3 or T4.

Table 42 Female Clinical Chemistry, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (21)^b^ | 2.5 BPA (22) | 25 BPA (21) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (24) | 0.05 EE_2_ (24) | 0.5 EE_2_ (26)
Urea nitrogen, mg/dL | 14.4 ± 0.6 | 13.5 ± 0.3 | 14.0 ± 0.4 | 15.5 ± 0.6 | 14.5 ± 0.7 | 14.4 ± 0.4 | 14.5 ± 0.5 | 15.6 ± 0.6
Creatinine, mg/dL | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.5 ± 0
Total protein, mg/dL | 7.5 ± 0.1 | 7.6 ± 0.1 | 7.8 ± 0.1 | 7.4 ± 0.1 | 7.7 ± 0.1 | 7.6 ± 0.1 | 7.6 ± 0.1 | 7.7 ± 0.1
Albumin, g/dL | 4.1 ± 0.1 | 4.0 ± 0.1 | 4.1 ± 0.1 | 4.0 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.0
Alkaline phosphatase, U/L | 54.3 ± 2.8 | 62.9 ± 3.6 | 72.1 ± 7.3 | 71.0 ± 5.5* | 63.9 ± 3.6 | 58.1 ± 3.6 | 67.6 ± 3.8* | 68.1 ± 5.5
Alanine aminotransferase, U/L | 31.0 ± 3.0 | 37.5 ± 6.8 | 37.6 ± 4.8 | 34.2 ± 2.5 | 32.0 ± 2.3 | 29.0 ± 1.8 | 30.5 ± 1.6 | 37.0 ± 2.6
Aspartate aminotransferase, U/L | 90.8 ± 8.0 | 82.5 ± 4.7 | 86.7 ± 10.6 | 76.2 ± 3.7 | 79.2 ± 4.5 | 78.9 ± 6.0 | 78.5 ± 3.7 | 80.3 ± 3.6
Sorbitol dehydrogenase, U/L | 27.4 ± 4.2 | 30.5 ± 5.7 | 33.2 ± 5.5 | 24.1 ± 2.1 | 22.3 ± 2.1 | 24.2 ± 3.1 | 26.8 ± 2.0 | 19.4 ± 2.0
Gamma-glutamyl transferase, U/L | 4.4 ± 0.3 | 4.1 ± 0.3 | 4.6 ± 0.3 | 4.0 ± 0.3 | 4.2 ± 0.3 | 4.2 ± 0.3 | 3.8 ± 0.2^c^ | 3.9 ± 0.3
Total bile acids, µmol/L | 47.0 ± 5.8 | 53.5 ± 9.9 | 49.7 ± 5.3 | 53.0 ± 5.3 | 51.4 ± 5.7 | 42.3 ± 5.6 | 50.6 ± 7.1 | 72.0 ± 9.1
Cholesterol, mg/dL | 109.5 ± 4.4 | 111.7 ± 7.2 | 128.9 ± 11.1 | 107.6 ± 4.6 | 111.3 ± 7.6 | 107.7 ± 8.4 | 127.5 ± 6.6 | 121.5 ± 4.9
Glucose, mg/dL | 130.0 ± 6.0 | 126.0 ± 4.8 | 130.2 ± 5 | 124.8 ± 4.8 | 122.1 ± 4.3 | 136.1 ± 6.6 | 128.8 ± 4.5 | 120.6 ± 3.3
Triglycerides, ng/mL | 266 ± 24.3 | 258.6 ± 24.3 | 299.6 ± 41.5 | 237.5 ± 30.3 | 330.7 ± 40.3 | 331.6 ± 67.7 | 282.9 ± 34.5 | 369.4 ± 39.2
Insulin, mg/mL | 1.5 ± 0.2 | 2.2 ± 0.4 | 2.0 ± 0.3 | 1.6 ± 0.2 | 1.6 ± 0.2 | 2.1 ± 0.5 | 2.0 ± 0.3 | 1.3 ± 0.1
Leptin, ng/mL | 19.3 ± 2.4 | 27.8 ± 3.5 | 24.5 ± 3.1 | 18.5 ± 2.5 | 19.8 ± 2.1 | 20.7 ± 2.7 | 23.7 ± 2.9 | 17.9 ± 1.8
Troponin T, pg/mL^d^ | 10.3 ± 1.6 | 8.0 ± 1.7 | 10.2 ± 2.2 | 6.6 ± 1.9 | 5.9 ± 1.5 | 6.5 ± 1.9 | 6.3 ± 1.4 | 6.9 ± 1.9
| 18/21 (86%)^e,f^ | 13/22 (59%) | 14/21 (67%) | 12/22 (55%) | 12/20 (60%) | 13/24 (54%) | 15/24 (62%) | 13/26 (50%)
T3, ng/dL | 71.6 ± 3.5 | 72.1 ± 4.1 | 79.2 ± 4.3 | 70.8 ± 3 | 78.2 ± 3.5 | 73.3 ± 2.5 | 79.3 ± 2.6 | 78.0 ± 3.5
T4, μg/dL | 3.8 ± 0.2^g^ | 3.9 ± 0.2 | 3.8 ± 0.2 | 3.8 ± 0.2 | 3.9 ± 0.2 | 4.1 ± 0.2 | 4.2 ± 0.2 | 3.8 ± 0.2
TSH, ng/mL | 3.7 ± 0.7 | 4.4 ± 0.9 | 3.6 ± 0.4 | 4.2 ± 0.4 | 4.9 ± 0.7 | 4.5 ± 0.4 | 3.4 ± 0.3 | 5.1 ± 0.5*

^a^ BPA and EE_2_ doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The average of the left and right ranks was used for ties. The five BPA treatments were compared to the vehicle control within each sex and dosing regimen. Similarly, the EE_2_ reference estrogen control treatments were compared to the vehicle control. Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Statistically significant effects are indicated by asterisks. Asterisks in the BPA or EE_2_ dose group columns indicate significant differences in pairwise comparisons to the vehicle group (*, p < 0.05). Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions or missing data are indicated by footnotes.

^c^ Gamma-glutamyl transferase in 0.05 μg EE_2_ /kg bw/day group significantly different from vehicle control (p = 0.018) in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

^d^ Means were calculated using ½ the limit of detection (LOD, 1.0 pg/mL) for samples below LOD. Troponin I was also measured, but the overall percentage of samples above the limit of detection was less than 5%, so no statistical analysis was conducted.

^e^ Number of samples with troponin T levels above LOD/total number of samples. Percentage of detects is given in parenthesis. Because of the high percentage of non-detects, the proportion of samples with detectable troponin T were statistically analyzed rather than means or medians. No significant trends across BPA dose groups or pairwise comparisons to vehicle control were detected.

^f^ ERRATUM: An error was identified in the NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats (RR-9). The method of calculation of mean Troponin T, number of samples with detectable levels of Troponin T, and statistical analysis approach were not originally included in the Table. This error has been corrected; the new information is italicized.

^g^ n = 20 in vehicle T4 assay due to insufficient quantity of serum for assay for one animal.

### Females, Stop-Dose Arm

Clinical chemistry endpoints examined at the interim sacrifice in stop-dose BPA female rats are shown in Table 43. No statistically significant differences were noted in pairwise comparisons between stop-dose BPA-treated female rats and the vehicle controls. There was a significant trend over levels of BPA dose concentrations for albumin (p = 0.004).

Table 43 Female Clinical Chemistry, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (22) | 25 BPA (20) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (19)
Urea nitrogen, mg/dL | 13.9 ± 0.5 | 14.0 ± 0.5 | 14.5 ± 0.5 | 14.1 ± 0.5 | 14.3 ± 0.5 | 14.3 ± 0.5
Creatinine, mg/dL | 0.5 ± 0.0 | 0.5 ± 0.0 | 0.5 ± 0.0 | 0.4 ± 0.0 | 0.5 ± 0.0 | 0.5 ± 0.0
Total protein, mg/dL | 7.4 ± 0.1 | 7.7 ± 0.1 | 7.6 ± 0.1 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.7 ± 0.1
Albumin, g/dL | 4.1 ± 0.1** | 4.2 ± 0.1 | 4.0 ± 0.0 | 4.0 ± 0.1 | 4.0 ± 0.1 | 4.2 ± 0.0
Alkaline phosphatase, U/L | 67.2 ± 3.8 | 75.4 ± 5.3 | 72.9 ± 3.8 | 62.5 ± 3.0 | 69.0 ± 6.0 | 83.1 ± 7.2
Alanine aminotransferase, U/L | 29.2 ± 2.0 | 33.3 ± 2.9 | 35.2 ± 3.8 | 29.5 ± 2.0 | 29.7 ± 2.8 | 35.4 ± 3.6
Aspartate aminotransferase, U/L | 77.5 ± 3.1 | 81.5 ± 5.7 | 82.8 ± 6.5 | 72.4 ± 3.3 | 76.5 ± 4.0 | 86.5 ± 7.9
Sorbitol dehydrogenase, U/L | 24.5 ± 3.0^c^ | 29.1 ± 3.5 | 31.8 ± 4.6 | 28.0 ± 1.9 | 22.3 ± 2.4 | 31.2 ± 2.7
Gamma-glutamyl transferase, U/L | 4.4 ± 0.3 | 4.3 ± 0.3 | 3.6 ± 0.4 | 3.8 ± 0.3 | 3.8 ± 0.3 | 3.9 ± 0.3
Total bile acids, µmol/L | 43.3 ± 4.1 | 48.9 ± 5.8 | 56.5 ± 6.1 | 44.8 ± 4.2 | 46.0 ± 4.7 | 59.2 ± 7.5
Cholesterol, mg/dL | 116.9 ± 6.7 | 116.0 ± 7.4 | 108.6 ± 6.7 | 111.9 ± 5.1 | 113.4 ± 4.4 | 125.8 ± 12.5
Glucose, mg/dL | 129.8 ± 3.8 | 137.2 ± 5.9 | 128.2 ± 4.5 | 128.4 ± 4.2 | 125.6 ± 5.4 | 125.4 ± 5.5
Triglycerides, ng/mL | 261.2 ± 21.4 | 373.7 ± 68.4 | 253.2 ± 38.4 | 274.6 ± 55.8 | 342.2 ± 49.8 | 315.2 ± 27.7
Insulin, mg/mL | 2.0 ± 0.3 | 2.6 ± 0.4 | 1.5 ± 0.2 | 2.3 ± 0.5 | 2.0 ± 0.3 | 2.1 ± 0.3
Leptin, ng/mL | 24.2 ± 3.1 | 28.1 ± 3.4 | 22.2 ± 2.9 | 22.4 ± 2.5 | 22.2 ± 2.7 | 24.2 ± 2.8
T3, ng/dL | 68.1 ± 3.3 | 72.1 ± 3.6 | 75.8 ± 3.2 | 71.0 ± 2.8 | 71.4 ± 4.1 | 78.7 ± 4.7
Troponin T, pg/mL^d^ | 7.0 ± 1.8 | 6.3 ± 1.5 | 3.6 ± 1.0 | 5.3 ± 1.0 | 6.5 ± 2.2 | 8.7 ± 2.9
| 10/20 (50%)^e,f^ | 13/22 (59%) | 10/20 (50%) | 12/22 (55%) | 12/20 (60%) | 10/19 (53%)
T4, μg/dL | 3.7 ± 0.2 | 3.6 ± 0.2 | 4.1 ± 0.2 | 3.7 ± 0.1 | 3.7 ± 0.2 | 3.7 ± 0.2
TSH, ng/mL | 4.6 ± 0.8 | 3.5 ± 0.4 | 3.8 ± 0.5 | 4.8 ± 0.7 | 4.3 ± 0.5 | 4.7 ± 0.5

^a^ BPA doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The five BPA treatments were compared to the vehicle control, and Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Asterisks in the vehicle column indicates a significant trend (**, p < 0.01) versus the vehicle control. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

^c^ Significant trend (p = 0.002) for sorbitol dehydrogenase in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

^d^ Means were calculated using ½ the limit of detection (LOD, 1.0 pg/mL) for samples below LOD. Troponin I was also measured, but the overall percentage of samples above the limit of detection was less than 5%, so no statistical analysis was conducted.

^e^ Number of samples with troponin T levels above LOD/total number of samples. Percentage of detects is given in parenthesis. Because of the high percentage of non-detects, the proportion of samples with detectable troponin T were statistically analyzed rather than means or medians. No significant trends across BPA dose groups or pairwise comparisons to vehicle control were detected.

^f^ ERRATUM: An error was identified in the NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats (RR-9). The method of calculation of mean Troponin T, number of samples with detectable levels of Troponin T, and statistical analysis approach were not originally included in the Table. This error has been corrected; the new information is italicized.

### Males, Continuous-Dose Arm

Clinical chemistry endpoints examined at the interim sacrifice in males dosed continuously with BPA or EE_2_ are shown in Table 44. No statistically significant differences were noted in pairwise comparisons between any BPA treatment group and vehicle controls. Significant trends were noted for albumin (p = 0.007), T4 (p = 0.002), total bile acids (p = 0.026), and troponin T (p = 0.003). For EE_2_, mean insulin levels were significantly lower (~35%, p = 0.047) in the 0.05 μg EE_2_/kg bw/day dose group and mean triglyceride levels were significantly higher (~26%) in the 0.5 μg EE_2_/kg bw/day dose group than those in vehicle controls.

Table 44 Male Clinical Chemistry, Vehicle, BPA, and EE2 Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (18)^b^ | 2.5 BPA (22) | 25 BPA (18) | 250 BPA (24) | 2500 BPA (18) | 25000 BPA (21) | 0.05 EE_2_ (22) | 0.5 EE_2_ (23)
Urea nitrogen, mg/dL | 14.2 ± 0.4 | 14.0 ± 0.3 | 14.3 ± 0.5 | 14.5 ± 0.4 | 14.3 ± 0.6 | 14.1 ± 0.3 | 14.4 ± 0.3 | 14.6 ± 0.4
Creatinine, mg/dL | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0 | 0.4 ± 0
Total protein, mg/dL | 7.4 ± 0.1 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.2 ± 0.1 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.2 ± 0.1
Albumin, g/dL | 3.7 ± 0** | 3.7 ± 0 | 3.6 ± 0 | 3.6 ± 0^c^ | 3.7 ± 0.1 | 3.7 ± 0 | 3.7 ± 0 | 3.7 ± 0
Alkaline phosphatase, U/L | 130.6 ± 24.1 | 107.2 ± 5.5 | 99.9 ± 5.4 | 98.7 ± 3.9 | 107.6 ± 7.7 | 99.7 ± 4.9 | 107.3 ± 4.5 | 104.2 ± 5.9
Alanine aminotransferase, U/L | 30.1 ± 1.6 | 33.8 ± 2.4 | 27.3 ± 2.0 | 29.6 ± 1.3 | 32.0 ± 2.3 | 31.0 ± 1.9 | 30.6 ± 2.7 | 33.7 ± 2.0
Aspartate aminotransferase, U/L | 69.7 ± 3.2 | 73.4 ± 4.8 | 73.5 ± 6.7 | 68.7 ± 2.4 | 76.7 ± 5.7 | 76.3 ± 6.4 | 79.9 ± 8.5 | 71.2 ± 3.0
Sorbitol dehydrogenase, U/L | 24.5 ± 2.4 | 26.8 ± 2.7 | 26.6 ± 2.7 | 27.4 ± 3.0 | 24.4 ± 2.7 | 25.9 ± 2.8 | 31.5 ± 4.8 | 22.8 ± 2.0
Gamma-glutamyl transferase, U/L | 4.1 ± 0.3 | 4.6 ± 0.3 | 4.2 ± 0.3 | 4.4 ± 0.3 | 4.8 ± 0.4 | 4.4 ± 0.3 | 4.2 ± 0.2 | 3.9 ± 0.2
Total bile acids, µmol/L | 32.8 ± 2.7* | 33.3 ± 4.1 | 32.5 ± 2.4 | 35.8 ± 3.4 | 42.0 ± 4.7 | 28.1 ± 2.7 | 38.6 ± 4.3 | 35.6 ± 3.2
Cholesterol, mg/dL | 118.0 ± 6.4 | 116.9 ± 4.8 | 118.3 ± 6.7 | 107.4 ± 4.4 | 127.3 ± 6.7 | 107.2 ± 5.2 | 120.4 ± 6.4 | 117.5 ± 7.1
Glucose, mg/dL | 126.1 ± 4.8 | 125.9 ± 3.9 | 127.1 ± 4.4 | 127.3 ± 6.1 | 136.3 ± 5.8 | 119.0 ± 3.4 | 125.4 ± 3.8 | 123.7 ± 4.1
Triglycerides, ng/mL | 267.9 ± 23.4 | 278.2 ± 19.5 | 276.1 ± 20.6 | 252.9 ± 18.7 | 304.6 ± 24.3 | 283.0 ± 13.5 | 266.8 ± 19.1 | 338.4 ± 21.8*
Insulin, mg/mL | 2.0 ± 0.2 | 1.6 ± 0.1 | 1.5 ± 0.1 | 1.4 ± 0.1 | 1.7 ± 0.3 | 1.8 ± 0.1 | 1.3 ± 0.1* | 1.6 ± 0.1
Leptin, ng/mL | 26 ± 2.5 | 29.2 ± 3.0 | 23.8 ± 2.3 | 26.3 ± 2.6 | 26.7 ± 3.0 | 29.4 ± 2.8 | 25.4 ± 2.6 | 27.2 ± 1.9
Troponin T, pg/mL^d^ | 7.4 ± 2.5 | 5.9 ± 1.4 | 9.8 ± 2.4 | 8.5 ± 2.2 | 6.4 ± 1.5 | 11.8 ± 2.2 | 5.1 ± 1.3 | 7.2 ± 1.6
| 11/18 (61%)^e,f**^ | 10/22 (46%) | 11/18 (61%) | 14/24 (58%) | 12/18 (67%) | 17/20 (85%) | 9/22 (41%) | 18/23 (78%)
T3, ng/dL | 62.8 ± 2.7 | 57.8 ± 3.4 | 63.3 ± 2.3 | 60.5 ± 3.0 | 67.3 ± 4.1 | 67.0 ± 4.0^g^ | 70.5 ± 4.1 | 66.4 ± 3.5
T4, μg/dL | 5.0 ± 0.3* | 4.3 ± 0.3 | 5.0 ± 0.2 | 4.9 ± 0.2 | 4.7 ± 0.2 | 5.5 ± 0.2 | 5.1 ± 0.2 | 4.7 ± 0.2
TSH, ng/mL | 3.6 ± 0.3 | 3.4 ± 0.3 | 3.4 ± 0.3 | 3.5 ± 0.4 | 3.5 ± 0.4 | 3.5 ± 0.4 | 4.1 ± 0.3 | 3.2 ± 0.4

^a^ BPA and EE_2_ doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The average of the left and right ranks was used for ties. The five BPA treatments were compared to the vehicle control within each sex and dosing regimen. Similarly, the EE_2_ reference estrogen control treatments were compared to the vehicle control. Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Statistically significant effects are indicated by asterisks (*, p < 0.05; **, p < 0.01). Asterisks in the vehicle column indicate a significant trend in the BPA dose groups versus the vehicle control. Asterisks in the BPA or EE_2_ dose group columns indicate significant differences in pairwise comparisons to the vehicle group. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

^c^ Albumin in 250 μg BPA/kg bw/day group significantly different from vehicle control (p = 0.012) in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

^d^ Means were calculated using ½ the limit of detection (LOD, 1.0 pg/mL) for samples below LOD. Troponin I was also measured, but the overall percentage of samples above the limit of detection was less than 5%, so no statistical analysis was conducted.

^e^ Number of samples with troponin T levels above LOD/total number of samples. Percentage of detects is given in parenthesis. Because of the high percentage of non-detects, the proportion of samples with troponin T were statistically analyzed rather than means or medians. The asterisks indicate a significant trend across BPA dose groups for the proportion of samples with detectable troponin T.

^f^ ERRATUM: An error was identified in the NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats (RR-9). The method of calculation of mean Troponin T, number of samples with detectable levels of Troponin T, and statistical analysis approach were not originally included in the Table. This error has been corrected; the new information is italicized.

^g^ n = 20 in 2,500 BPA T3 assay due to insufficient quantity of serum for assay for one animal.

### Males, Stop-Dose Arm

Clinical chemistry endpoints examined at the interim sacrifice in stop-dose BPA male rats are shown in Table 45. In the 25 μg BPA/kg bw/day dose group, decreases in the mean levels of total protein (~4%) and total bile acids (~31%) relative to vehicle controls were observed. Significant trends were noted over the levels of BPA dose concentrations for T4 (p = 0.046) and for total bile acids (p = 0.024).

Table 45 Male Clinical Chemistry, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (20) | 25 BPA (19) | 250 BPA (19) | 2500 BPA (20) | 25000 BPA (22)
Urea nitrogen, mg/dL | 14.1 ± 0.4 | 13.7 ± 0.3 | 15.0 ± 1.0 | 13.8 ± 0.6 | 14.4 ± 0.4 | 19.6 ± 3.7
Creatinine, mg/dL | 0.4 ± 0 | 0.4 ± 0 | 0.5 ± 0 | 0.5 ± 0 | 0.4 ± 0 | 0.6 ± 0.1
Total protein, mg/dL | 7.3 ± 0.1 | 7.1 ± 0.1 | 7.0 ± 0.1* | 7.2 ± 0.1 | 7.2 ± 0.1 | 7.2 ± 0.1
Albumin, g/dL | 3.6 ± 0 | 3.6 ± 0 | 3.5 ± 0.1 | 3.6 ± 0.1 | 3.6 ± 0.1 | 3.6 ± 0.1
Alkaline phosphatase, U/L | 108.8 ± 7.9 | 100.4 ± 4.2 | 104.5 ± 5.7 | 103.5 ± 11.3 | 100.5 ± 5.3 | 102.9 ± 6.0
Alanine aminotransferase, U/L | 32.4 ± 3.1 | 32.3 ± 2.0 | 28.5 ± 1.5 | 32.6 ± 5.5 | 26.7 ± 1.2 | 29.0 ± 2.6
Aspartate aminotransferase, U/L | 84.6 ± 8.8 | 85.3 ± 4.5 | 82.7 ± 7.4 | 77.2 ± 7.1 | 68.8 ± 3.1 | 69.9 ± 3.6
Sorbitol dehydrogenase, U/L | 25.0 ± 2.8 | 27.4 ± 2.8 | 32.0 ± 3.2 | 28.9 ± 2.8 | 26.7 ± 2.3 | 28.6 ± 2.9
Gamma-glutamyl transferase, U/L | 4.3 ± 0.4 | 4.1 ± 0.3 | 4.2 ± 0.4 | 3.7 ± 0.3 | 4.8 ± 0.2 | 4.3 ± 0.3
Total bile acids, µmol/L | 36.4 ± 3.1* | 34.6 ± 3.2 | 25.0 ± 2.7* | 32.6 ± 6.5 | 33.7 ± 4.3 | 35.0 ± 2.5
Cholesterol, mg/dL | 123.5 ± 5.6 | 115.5 ± 5.9 | 115.3 ± 6.7 | 117.8 ± 8.9 | 132.7 ± 4.7 | 147.7 ± 14.2
Glucose, mg/dL | 128.7 ± 5.3 | 121.9 ± 3.2 | 130.8 ± 5.9 | 120.1 ± 4.1 | 131.3 ± 4.7 | 125.2 ± 3.4
Triglycerides, ng/mL | 285.2 ± 20.0 | 252.3 ± 15.4 | 282.3 ± 26.1 | 279.9 ± 16.5 | 355.2 ± 22 | 329.8 ± 24.2
Insulin, mg/mL | 1.5 ± 0.2 | 1.5 ± 0.2 | 1.9 ± 0.2 | 1.5 ± 0.1 | 1.7 ± 0.2 | 1.6 ± 0.2
Leptin, ng/mL | 26.8 ± 3.5 | 26.8 ± 1.7 | 32.9 ± 3.7 | 25.5 ± 3.4 | 28.0 ± 3.0 | 28.1 ± 2.8
Troponin T, pg/mL^d^ | 8.0 ± 1.9 | 5.9 ± 1.7 | 4.2 ± 1.3 | 7.7 ± 2.3 | 4.8 ± 1.6 | 5.1 ± 1.8
| 12/20 (60%)^e,f^ | 8/20 (40%) | 7/19 (37%) | 12/19 (63%) | 9/20 (45%) | 8/22 (36%)
T3, ng/dL | 65.8 ± 3.1 | 63.3 ± 3.3 | 56.7 ± 3.0 | 60.6 ± 4.5 | 69.4 ± 2.9 | 66.6 ± 2.8
T4, μg/dL | 4.9 ± 0.2* | 4.8 ± 0.2 | 4.7 ± 0.2 | 4.7 ± 0.2 | 4.7 ± 0.3 | 4.2 ± 0.2^c^
TSH, ng/mL | 4.0 ± 0.4 | 4.2 ± 0.4 | 3.8 ± 0.5 | 4.5 ± 0.5 | 5.0 ± 0.6 | 3.9 ± 0.4

^a^ BPA doses are μg/kg bw/day. A non-parametric ANOVA based on mid-ranks was used to evaluate the effect of treatment. The five BPA treatments were compared to the vehicle control, and Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trend over increasing BPA dose concentrations. All statistical tests are two-sided. Statistical significance was assessed at the 0.05 level. Statistically significant effects are indicated by asterisks (*, p < 0.05). Asterisks in the vehicle column indicate a significant trend, while asterisks in BPA dose group columns indicate significant differences in pairwise comparisons to the vehicle group. Full results of the analyses are presented in Supplemental Appendix XXIX.

^b^ Numbers in parentheses are the number of animals examined.

^c^ 25,000 μg BPA/kg bw/day T4 significantly different from vehicle control (p = 0.015) in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day.

^d^ Means were calculated using ½ the limit of detection (LOD, 1.0 pg/mL) for samples below LOD. Troponin I was also measured, but the overall percentage of samples above the limit of detection was less than 5%, so no statistical analysis was conducted.

^e^ Number of samples with troponin T levels above LOD/total number of samples. Percentage of detects is given in parenthesis. Because of the high percentage of non-detects, the proportion of samples with detectable troponin T were statistically analyzed rather than means or medians. No significant trends across BPA dose groups or pairwise comparisons to vehicle control were detected.

^f^ ERRATUM: An error was identified in the NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats (RR-9). The method of calculation of mean Troponin T, number of samples with detectable levels of Troponin T, and statistical analysis approach were not originally included in the Table. This error has been corrected; the new information is italicized.

## Organ Weights in Interim Sacrifice Animals

### Females, Continuous-Dose Arm

Summary statistics for organ weights collected from females in the continuous-dose BPA and EE_2_ dose groups are shown in Table 46. Organ weights were analyzed as absolute weights, and relative weights with brain and body weight at necropsy as covariates. There were few sporadic significant differences between BPA groups and the vehicle control group. In the 2.5 μg BPA/kg bw/day dose group, the mean absolute retroperitoneal fat pad weight was significantly higher (40%) than the mean weight in the vehicle control group. The brain weight-adjusted retroperitoneal fat pad weight was similarly significantly greater than the vehicle control. The mean retroperitoneal fat pad weight adjusted for body weight was higher (23%) than the vehicle control group, but this was not a statistically significant difference. The only other significant BPA treatment effect was a dose trend for liver adjusted for body weight.

Table 46 Female Organ Weights, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (21)^b^ | 2.5 BPA (22) | 25 BPA (21) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (24) | 0.05 EE_2_ (24) | 0.5 EE_2_ (26)
Body Weight at Necropsy
g | 420 ± 19 | 477 ± 22 | 445 ± 15 | 411 ± 14 | 422 ± 13 | 425 ± 17 | 453 ± 13 | 423 ± 12
Adrenal
Absolute, mg | 72.4 ± 2.0 | 76.4 ± 2.8 | 74.9 ± 3.8 | 75.4 ± 4.7 | 76.5 ± 3.8 | 73.3 ± 3.1 | 75.3 ± 4.2 | 92.2 ± 3.8***
Ratio to Brain, mg/g | 34.8 ± 1.0 | 36.2 ± 1.4 | 35.6 ± 1.7 | 36.2 ± 2.2 | 37.4 ± 1.9 | 35.4 ± 1.5 | 36.0 ± 1.9 | 44.7 ± 1.9***
Ratio to bw, mg/g | 0.18 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.22 ± 0.01***
Brain
Absolute, g | 2.09 ± 0.02 | 2.11 ± 0.03 | 2.10 ± 0.02 | 2.08 ± 0.02 | 2.05 ± 0.03 | 2.08 ± 0.03 | 2.09 ± 0.02 | 2.07 ± 0.02
Ratio to bw, mg/g | 5.16 ± 0.23 | 4.60 ± 0.19 | 4.82 ± 0.16 | 5.18 ± 0.17 | 4.93 ± 0.13 | 5.04 ± 0.18 | 4.71 ± 0.14 | 4.98 ± 0.13
Ovarian/Parametrial Fat Pad
Absolute, g | 14.1± 1.2 | 17.1 ± 1.0 | 14.4 ± 0.8 | 14.4 ± 0.8 | 14.8 ± 1.0 | 14.2 ± 0.9 | 15.5 ± 0.8 | 11.4 ± 0.6
Ratio to Brain, g/g | 6.72 ± 0.54 | 8.13 ± 0.47 | 6.83 ± 0.35 | 6.93 ± 0.40 | 7.21 ± 0.44 | 6.83 ± 0.40 | 7.42 ± 0.35 | 5.50 ± 0.30
Ratio to bw, mg/g | 32.3 ± 1.8 | 36.3 ± 1.7 | 32.2 ± 1.2 | 34.8 ± 1.2 | 34.7 ± 1.6 | 33.2 ± 1.3 | 34.1 ± 1.0 | 26.7 ± 1.0***
Retroperitoneal Fat Pad
Absolute, g | 14.1 ± 1.5 | 19.8 ± 2.0* | 16.1 ± 1.4 | 14.1 ± 1.1 | 14.1 ± 1.2 | 14.7 ± 1.2 | 15.6 ± 1.2 | 13.0 ± 0.9
Ratio to Brain, g/g | 6.72 ± 0.70 | 9.41 ± 0.97* | 7.64 ± 0.67 | 6.76 ± 0.52 | 6.84 ± 0.55 | 7.09 ± 0.56 | 7.41 ± 0.58 | 6.26 ± 0.44
Ratio to bw, mg/g | 32.4 ± 2.7 | 40.0 ± 2.8 | 35.0 ± 2.1 | 33.5 ± 1.7 | 32.9 ± 2.5 | 33.7 ± 1.6 | 33.7 ± 2.0 | 30.0 ± 1.5
Heart
Absolute, g | 1.31 ± 0.05 | 1.44 ± 0.04 | 1.42 ± 0.04 | 1.29 ± 0.03 | 1.31 ± 0.04 | 1.38 ± 0.04 | 1.40 ± 0.04 | 1.42 ± 0.04
Ratio to Brain, g/g | 0.63 ± 0.02 | 0.68 ± 0.02 | 0.67 ± 0.02 | 0.62 ± 0.01 | 0.64 ± 0.02 | 0.66 ± 0.02 | 0.67 ± 0.02 | 0.68 ± 0.02
Ratio to bw, mg/g | 3.16 ± 0.08 | 3.06 ± 0.08 | 3.21 ± 0.10 | 3.18 ± 0.09 | 3.13 ± 0.08 | 3.30 ± 0.08 | 3.13 ± 0.09 | 3.36 ± 0.04*
Kidney
Absolute, g | 2.27 ± 0.07 | 2.54 ± 0.08 | 2.51 ± 0.10 | 2.23 ± 0.06 | 2.31 ± 0.08 | 2.30 ± 0.07^c^ | 2.42 ± 0.08^c^ | 2.61 ± 0.08**
Ratio to Brain, g/g | 1.09 ± 0.03 | 1.21 ± 0.04 | 1.20 ± 0.05 | 1.07 ± 0.03 | 1.12 ± 0.03 | 1.11 ± 0.03 | 1.15 ± 0.04 | 1.26 ± 0.04**
Ratio to bw, mg/g | 5.50 ± 0.17 | 5.43 ± 0.17 | 5.69 ± 0.22 | 5.47 ± 0.12 | 5.51 ± 0.17 | 5.59 ± 0.13 | 5.34 ± 0.10 | 6.19 ± 0.10***
Liver
Absolute, g | 10.7 ± 0.5 | 12.4 ± 0.7 | 12.2 ± 0.5 | 10.8 ± 0.3 | 11.3 ± 0.5 | 11.6 ± 0.7 | 12.1 ± 0.4 | 12.8 ± 0.5**
Ratio to Brain, g/g | 5.12 ± 0.24 | 5.90 ± 0.36 | 5.81 ± 0.25 | 5.18 ± 0.16 | 5.49 ± 0.21 | 5.60 ± 0.30 | 5.77 ± 0.20 | 6.17 ± 0.21**
Ratio to bw, mg/g | 25.5 ± 0.6* | 25.9 ± 0.8 | 27.3 ± 0.6 | 26.4 ± 0.6 | 26.7 ± 0.7 | 27.2 ± 0.7 | 26.7 ± 0.7 | 30.1 ± 0.5***
Ovary
Absolute, mg | 140 ± 8^d^ | 147 ± 7 | 142 ± 6^d^ | 138 ± 5^d^ | 140 ± 7^d^ | 140 ± 5^d^ | 143 ± 4^d^ | 115 ± 8^*, d^
Ratio to Brain, mg/g | 67 ± 3 | 70 ± 4 | 68 ± 3 | 66 ± 2 | 68 ± 3 | 68 ± 3 | 68 ± 2 | 56 ± 4*
Ratio to bw, mg/g | 0.33 ± 0.02 | 0.32 ± 0.02 | 0.33 ± 0.01 | 0.34 ± 0.01 | 0.33 ± 0.01 | 0.34 ± 0.02 | 0.32 ± 0.01 | 0.28 ± 0.02*
Pituitary
Absolute, mg | 20.6 ± 1.1 | 21.2 ± 1.3 | 23.5 ± 1.8 | 20.4 ± 1.5 | 20.2 ± 1.4 | 21.6 ± 1.1 | 22.7 ± 1.7 | 26.9 ± 1.2**
Ratio to Brain, mg/g | 9.9 ± 0.5 | 10.0 ± 0.6 | 11.2 ± 0.9 | 9.8 ± 0.7 | 9.9 ± 0.7 | 10.4 ± 0.5 | 10.8 ± 0.8 | 13.1 ± 0.6**
Ratio to bw, mg/g | 0.05 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.06 ± 0**
Spleen
Absolute, mg | 598 ± 25 | 648 ± 27 | 638 ± 17 | 600 ± 20 | 642 ± 23 | 638 ± 26 | 645 ± 21 | 646 ± 25
Ratio to Brain, mg/g | 286 ± 11 | 307 ± 13 | 304 ± 8 | 288 ± 9 | 314 ± 10 | 307 ± 11 | 308 ± 10 | 311 ± 11
Ratio to bw, mg/g | 1.44 ± 0.05 | 1.37 ± 0.04 | 1.45 ± 0.05 | 1.48 ± 0.05 | 1.54 ± 0.05 | 1.52 ± 0.05 | 1.43 ± 0.04 | 1.52 ± 0.04
Thymus
Absolute, mg | 150 ± 11 | 185 ± 16 | 155 ± 12 | 135 ± 12 | 142 ± 9 | 151 ± 10 | 137 ± 10 | 137 ± 9
Ratio to Brain, mg/g | 72 ± 5 | 88 ± 8 | 74 ± 6 | 65 ± 6 | 70 ± 5 | 73 ± 5 | 65 ± 5 | 66 ± 4
Ratio to bw, mg/g | 0.37 ± 0.03 | 0.39 ± 0.03 | 0.35 ± 0.02 | 0.33 ± 0.03 | 0.34 ± 0.02 | 0.36 ± 0.02 | 0.30 ± 0.02 | 0.32 ± 0.02
Thyroid
Absolute, mg | 38.2 ± 1.7 | 37.4 ± 1.6 | 37.2 ± 1.5 | 35.8 ± 1.2 | 37.8 ± 2.0 | 38.5 ± 1.5 | 39.0 ± 1.8 | 36.5 ± 1.2
Ratio to Brain, mg/g | 18.3 ± 0.8 | 17.8 ± 0.8 | 17.8 ± 0.7 | 17.2 ± 0.6 | 18.5 ± 1.0 | 18.6 ± 0.7 | 18.6 ± 0.8 | 17.7 ± 0.6
Ratio to bw, mg/g | 0.09 ± 0 | 0.08 ± 0 | 0.08 ± 0 | 0.09 ± 0 | 0.09 ± 0 | 0.09 ± 0 | 0.09 ± 0 | 0.09 ± 0
Uterus
Absolute, mg | 773 ± 45 | 742 ± 52 | 872 ± 60^e^ | 757 ± 58 | 831 ± 51 | 832 ± 61 | 777 ± 38 | 827 ± 37
Ratio to Brain, mg/g | 371 ± 22 | 354 ± 26 | 414 ± 26 | 364 ± 28 | 411 ± 29 | 403 ± 30 | 372 ± 19 | 399 ± 16
Ratio to bw, mg/g | 1.92 ± 0.15 | 1.64 ± 0.14 | 1.98 ± 0.15 | 1.89 ± 0.16 | 2.05 ± 0.17 | 2.07 ± 0.21 | 1.76 ± 0.11 | 1.97 ± 0.09

^a^ BPA and EE_2_ doses are μg/kg bw/day. The indicated organs were collected from animals at the interim (one-year) necropsy and weights recorded. BPA and EE_2_ groups were analyzed separately. Paired organs are presented and were analyzed as combined weights. ANOVA was performed for absolute organ weights to determine the effect of treatment on organ weight. Separate ANOCOVA were performed to determine the effect of treatment on organ weight adjusted for brain weight or receiving weight. Comparisons of dosed groups versus vehicle control were performed using Dunnett’s method to adjust for multiple comparisons. Tests of trends, increasing treatment effect with increasing dose, were also performed for vehicle and BPA groups. Tests were conducted as two-sided at the 0.05 significance level. Statistically significant effects are indicated by asterisks (*, p < 0.05; **, p < 0.01; ***, p < 0.001); asterisks in the vehicle column indicate a significant trend, while asterisks in BPA or EE_2_ dose group columns indicate significant differences in pairwise comparisons to the vehicle group. There were no additional statistically significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods). The complete statistical report is found in Supplemental Appendix XXX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ For kidneys, n = 23 for both the 25,000 BPA and 0.05 EE_2_ dose groups.

^d^ For ovaries, n = 20 for vehicle group, 17 for 25 BPA, 21 for 250 BPA, 18 for 2,500 BPA, 21 for 25,000 BPA, and 23 for both 0.05 and 0.5 EE_2_ dose groups.

^e^ For uterus, n = 20 for 25 BPA dose group.

Multiple organ weights were significantly affected by the 0.5 μg EE_2_/kg bw/day treatment. Mean absolute adrenal weights, as well as adrenal weights adjusted for brain and body weights, were increased by 27%, 28%, and 22%, respectively. Mean ovarian/parametrial fat pad weight was decreased, with mean weight adjusted for body weight significantly decreased (~17%) relative to the vehicle control group mean. Mean heart weight was also increased in the high EE_2_ dose group, with mean heart weight adjusted for body weight significantly increased (~6%) relative to the vehicle control group mean. Mean absolute kidney weights, as well as kidney weights adjusted for brain and body weights, were increased relative to the vehicle control mean by 15%, 16%, and 13%, respectively. Mean absolute liver weights, as well as liver weights adjusted for brain and body weights, were increased relative to the vehicle control mean by 20%, 20%, and 18%, respectively. Mean absolute ovary weights, as well as ovary weights adjusted for brain and body weights, were decreased relative to the vehicle control mean by 18%, 16%, and 15%, respectively. Mean absolute pituitary weights, as well as pituitary weights adjusted for brain and body weights, were increased by 31%, 32%, and 20%, respectively.

### Females, Stop-Dose Arm

Summary statistics for organ weights collected from females in the BPA stop-dose groups are shown in Table 47. There were significant dose trends for absolute ovary weight and ovary weight adjusted for brain and body weight. The mean absolute ovary weight, as well as ovary weight adjusted for brain weight, in the 25,000 μg BPA/kg bw/day dose group were significantly lower than the vehicle control group by approximately 13% and 12%, respectively. Mean ovary weight adjusted for body weight was also 9% lower than the controls, but this difference was not statistically different.

Table 47 Female Organ Weights, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (22) | 25 BPA (20) | 250 BPA (22) | 2500 BPA (20) | 25000 BPA (20)
Body Weight
g | 465 ± 19 | 455 ± 14 | 437 ± 19 | 453 ± 19 | 454 ± 19 | 444 ± 14
Adrenal
Absolute, mg | 73.1 ± 2.9 | 70.0 ± 1.6 | 71.6 ± 2.7 | 71.2 ± 2.4 | 68.5 ± 2.9 | 75.6 ± 3.1
Ratio to Brain, mg/g | 34.9 ± 1.3 | 33.4 ± 0.7 | 34.3 ± 1.3 | 34.8 ± 1.2 | 32.8 ± 1.3 | 36.5 ± 1.4
Ratio to bw, mg/g | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.01
Brain
Absolute, g | 2.09 ± 0.02 | 2.10 ± 0.02 | 2.09 ± 0.03 | 2.05 ± 0.02 | 2.09 ± 0.02 | 2.07 ± 0.02
Ratio to bw, mg/g | 4.60 ± 0.14 | 4.68 ± 0.13 | 4.93 ± 0.20 | 4.68 ± 0.18 | 4.75 ± 0.20 | 4.75 ± 0.14
Ovarian/Parametrial Fat Pad
Absolute, g | 17.2 ± 1.2 | 16.2 ± 0.7 | 14.3 ± 1.0^c^ | 15.3 ± 1.1 | 16.3 ± 1.1 | 15.0 ± 0.9
Ratio to Brain, g/g | 8.17 ± 0.53 | 7.72 ± 0.33 | 6.84 ± 0.45^c^ | 7.47 ± 0.51 | 7.79 ± 0.53 | 7.22 ± 0.41
Ratio to bw, mg/g | 36.3 ± 1.3 | 35.4 ± 1.0 | 32.4 ± 1.1^c^ | 33.3 ± 1.6 | 35.6 ± 1.7 | 33.3 ± 1.1
Retroperitoneal Fat Pad
Absolute, g | 18.2 ± 1.6 | 15.4 ± 1.5 | 17.0 ± 1.8 | 17.1 ± 1.5 | 16.2 ± 1.3 | 16.4 ± 1.4
Ratio to Brain, g/g | 8.66 ± 0.67 | 7.36 ± 0.73 | 8.10 ± 0.87 | 8.28 ± 0.69 | 7.71 ± 0.61 | 7.93 ± 0.68
Ratio to bw, mg/g | 38.1 ± 1.8 | 33.3 ± 2.6 | 37.0 ± 2.7 | 36.3 ± 2.1 | 34.8 ± 2.0 | 36.0 ± 2.3
Heart
Absolute, g | 1.43 ± 0.05 | 1.36 ± 0.02 | 1.35 ± 0.04 | 1.37 ± 0.04 | 1.38 ± 0.04 | 1.35 ± 0.04
Ratio to Brain, g/g | 0.68 ± 0.02 | 0.65 ± 0.01 | 0.65 ± 0.02 | 0.67 ± 0.02 | 0.66 ± 0.02 | 0.65 ± 0.02
Ratio to bw, mg/g | 3.11 ± 0.08 | 3.02 ± 0.07 | 3.13 ± 0.09 | 3.07 ± 0.10 | 3.06 ± 0.07 | 3.06 ± 0.08
Kidney
Absolute, g | 2.47 ± 0.11 | 2.30 ± 0.09^d^ | 2.28 ± 0.09 | 2.41 ± 0.1^d^ | 2.35 ± 0.09 | 2.38 ± 0.08
Ratio to Brain, g/g | 1.18 ± 0.04 | 1.10 ± 0.04 | 1.09 ± 0.04 | 1.17 ± 0.04 | 1.12 ± 0.04 | 1.15 ± 0.04
Ratio to bw, mg/g | 5.34 ± 0.12 | 5.17 ± 0.23 | 5.24 ± 0.12 | 5.38 ± 0.15 | 5.22 ± 0.14 | 5.39 ± 0.15
Liver
Absolute, g | 12.3 ± 0.7 | 11.5 ± 0.4 | 11.2 ± 0.6 | 12.1 ± 0.6 | 12.0 ± 0.6 | 11.6 ± 0.4
Ratio to Brain, g/g | 5.86 ± 0.28 | 5.52 ± 0.19 | 5.38 ± 0.27 | 5.89 ± 0.26 | 5.70 ± 0.25 | 5.63 ± 0.20
Ratio to bw, mg/g | 26.4 ± 0.8 | 25.4 ± 0.6 | 25.7 ± 0.6 | 26.8 ± 0.8 | 26.4 ± 0.9 | 26.3 ± 0.6
Ovary
Absolute, mg | 157 ± 6* | 149 ± 4 | 148 ± 6 | 147 ± 4 | 147 ± 6 | 136 ± 5*
Ratio to Brain, mg/g | 75 ± 3* | 71 ± 2 | 71 ± 3 | 72 ± 2 | 70 ± 3 | 66 ± 3*
Ratio to bw, mg/g | 0.34 ± 0.02* | 0.33 ± 0.01 | 0.35 ± 0.02 | 0.33 ± 0.02 | 0.33 ± 0.01 | 0.31 ± 0.01
Pituitary
Absolute, mg | 21.1 ± 1 | 20.3 ± 0.8 | 19.9 ± 1.3 | 20.1 ± 0.7 | 19 ± 0.9 | 20.3 ± 1.1
Ratio to Brain, mg/g | 10.0 ± 0.4 | 9.7 ± 0.4 | 9.6 ± 0.7 | 9.8 ± 0.3 | 9.1 ± 0.4 | 9.8 ± 0.5
Ratio to bw, mg/g | 0.05 ± 0 | 0.04 ± 0 | 0.05 ± 0 | 0.05 ± 0 | 0.04 ± 0 | 0.05 ± 0
Spleen
Absolute, mg | 678 ± 30 | 618 ± 16 | 612 ± 24^e^ | 693 ± 24 | 659 ± 30 | 611 ± 17
Ratio to Brain, mg/g | 323 ± 11 | 295 ± 7^e^ | 293 ± 11^e^ | 339 ± 12 | 315 ± 14 | 295 ± 8
Ratio to bw, mg/g | 1.47 ± 0.05 | 1.37 ± 0.04 | 1.41 ± 0.04 | 1.56 ± 0.06 | 1.48 ± 0.07 | 1.40 ± 0.05
Thymus
Absolute, mg | 154 ± 7 | 139 ± 6^f^ | 142 ± 10 | 164 ± 14 | 150 ± 11 | 167 ± 12
Ratio to Brain, mg/g | 74 ± 3 | 67 ± 3 | 68 ± 5 | 80 ± 7 | 72 ± 5 | 80 ± 6
Ratio to bw, mg/g | 0.34 ± 0.02 | 0.31 ± 0.02 | 0.32 ± 0.02 | 0.37 ± 0.03 | 0.34 ± 0.03 | 0.38 ± 0.02
Thyroid
Absolute, mg | 37.8 ± 2.2 | 36.0 ± 1.6 | 36.3 ± 1.7 | 36.3 ± 1.3 | 38.2 ± 2.3 | 36.9 ± 1.7
Ratio to Brain, mg/g | 18.0 ± 1 | 17.2 ± 0.8 | 17.4 ± 0.8 | 17.7 ± 0.6 | 18.3 ± 1.1 | 17.8 ± 0.8
Ratio to bw, mg/g | 0.08 ± 0 | 0.08 ± 0 | 0.08 ± 0 | 0.08 ± 0 | 0.08 ± 0 | 0.08 ± 0
Uterus
Absolute, mg | 744 ± 46 | 699 ± 45 | 795 ± 80 | 843 ± 76^g^ | 747 ± 54 | 789 ± 51
Ratio to Brain, mg/g | 356 ± 22 | 334 ± 22 | 382 ± 40 | 410 ± 35 | 360 ± 28 | 381 ± 24
Ratio to bw, mg/g | 1.67 ± 0.14 | 1.58 ± 0.12 | 1.87 ± 0.19 | 1.93 ± 0.20 | 1.74 ± 0.16 | 1.83 ± 0.14

^a^ BPA doses are μg/kg bw/day. The indicated organs were collected from animals at the interim (one-year) necropsy and weights recorded. Paired organs are presented and were analyzed as combined weights. ANOVA was performed for absolute organ weights to determine the effect of treatment on organ weight. Separate ANOCOVA were performed to determine the effect of treatment on organ weight adjusted for brain weight or receiving body weight. Comparisons of dosed groups versus vehicle control were performed using Dunnett’s method to adjust for multiple comparisons. Tests of trends, increasing treatment effect with increasing dose, were also performed. Tests were conducted as two-sided at the 0.05 significance level. Statistically significant effects are indicated by asterisks (*, p < 0.05); asterisks in the vehicle column indicate a significant trend, while asterisks in BPA dose group columns indicate significant differences in pairwise comparisons to the vehicle group. The complete statistical report is found in Supplemental Appendix XXX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ 25 BPA ovarian/parametrial fat pad weight significantly different from vehicle control in sensitivity analysis (see Statistical Methods) that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day: absolute weight, 25.7% lower than control (p = 0.010); brain as covariate, 25% lower than control (p = 0.010); body weight as covariate, 13.7% lower than control (p = 0.035).

^d^ n = 21 for kidneys in the 2.5 and 250 BPA dose groups. One kidney weight in each indicated dose group was excluded because kidneys had grossly observable cysts.

^e^ Spleen weight statistically different from vehicle control in sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods): 2.5 BPA, brain covariate, 13.1% lower than control (p = 0.039); 25 BPA absolute and brain covariate, 14.2% and 13.7% lower than control, respectively (p = 0.023 for both).

^f^ n = 21 for thymus in the 2.5 BPA dose group, one (627 mg) excluded as a statistical outlier.

^g^ n = 21 for uterus in the 250 BPA dose group, one (4,680 mg) excluded as it was the only uterus noted to be fluid filled.

### Males, Continuous-Dose Arm

Summary statistics for organ weights collected from males in the continuous-dose BPA and EE_2_ dose groups are shown in Table 48. The sole significant BPA treatment effect was a lower (~7%) mean liver weight adjusted for body weight relative to the vehicle control in the 2.5 μg BPA/kg bw/day dose group. There were no significant treatment effects of either EE_2_ dose.

Table 48 Male Organ Weights, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (18)^b^ | 2.5 BPA (22) | 25 BPA (18) | 250 BPA (24) | 2500 BPA (18) | 25000 BPA (21) | 0.05 EE_2_ (22) | 0.5 EE_2_ (23)
Body Weight at Necropsy
g | 701 ± 19 | 722 ± 20 | 709 ± 21 | 713 ± 15 | 704 ± 26 | 695 ± 18 | 712 ± 21 | 704 ± 16
Adrenal
Absolute, mg | 60.1 ± 2.8 | 64.2 ± 2.8 | 68.0 ± 2.4 | 62.5 ± 2.1 | 61.7 ± 2.6 | 57.4 ± 1.7 | 62.6 ± 2.2^c^ | 62.9 ± 1.8
Ratio to Brain, mg/g | 26.1 ± 1.2 | 27.8 ± 1.1 | 29.7 ± 1.1 | 27.8 ± 0.8 | 27.0 ± 1.0 | 25.7 ± 0.8 | 27.4 ± 0.9 | 27.1 ± 0.7
Ratio to bw, mg/g | 0.09 ± 0 | 0.09 ± 0 | 0.10 ± 0 | 0.09 ± 0 | 0.09 ± 0 | 0.08 ± 0 | 0.09 ± 0 | 0.09 ± 0
Brain
Absolute, g | 2.30 ± 0.02 | 2.31 ± 0.03 | 2.30 ± 0.04 | 2.24 ± 0.03 | 2.28 ± 0.03 | 2.24 ± 0.02 | 2.29 ± 0.02 | 2.32 ± 0.02
Ratio to bw, mg/g | 3.32 ± 0.07 | 3.25 ± 0.10 | 3.27 ± 0.08 | 3.18 ± 0.08 | 3.30 ± 0.10 | 3.26 ± 0.08 | 3.27 ± 0.09 | 3.32 ± 0.07
Epididymides
Absolute, g | 1.28 ± 0.04 | 1.21 ± 0.04 | 1.32 ± 0.02 | 1.27 ± 0.04 | 1.27 ± 0.04 | 1.25 ± 0.02 | 1.24 ± 0.03 | 1.34 ± 0.03
Ratio to Brain, g/g | 0.56 ± 0.02 | 0.53 ± 0.02 | 0.58 ± 0.01 | 0.56 ± 0.02 | 0.56 ± 0.01 | 0.56 ± 0.01 | 0.54 ± 0.01 | 0.58 ± 0.01
Ratio to bw, mg/g | 1.85 ± 0.06 | 1.70 ± 0.07 | 1.89 ± 0.06 | 1.79 ± 0.06 | 1.83 ± 0.06 | 1.82 ± 0.06 | 1.76 ± 0.06 | 1.90 ± 0.04
Epididymal Fat Pad
Absolute, g | 13.0 ± 0.7 | 14.5 ± 0.8 | 13.6 ± 0.6 | 14.1 ± 0.8 | 14.3 ± 1.2 | 14.2 ± 1.0 | 14.2 ± 0.8 | 12.8 ± 0.8
Ratio to Brain, g/g | 5.62 ± 0.26 | 6.28 ± 0.37 | 5.91 ± 0.23 | 6.29 ± 0.39 | 6.24 ± 0.50 | 6.35 ± 0.45 | 6.18 ± 0.32 | 5.54 ± 0.33
Ratio to bw, mg/g | 18.5 ± 0.8 | 19.8 ± 0.7 | 19.2 ± 0.7 | 19.5 ± 1.0 | 20.0 ± 1.1 | 20.2 ± 1.2 | 19.8 ± 0.7 | 18.0 ± 0.8
Retroperitoneal Fat Pad
Absolute, g | 22.2 ± 1.8 | 22.8 ± 1.6 | 24.5 ± 2.5 | 22.9 ± 1.9 | 21.8 ± 2.7 | 23.6 ± 2.4 | 22.6 ± 2.3 | 21.0 ± 2.3
Ratio to Brain, g/g | 9.59 ± 0.74 | 9.88 ± 0.69 | 10.57 ± 1.02 | 10.19 ± 0.81 | 9.56 ± 1.21 | 10.59 ± 1.09 | 9.79 ± 0.97 | 9.04 ± 1.01
Ratio to bw, mg/g | 31.3 ± 2.0 | 30.9 ± 1.5 | 33.7 ± 2.6 | 31.5 ± 2.3 | 29.7 ± 2.7 | 33.2 ± 2.9 | 30.9 ± 2.5 | 29.0 ± 2.7
Heart
Absolute, g | 2.04 ± 0.06 | 2.14 ± 0.05 | 2.26 ± 0.08 | 2.21 ± 0.07 | 2.19 ± 0.07 | 1.99 ± 0.04 | 2.11 ± 0.06 | 2.12 ± 0.05
Ratio to Brain, g/g | 0.89 ± 0.02 | 0.93 ± 0.02 | 0.99 ± 0.04 | 0.98 ± 0.03 | 0.96 ± 0.03 | 0.89 ± 0.02 | 0.92 ± 0.02 | 0.91 ± 0.02
Ratio to bw, mg/g | 2.92 ± 0.07 | 3.00 ± 0.09 | 3.20 ± 0.10 | 3.11 ± 0.10 | 3.14 ± 0.09 | 2.88 ± 0.05 | 2.99 ± 0.08 | 3.02 ± 0.08
Kidney
Absolute, g | 4.08 ± 0.15^d^ | 4.20 ± 0.12 | 4.15 ± 0.17^d^ | 4.05 ± 0.11 | 4.00 ± 0.17^d^ | 3.88 ± 0.08 | 4.01 ± 0.13^d^ | 4.17 ± 0.12
Ratio to Brain, g/g | 1.77 ± 0.05 | 1.82 ± 0.05 | 1.80 ± 0.06 | 1.80 ± 0.04 | 1.75 ± 0.07 | 1.73 ± 0.04 | 1.75 ± 0.05 | 1.80 ± 0.05
Ratio to bw, mg/g | 5.83 ± 0.14 | 5.85 ± 0.14 | 5.87 ± 0.15 | 5.70 ± 0.12 | 5.67 ± 0.16 | 5.62 ± 0.11 | 5.63 ± 0.10 | 5.91 ± 0.09
Liver
Absolute, g | 22.1 ± 0.9 | 21.1 ± 0.7 | 22.6 ± 1.0 | 22.4 ± 0.6 | 22.1 ± 1.0 | 20.6 ± 0.6 | 22.2 ± 0.7 | 23.1 ± 0.6
Ratio to Brain, g/g | 9.58 ± 0.34 | 9.15 ± 0.29 | 9.84 ± 0.34 | 9.97 ± 0.26 | 9.71 ± 0.43 | 9.21 ± 0.26 | 9.66 ± 0.29 | 9.96 ± 0.29
Ratio to bw, mg/g | 31.4 ± 0.6 | 29.3 ± 0.6* | 31.9 ± 0.8 | 31.4 ± 0.5 | 31.4 ± 0.6 | 29.7 ± 0.5 | 31.1 ± 0.5 | 32.7 ± 0.4
Pituitary
Absolute, mg | 14.6 ± 0.7 | 14.6 ± 0.6 | 15.2 ± 0.6 | 16.1 ± 1.2 | 15.4 ± 0.8 | 15.1 ± 0.6 | 15.6 ± 0.6 | 16.0 ± 0.5
Ratio to Brain, mg/g | 6.3 ± 0.2 | 6.3 ± 0.3 | 6.7 ± 0.3 | 7.1 ± 0.5 | 6.7 ± 0.4 | 6.7 ± 0.3 | 6.8 ± 0.3 | 6.9 ± 0.2
Ratio to bw, mg/g | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0
Seminal Vesicles
Absolute, g | 1.18 ± 0.04 | 1.11 ± 0.05 | 1.14 ± 0.05 | 1.17 ± 0.05 | 1.10 ± 0.06 | 1.19 ± 0.04 | 1.27 ± 0.06 | 1.12 ± 0.04
Ratio to Brain, g/g | 0.51 ± 0.02 | 0.48 ± 0.02 | 0.50 ± 0.02 | 0.52 ± 0.02 | 0.48 ± 0.02 | 0.53 ± 0.02 | 0.56 ± 0.03 | 0.49 ± 0.02
Ratio to bw, mg/g | 1.70 ± 0.06 | 1.56 ± 0.07 | 1.64 ± 0.09 | 1.66 ± 0.08 | 1.58 ± 0.10 | 1.73 ± 0.08 | 1.82 ± 0.10 | 1.60 ± 0.05
Spleen
Absolute, g | 0.92 ± 0.03 | 0.96 ± 0.03 | 0.97 ± 0.04 | 0.96 ± 0.03 | 0.96 ± 0.04 | 0.87 ± 0.03 | 0.94 ± 0.04 | 1.01 ± 0.05
Ratio to Brain, g/g | 0.40 ± 0.01 | 0.42 ± 0.01 | 0.42 ± 0.02 | 0.43 ± 0.01 | 0.42 ± 0.02 | 0.39 ± 0.01 | 0.41 ± 0.02 | 0.44 ± 0.02
Ratio to bw, mg/g | 1.33 ± 0.05 | 1.33 ± 0.04 | 1.39 ± 0.06 | 1.36 ± 0.04 | 1.36 ± 0.05 | 1.26 ± 0.04 | 1.32 ± 0.04 | 1.44 ± 0.07
Testes
Absolute, g | 3.59 ± 0.12 | 3.44 ± 0.13 | 3.62 ± 0.08 | 3.38 ± 0.14 | 3.56 ± 0.08 | 3.51 ± 0.12 | 3.48 ± 0.09 | 3.56 ± 0.09
Ratio to Brain, g/g | 1.56 ± 0.05 | 1.50 ± 0.06 | 1.58 ± 0.04 | 1.50 ± 0.06 | 1.56± 0.03 | 1.57 ± 0.05 | 1.52 ± 0.04 | 1.54 ± 0.04
Ratio to bw, mg/g | 5.16 ± 0.18 | 4.82 ± 0.21 | 5.18 ± 0.19 | 4.77 ± 0.21 | 5.12 ± 0.13 | 5.14 ± 0.22 | 4.96 ± 0.18 | 5.09 ± 0.13
Thymus
Absolute, mg | 150 ± 11 | 138 ± 9 | 125 ± 12 | 158 ± 10 | 140 ± 10 | 150 ± 11 | 124 ± 11 | 154 ± 10
Ratio to Brain, g/g | 65 ± 5 | 60 ± 4 | 54 ± 5 | 71 ± 4 | 62 ± 5 | 67 ± 5 | 54 ± 5 | 67 ± 4
Ratio to bw, mg/g | 0.22 ± 0.02 | 0.20 ± 0.02 | 0.18 ± 0.02 | 0.22 ± 0.01 | 0.20 ± 0.02 | 0.22 ± 0.02 | 0.17 ± 0.01 | 0.22 ± 0.01
Thyroid
Absolute, mg | 43.5 ± 2.0 | 42.7 ± 2.4 | 44.0 ± 2.5 | 42.2 ± 1.6 | 40.9 ± 1.9 | 44.5 ± 1.8 | 43.6 ± 2.0 | 43.7 ± 1.5
Ratio to Brain,mg/g | 18.8 ± 0.8 | 18.5 ± 1.0 | 19.1 ± 1.0 | 18.8 ± 0.7 | 17.8 ± 0.7 | 19.9 ± 0.8 | 19.0 ± 0.9 | 18.9 ± 0.6
Ratio to bw, mg/g | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0

^a^ BPA and EE_2_ doses are μg/kg bw/day. The indicated organs were collected from animals at the interim (one-year) necropsy and weights recorded. BPA and EE_2_ groups were analyzed separately. Paired organs are presented and were analyzed as combined weights. ANOVA was performed for absolute organ weights to determine the effect of treatment on organ weight. Separate ANOCOVA were performed to determine the effect of treatment on organ weight adjusted for brain weight or receiving weight. Comparisons of dosed groups versus vehicle control were performed using Dunnett’s method to adjust for multiple comparisons. Tests of trends, increasing treatment effect with increasing dose, were also performed for vehicle and BPA groups. Tests were conducted as two-sided at the 0.05 significance level. Statistically significant effects are indicated by asterisks (*, p < 0.05). There were no additional statistically significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods). The complete statistical report is found in Supplemental Appendix XXX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ For adrenal, n = 21 for the 0.05 EE_2_ dose group.

^d^ For kidneys, n = 17 for vehicle, 25 BPA, and 2,500 BPA dose groups; n = 21 for 0.05 EE_2_ dose group.

### Males, Stop-Dose Arm

Summary statistics for organ weights collected from males in the BPA stop-dose groups are shown in Table 49. The sole significant treatment effect was a significant dose trend for liver weight adjusted for body weight.

Table 49 Male Organ Weights, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (20) | 25 BPA (19) | 250 BPA (19) | 2500 BPA (20) | 25000 BPA (22)
Body Weight at Necropsy
g | 735 ± 26 | 787 ± 23 | 760 ± 22 | 733 ± 21 | 738 ± 21 | 743 ± 17
Adrenal
Absolute, mg | 63.4 ± 2.0 | 65.7 ± 2.1 | 67.9 ± 3.3 | 68.9 ± 2.7 | 65.4 ± 3.5 | 68.3 ± 3.3
Ratio to Brain, mg/g | 27.3 ± 0.8 | 28.2 ± 0.9 | 29.3 ± 1.5 | 30.0 ± 1.3 | 28.7 ± 1.4 | 29.6 ± 1.3
Ratio to bw, mg/g | 0.09 ± 0 | 0.08 ± 0 | 0.09 ± 0 | 0.10 ± 0 | 0.09 ± 0 | 0.09 ± 0
Brain
Absolute, g | 2.32 ± 0.02 | 2.33 ± 0.02 | 2.32 ± 0.03 | 2.30 ± 0.03 | 2.28 ± 0.02 | 2.30 ± 0.03
Ratio to bw, mg/g | 3.24 ± 0.12 | 3.00 ± 0.08 | 3.10 ± 0.09 | 3.17 ± 0.07 | 3.13 ± 0.09 | 3.13 ± 0.08
Epididymides
Absolute, g | 1.31 ± 0.03 | 1.28 ± 0.03 | 1.30 ± 0.03 | 1.32 ± 0.03 | 1.26 ± 0.04 | 1.37 ± 0.02
Ratio to Brain, g/g | 0.56 ± 0.01 | 0.55 ± 0.02 | 0.56 ± 0.01 | 0.57 ± 0.02 | 0.56 ± 0.02 | 0.60 ± 0.01
Ratio to bw, mg/g | 1.83 ± 0.08 | 1.65 ± 0.06 | 1.73 ± 0.05 | 1.83 ± 0.07 | 1.73 ± 0.07 | 1.87 ± 0.05
Epididymal Fat Pad
Absolute, g | 13.9 ± 0.7 | 16.0 ± 0.9 | 14.9 ± 1.0 | 13.5 ± 0.6 | 14.8 ± 1.0^c^ | 14.6 ± 0.7
Ratio to Brain, g/g | 5.99 ± 0.31 | 6.85 ± 0.38 | 6.38 ± 0.44 | 5.82 ± 0.26 | 6.52 ± 0.41 | 6.38 ± 0.33
Ratio to bw, mg/g | 18.8 ± 0.5 | 20.3 ± 0.9 | 19.2 ± 0.9 | 18.3 ± 0.7 | 19.8 ± 0.9 | 19.6 ± 0.7
Retroperitoneal Fat Pad
Absolute, g | 25.0 ± 2.3 | 27.8 ± 2.0 | 25.6 ± 2.3 | 23.0 ± 1.7 | 23.4 ± 2.7 | 25.0 ± 2.1
Ratio to Brain, g/g | 10.8 ± 1.0 | 11.9 ± 0.8 | 11.0 ± 1.0 | 10.0 ± 0.7 | 10.3 ± 1.2 | 10.9 ± 0.9
Ratio to bw, mg/g | 33.1 ± 2.1 | 34.7 ± 1.6 | 33.0 ± 2.3 | 31.3 ± 2.0 | 31.0 ± 2.9 | 33.0 ± 2.2
Heart
Absolute, g | 2.27 ± 0.07 | 2.45 ± 0.09 | 2.40 ± 0.08 | 2.25 ± 0.08 | 2.22 ± 0.07 | 2.35 ± 0.10
Ratio to Brain, g/g | 0.98 ± 0.03 | 1.05 ± 0.04 | 1.03 ± 0.04 | 0.97 ± 0.03 | 0.98 ± 0.03 | 1.02 ± 0.05
Ratio to bw, mg/g | 3.12 ± 0.08 | 3.13 ± 0.09 | 3.18 ± 0.11 | 3.09 ± 0.10 | 3.04 ± 0.10 | 3.20 ± 0.16
Kidney
Absolute, g | 4.38 ± 0.15 | 4.43 ± 0.15 | 4.54 ± 0.11 | 4.32 ± 0.11 | 4.17 ± 0.15 | 4.33 ± 0.10^d^
Ratio to Brain, g/g | 1.89 ± 0.07 | 1.90 ± 0.06 | 1.95 ± 0.05 | 1.88 ± 0.05 | 1.83 ± 0.06 | 1.89 ± 0.04
Ratio to bw, mg/g | 5.98 ± 0.09 | 5.62 ± 0.09 | 6.01 ± 0.13 | 5.94 ± 0.15 | 5.64 ± 0.08 | 5.78 ± 0.09
Liver
Absolute, g | 23.6 ± 0.9 | 24.4 ± 0.7 | 25.1 ± 1.0 | 23.2 ± 0.8 | 24.8 ± 1.0 | 25.1 ± 0.9
Ratio to Brain, g/g | 10.2 ± 0.4 | 10.5 ± 0.3 | 10.8 ± 0.4 | 10.1 ± 0.3 | 10.9 ± 0.4 | 10.9 ± 0.4
Ratio to bw, mg/g | 32.1 ± 0.4* | 31.1 ± 0.5 | 33.1 ± 1.0 | 31.8 ± 0.8 | 33.6 ± 0.7 | 33.9 ± 1.2
Pituitary
Absolute, mg | 15.1 ± 0.6 | 16.5 ± 0.9 | 15.3 ± 0.3 | 15.6 ± 0.6 | 14.5 ± 0.4 | 15.1 ± 0.5
Ratio to Brain, mg/g | 6.5 ± 0.2 | 7.1 ± 0.4 | 6.6 ± 0.1 | 6.8 ± 0.2 | 6.4 ± 0.2 | 6.6 ± 0.2
Ratio to bw, mg/g | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0 | 0.02 ± 0
Seminal Vesicles
Absolute, g | 1.22 ± 0.05 | 1.23 ± 0.06 | 1.27 ± 0.09 | 1.12 ± 0.05 | 1.12 ± 0.07 | 1.17 ± 0.04
Ratio to Brain, g/g | 0.53 ± 0.02 | 0.53 ± 0.02 | 0.54 ± 0.04 | 0.48 ± 0.02 | 0.49 ± 0.03 | 0.51 ± 0.02
Ratio to bw, mg/g | 1.69 ± 0.08 | 1.58 ± 0.07 | 1.70 ± 0.13 | 1.54 ± 0.07 | 1.52 ± 0.09 | 1.59 ± 0.07
Spleen
Absolute, g | 1.00 ± 0.03 | 1.04 ± 0.04 | 1.02 ± 0.03 | 1.03 ± 0.05 | 1.07 ± 0.06 | 1.06 ± 0.06
Ratio to Brain, g/g | 0.43 ± 0.01 | 0.45 ± 0.02 | 0.44 ± 0.01 | 0.45 ± 0.02 | 0.47 ± 0.03 | 0.46 ± 0.02
Ratio to bw, mg/g | 1.38 ± 0.05 | 1.33 ± 0.06 | 1.34 ± 0.04 | 1.42 ± 0.07 | 1.46 ± 0.08 | 1.44 ± 0.10
Testes
Absolute, g | 3.64 ± 0.07 | 3.59 ± 0.08 | 3.63 ± 0.09 | 3.49 ± 0.09 | 3.55 ± 0.15 | 3.71 ± 0.06
Ratio to Brain, g/g | 1.57 ± 0.03 | 1.54 ± 0.04 | 1.57 ± 0.05 | 1.52 ± 0.04 | 1.56 ± 0.07 | 1.62 ± 0.03
Ratio to bw, mg/g | 5.05 ± 0.17 | 4.62 ± 0.13 | 4.82 ± 0.13 | 4.82 ± 0.18 | 4.84 ± 0.18 | 5.04 ± 0.14
Thymus
Absolute, mg | 137 ± 9 | 123 ± 5 | 154 ± 10 | 130 ± 8 | 134 ± 9 | 145 ± 8
Ratio to Brain, mg/g | 59 ± 4 | 53 ± 2 | 66 ± 4 | 57 ± 3 | 59 ± 4 | 63 ± 4
Ratio to bw, mg/g | 0.19 ± 0.01 | 0.16 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.20 ± 0.1
Thyroid
Absolute, mg | 43.1 ± 1.9 | 43.4 ± 2.5 | 44.9 ± 1.8 | 41.2 ± 1.9 | 42.2 ± 2.4 | 45.4 ± 2.7
Ratio to Brain, mg/g | 18.6 ± 0.8 | 18.6 ± 1.1 | 19.4 ± 0.8 | 18.0 ± 0.9 | 18.6 ± 1.0 | 19.7 ± 1.1
Ratio to bw, mg/g | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0 | 0.06 ± 0

^a^ BPA doses are μg/kg bw/day. The indicated organs were collected from animals at the interim (one-year) necropsy and weights recorded. Paired organs are presented and were analyzed as combined weights. ANOVA was performed for absolute organ weights to determine the effect of treatment on organ weight. Separate ANOCOVA were performed to determine the effect of treatment on organ weight adjusted for brain weight or receiving weight. Comparisons of dosed groups versus vehicle control were performed using Dunnett’s method to adjust for multiple comparisons. Tests of trends, increasing treatment effect with increasing dose, were also performed for vehicle and BPA groups. Tests were conducted as two-sided at the 0.05 significance level. Statistically significant effects are indicated by asterisks (*, p < 0.05); asterisks in the vehicle column indicate a significant trend. There were no additional statistically significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods). The complete statistical report is found in Supplemental Appendix XXX.

^b^ Numbers in parentheses are the number of animals examined. Any deviations from this number due to exclusions are indicated by footnotes.

^c^ For epididymal fat pad, n = 19 for 2,500 BPA dose group.

^d^ For kidney, n = 20 for 25,000 BPA dose group.

## Sperm Analysis, Interim Sacrifice Animals

Testicular spermatid head counts, caudal sperm counts, and caudal sperm motility and morphology data are shown in Table 50 for continuous BPA and EE_2_ dose groups and in Table 51 for BPA stop-dose groups. There were no significant treatment effects observed for either compound.

Table 50 Sperm Analysis, Vehicle, BPA, and EE_2_ Continuous-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (18)^b^ | 2.5 BPA (22) | 25 BPA (18) | 250 BPA (24) | 2500 BPA (18) | 25000 BPA (21) | 0.05 EE_2_ (22) | 0.5 EE_2_ (23)
Testicular spermatid heads, 10^6^/g | 83.4 ± 9.5 | 76.8 ± 7.7 | 88.5 ± 6.1 | 81.5 ± 6.8 | 85.1 ± 7.1 | 76.6 ± 6.0 | 70.0 ± 4.7 | 73.7 ± 4.5
Cauda sperm counts, 10^6^/g | 991 ± 78 | 999 ± 88 | 1076 ± 68 | 998 ± 69 | 1062 ± 51 | 1027 ± 81 | 892 ± 72 | 857 ± 53
Cauda sperm, % Motility | 65.9 ± 4.6 | 64.0 ± 5.1 | 72.4 ± 3.1 | 66.7 ± 4.5 | 69.9 ± 3.4 | 69.4 ± 4.2 | 67.2 ± 4.8 | 70.8 ± 2.7
Cauda sperm, head, abnormal counts per animal | 0.00 ± 0 | 0.05 ± 0.05 | 0.06 ± 0.06 | 0.08 ± 0.06 | 0.11 ± 0.08 | 0.00 ± 0 | 0.23 ± 0.10 | 0.04 ± 0.04
Cauda sperm, tail, abnormal counts per animal | 0.17 ± 0.10 | 0.36 ± 0.13 | 0.17 ± 0.10 | 0.08 ± 0.06 | 0.11 ± 0.08 | 0.14 ± 0.08 | 0.23 ± 0.10 | 0.13 ± 0.08
Cauda sperm, head and tail combined, abnormal counts per animal | 0.17 ± 0.10 | 0.41 ± 0.14 | 0.22 ± 0.11 | 0.17 ± 0.08 | 0.22 ± 0.11 | 0.14 ± 0.08 | 0.45 ± 0.14 | 0.17 ± 0.09

^a^ BPA and EE_2_ doses are μg/kg bw/day. Values presented are means ± S.E.M. BPA and EE_2_ groups were analyzed separately. Testicular spermatid head counts, cauda sperm counts, and percent sperm motility were analyzed using an ANOVA model. Analysis of sperm morphology data was performed using a generalized linear model with a Poisson distribution and a log link function. Pairwise comparisons to the vehicle control group were adjusted for multiple comparisons using Dunnett’s method. Tests of trends, increasing treatment effect with increasing dose, were also performed for vehicle and BPA groups only. All tests were conducted as two-sided at the 0.05 significance level. There were no significant treatment effects. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods). The full statistical report is found in Supplemental Appendix XXXI.

^b^ Numbers in parentheses are numbers of animals examined.

Table 51 Sperm Analysis, Vehicle and BPA Stop-Dose, Interim Sacrifice (Mean ± S.E.M.)^a^

Endpoint, Units | Vehicle (20)^b^ | 2.5 BPA (20) | 25 BPA (19) | 250 BPA (19) | 2500 BPA (20) | 25000 BPA (22)
Testicular spermatid heads, 10^6^/g | 76.5 ± 9.4 | 77.7 ± 4.8 | 72.2 ± 5.3 | 72.5 ± 6.3 | 73.6 ± 9.0 | 75.8 ± 4.7
Cauda sperm counts, 10^6^/g | 1,059 ± 87 | 1,186 ± 83 | 1,017 ± 66 | 1,111 ± 66 | 1,020 ± 89 | 1,016 ± 81
Cauda sperm % Motility | 74.8 ± 4.3 | 75.8 ± 2.3 | 72.4 ± 3.4 | 70.2 ± 4.2 | 67.9 ± 5.6 | 77.7 ± 2.2
Cauda sperm, head, abnormal counts per animal | 0.00 ± 0 | 0.00 ± 0 | 0.11 ± 0.07 | 0.05 ± 0.05 | 0.10 ± 0.07 | 0.00 ± 0
Cauda sperm, tail, abnormal counts per animal | 0.15 ± 0.09 | 0.15 ± 0.09 | 0.21 ± 0.11 | 0.11 ± 0.07 | 0.20 ± 0.10 | 0.00 ± 0
Cauda sperm, head and tail combined, abnormal counts per animal | 0.15 ± 0.09 | 0.015 ± 0.09 | 0.32 ± 0.13 | 0.16 ± 0.09 | 0.30 ± 0.12 | 0.00 ± 0

^a^ BPA doses are μg/kg bw/day. Values presented are means ± S.E.M. Testicular spermatid head counts, cauda sperm counts, and percent sperm motility were analyzed using an ANOVA model. Analysis of sperm morphology data was performed using a generalized linear model with a Poisson distribution and a log link function. Pairwise comparisons to the vehicle control group were adjusted for multiple comparisons using Dunnett’s method. Tests of trends, increasing treatment effect with increasing dose, were also performed. All tests were conducted as two-sided at the 0.05 significance level. There were no significant treatment effects. Also, there were no additional statistically significant effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods). The full statistical report is found in Supplemental Appendix XXXI.

^b^ Numbers in parentheses are numbers of animals examined.

## Histopathology

The pathology report, which has tabulations of organs assessed and all lesions noted in all animals in both the interim (one-year) and terminal (two-year) phases of the study, along with the Study Pathologist’s narrative report, is found in Supplemental Appendix XXXII. Neoplastic lesions that showed any statistically significant increased incidence for either BPA or the reference estrogen, EE_2_, are discussed below. As noted in the pathology narrative, many non-neoplastic lesions common to aging animals in this strain of rat were found in both sexes at one and two years of age. Incidences were highly variable across dose groups and BPA treatment effects were not evident to the Study Pathologist. After the finalization of the pathology report, statistical analyses, described in Materials and Methods, were conducted for any lesion that had an incidence of two or more in the interim sacrifice animals or in the EE_2_ terminal sacrifice animals and four or more in the BPA-treated terminal sacrifice animals. All statistical results are shown in Supplemental Appendix XXXIII for interim sacrifice animals and Supplemental Appendix XXXIV for terminal sacrifice animals and selected lesions with statistically significant increased incidences in BPA or EE_2_ dose groups are discussed below. Lesions for which there was significantly lower incidence in treatment groups relative to vehicle controls are generally not discussed, although a few of these cases are presented. For statistical analyses of microscopic lesions, one-sided p-values with no correction for multiple comparisons are reported for pairwise comparisons with the vehicle control, while two-sided results are reported for trends. In the text, the unadjusted incidence (i.e., lesions observed/animals examined) is reported, while in the tables both the unadjusted and survival-adjusted (Poly-3) incidences are shown for terminal sacrifice animals.

### Females

Neoplastic lesions showing statistically significant differences in the BPA dose groups versus the vehicle control group were limited to the female mammary gland and uterus. For EE_2_, there were significant trends and significant differences between the high dose group and vehicle control for adenocarcinomas in the mammary gland and combined adenoma/carcinoma in the pituitary pars distalis. Significant dose trends were also noted in terminal sacrifice animals for benign pheochromocytoma in the adrenal medulla and C-cell adenomas in the thyroid gland with incidences in the high dose EE_2_ group of 8% versus 0% in controls for both cases (Supplemental Appendix XXXII and XXXIV).

#### Mammary gland, neoplastic lesions

Neoplastic lesions in the mammary glands of interim and terminal sacrifice females for continuous BPA, continuous EE_2_ and stop-dose BPA treatments are shown in Table 52, Table 53, and Table 54, respectively. Fibroadenomas are a common high-incidence lesion in this strain of rats, with a historical control incidence at two years of 132/210 (63%, range 59–69%). Fibroadenomas were observed in 4–25% of interim sacrifice females and 54–90% of terminal sacrifice animals with no significant treatment effects. Fibroadenoma counts in each affected animal were recorded and are found in an appendix to the pathology report (Supplemental Appendix XXXII, Subappendix VII).

Table 52 Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a, b^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenocarcinoma | Interim^c^ | Incidence | 0/23 | 1/22 (4%) | 1/22 (4%) | 0/24 | 0/20 | 0/24
| Terminal | Incidence | 4/50 (8%) | 6/48 (12%) | 6/46 (13%) | 5/49 (10%) | 9/50 (18%) | 3/46 (6%)
| | Poly-3 Incidence | 4/34.4 (12%) | 6/32.9 (18%) | 6/30.4 (20%) | 5/34.6 (14%) | 9/31.3 (29%) | 3/31.2 (10%)
| | Terminal Incidence | 3/16 (19%) | 6/19 (32%) | 1/14 (7%) | 0/13 (0%) | 3/10 (30%) | 0/8 (0%)
| | Time-to-First | 673 | 719 (T) | 434 | 377 | 561 | 685
| | Poly-3 p-value | 0.412 | 0.336 | 0.286 | 0.504 | 0.071 | 0.555N
| | Multiple Incidence^d^ | 2/50 (4%) | 3/48 (6%) | 3/46 (7%) | 2/49 (4%) | 3/50 (6%) | 1/46 (2%)
Adenoma or Adenocarcinoma | Interim^c^ | Incidence | 0/23 | 1/22 (4%) | 1/22 (4%) | 0/24 | 0/20 | 0/24
| Terminal | Incidence | 6/50 (12%) | 7/48 (15%) | 8/46 (17%) | 6/49 (12%) | 10/50 (20%) | 4/46 (9%)
| | Poly-3 Incidence | 6/34.9 (17%) | 7/32.9 (21%) | 8/30.4 (26%) | 6/34.8 (17%) | 10/31.3 (32%) | 4/31.8 (13%)
| | Terminal Incidence | 4/16 (25%) | 7/19 (37%) | 3/14 (21%) | 0/13 (0%) | 4/10 (40%) | 0/8 (0%)
| | Time-to-First | 564 | 719 (T) | 434 | 377 | 561 | 542
| | Poly-3 p-value | 0.513N | 0.452 | 0.271 | 0.624 | 0.126 | 0.428N
| | Multiple indicence^d^ | 2/50 (4%) | 3/48 (6%) | 3/46 (7%) | 3/49 (6%) | 3/50 (6%) | 1/46 (2%)
Fibroadenoma | Interim | Incidence | 2/23 (9%) | 3/22 (13%) | 3/22 (13%) | 1/24 (4%) | 2/20 (10%) | 6/24 (25%)
| | Terminal Incidence | 2/21 (10%) | 3/22 (14%) | 2/21 (10%) | 0/22 (0%) | 2/20 (10%) | 6/24 (25%)
| | Time-to-First | 361 (T) | 356 (T) | 311 | 256 | 362 (T) | 362 (T)
| | CAFE p-value | 0.150 | 0.478 | 0.478 | 0.484N | 0.641 | 0.136
| | Multiple Incidence^d^ | 0/23 (0%) | 0/22 (0%) | 1/22 (5%) | 0/24 (0%) | 0/20 (0%) | 1/24 (4%)
| Terminal | Incidence | 41/50 (82%) | 40/48 (83%) | 33/46 (72%) | 39/49 (80%) | 35/50 (70%) | 38/46 (83%)
| | Poly-3 Incidence | 41/47.0 (87%) | 40/43.7 (92%) | 33/38.4 (86%) | 39/45.3 (86%) | 35/42.3 (83%) | 38/42.2 (90%)
| | Terminal Incidence | 13/16 (81%) | 17/19 (90%) | 12/14 (86%) | 10/13 (77%) | 7/10 (70%) | 7/8 (88%)
| | Time-to-First | 431 | 321 | 434 | 261 | 419 | 467
| | Poly-3 p-value | 0.410N | 0.366 | 0.567N | 0.565N | 0.366N | 0.457
| | Multiple Incidence^d^ | 21/50 (42%) | 32/48 (67%) | 20/46 (43%) | 32/49 (65%) | 21/50 (42%) | 31/46 (67%)

^a^ BPA doses are μg/kg bw/day. Statistical analyses were conducted for any lesion that was diagnosed in two animals in any dose group in the interim sacrifice groups or in the EE_2_ terminal sacrifice groups or four animals in the control and BPA groups in the terminal sacrifice. A complete tabulation of all neoplastic lesions is found in Supplemental Appendix XXXII and complete results of the statistical analyses are found in Supplemental Appendices XXXIII (interim sacrifice) and XXXIV (terminal sacrifice). Details of the statistical methods are found in Materials and Methods and in Supplemental Appendices XXXIII (interim sacrifice) and XXXIV (terminal sacrifice). Data are presented as follows: Incidence, lesions observed/number of animals examined microscopically with percent animals affected in parentheses; Poly-3 Incidence, Poly-3 adjusted neoplasm incidence after adjustment for intercurrent mortality in terminal sacrifice animals; Terminal Incidence, lesions observed/number of animals reaching terminal sacrifice that were microscopically examined. Time-to-First, age of animal in which lesion was first observed, T in parentheses indicates that the first observation occurred at terminal sacrifice. For interim sacrifice data: CAFE p-value, p-value for Cochran-Armitage trend test in vehicle column, Fisher’s exact test versus vehicle control in dose columns. For terminal sacrifice data, the Poly-3 p-value for the trend test is given in the vehicle column and values for pairwise comparisons to vehicle control are shown in dose columns. Significant trends are shown in the vehicle column, while significant pairwise comparisons to the vehicle control are shown in BPA and EE_2_ dose group columns. All p-values are one-sided and not corrected for multiple comparisons. “N” next to a p-value indicates a result that is a negative trend or negative relative to control. Significant effects are indicated with asterisks. *, p < 0.05; **, p < 0.01; ***, p < 0.001.

^b^ There were no statistically significant effects in the female mammary gland in the continuous BPA dose groups in the interim or terminal sacrifice animals.

^c^ Statistical analysis was not conducted since no group had 2 or more lesions diagnosed. There were no multiple adenocarcinomas in interim sacrifice animals.

^d^ Proportion of animals examined that had multiple neoplasms. These animals with multiple neoplasms are included in the incidence row and were not analyzed separately. The numbers of mammary neoplasms found in each female are tabulated in Supplemental Appendix XXXII, Subappendix VII.

Table 53 Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Adenocarcinoma^c^ | Interim | Incidence^d^ | 0/23 (0%) | 2/26 (8%) | 0/26 (0%)
| | Terminal Incidence | 0/21 (0%) | 1/24 (4%) | 0/26 (0%)
| | Time-to-First | – | 257 | –
| | CAFE p-value | 0.639N | 0.276 | –
| Terminal | Incidence | 4/50 (8%) | 2/26 (8%) | 10/26 (38%)
| | Poly-3 Incidence | 4/34.4 (12%) | 2/16.8 (12%) | 10/17.6 (57%)
| | Terminal Incidence | 3/16 (19%) | 0/7 (0%) | 3/4 (75%)
| | Time-to-First | 673 | 490 | 488
| | Poly-3 p-value | <0.001*** | 0.667 | <0.001***
| | Multiple Incidence^e^ | 2/50 (4%) | 0/26 | 4/26 (15%)
Fibroadenoma | Interim | Incidence^d^ | 2/23 (9%) | 2/26 (8%) | 4/26 (15%)
| | Terminal Incidence | 2/21 (10%) | 2/24 (8%) | 4/26 (15%)
| | Time-to-First | 361 (T) | 361 (T) | 360 (T)
| | CAFE p-value | 0.297 | 0.647N | 0.395
| Terminal | Incidence | 41/50 (82%) | 18/26 (69%) | 14/26 (54%)
| | Poly-3 Incidence | 41/47.0 (87%) | 18/22.3 (81%) | 14/20.2 (69%)
| | Terminal Incidence | 13/16 (81%) | 5/7 (71%) | 2/4 (50%)
| | Time-to-First | 431 | 460 | 360
| | Poly-3 p-value | 0.041N* | 0.354N | 0.056N
| | Multiple Incidence^e^ | 21/50 (42%) | 11/26 (42%) | 4/26 (15%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. Adenocarcinoma incidence was significantly increased in the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control and there was a significant dose trend.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 52.

^c^ No mammary gland adenomas were diagnosed in interim or terminal sacrifice EE_2_ females, so no tabulation of adenoma or adenocarcinoma is included.

^d^ There were no animals with multiple mammary gland neoplasms in the interim sacrifice females.

^e^ Proportion of animals examined that had multiple neoplasms. These animals with multiple neoplasms are included in the incidence row and were not analyzed separately. The numbers of mammary neoplasms found in each female are tabulated in Supplemental Appendix XXXII, Subappendix VII.

Table 54 Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenocarcinoma^b^ | Terminal | Incidence | 3/50 (6%) | 11/50 (22%) | 5/48 (10%) | 7/49 (14%) | 9/50 (18%) | 5/46 (11%)
| | Poly-3 Incidence | 3/32.3 (9%) | 11/33.3 (33%) | 5/32.1 (16%) | 7/35.4 (20%) | 9/36.6 (25%) | 5/32.0 (16%)
| | Terminal Incidence | 1/11 (9%) | 2/12 (17%) | 2/13 (15%) | 0/13 (0%) | 5/17 (29%) | 0/13 (0%)
| | Time-to-First | 681 | 573 | 458 | 450 | 488 | 615
| | Poly-3 p-value | 0.453 | 0.016* | 0.348 | 0.189 | 0.083 | 0.346
| | Multiple Incidence^d^ | 1/50 (2%) | 1/50 (2%) | 1/48 (2%) | 2/49 (4%) | 1/50 (2%) | 2/46 (4%)
Adenoma or Adenocarcinoma^b^ | Terminal | Incidence | 4/50 (8%) | 12/50 (24%) | 5/48 (10%) | 9/49 (18%) | 9/50 (18%) | 6/46 (13%)
| | Poly-3 Incidence | 4/33.0 (12%) | 12/33.3 (36%) | 5/32.1 (16%) | 9/35.9 (25%) | 9/36.6 (25%) | 6/32.8 (18%)
| | Terminal Incidence | 1/11 (9%) | 3/12 (25%) | 2/13 (15%) | 1/13 (8%) | 5/17 (29%) | 0/13 (0%)
| | Time-to-First | 514 | 573 | 458 | 450 | 488 | 463
| | Poly-3 p-value | 0.483 | 0.018* | 0.482 | 0.140 | 0.149 | 0.360
| | Multiple Incidence^d^ | 1/50 (2%) | 1/50 (2%) | 1/48 (2%) | 2/49 (4%) | 1/50 (2%) | 2/46 (4%)
Fibroadenoma | Interim | Incidence^c^ | 4/20 (20%) | 1/22 (4%) | 1/20 (5%) | 1/22 (4%) | 1/20 (5%) | 2/22 (9%)
| | Terminal Incidence | 4/20 (20%) | 1/22 (4%) | 1/20 (5%) | 1/22 (4%) | 1/20 (5%) | 2/20 (10%)
| | Time-to-First | 363 (T) | 365 (T) | 365 (T) | 363 (T) | 364 (T) | 363 (T)
| | CAFE p-value | 0.184N | 0.144N | 0.171N | 0.144N | 0.171N | 0.286N
| Terminal | Incidence | 43/50 (86%) | 45/50 (90%) | 37/48 (77%) | 42/49 (86%) | 36/50 (72%) | 34/46 (74%)
| | Poly-3 Incidence | 43/47.7 (90%) | 45/47.5 (95%) | 37/42.2 (88%) | 42/46.2 (91%) | 36/45.5 (79%) | 34/40.6 (84%)
| | Terminal Incidence | 8/11(73%) | 11/12 (92%) | 11/13 (85%) | 11/13 (85%) | 12/17 (71%) | 12/13 (92%)
| | Time-to-First | 385 | 400 | 339 | 448 | 390 | 383
| | Poly-3 p-value | 0.021N* | 0.319 | 0.489N | 0.600 | 0.099N | 0.257N
| | Multiple Incidence^d^ | 29/50 (58%) | 32/50 (64%) | 28/48 (58%) | 31/49 (63%) | 29/50 (58%) | 28/46 (61%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. There was a significant increase in adenocarcinoma, and combined adenoma or adenocarcinoma, in the 2.5 BPA μg/kg bw/day dose group relative to vehicle controls.

^b^ No adenomas or adenocarcinomas were diagnosed in the mammary glands of interim sacrifice stop-dose females.

^c^ There were no interim sacrifice females with multiple fibroadenomas.

^d^ Proportion of animals examined that had multiple neoplasms. These animals with multiple neoplasms are included in the incidence row and were not analyzed separately. The numbers of mammary neoplasms found in each female are tabulated in Supplemental Appendix XXXII, Subappendix VII.

Adenocarcinomas and/or adenomas were observed in the continuous-dose BPA-treated animals (Table 52). In interim sacrifice animals, there were no treatment-related increases in neoplasm incidence, but both the 2.5 and 25 μg BPA/kg bw/day continuous-dose groups had single adenocarcinomas in 22 animals examined (4% incidence). In the terminal sacrifice continuous-dose vehicle control animals, 8% had adenocarcinoma and 12% had adenoma or adenocarcinoma. In the continuous BPA dose groups, the incidence of adenocarcinoma varied between 6 and 18%, and the incidence of adenocarcinoma or adenoma varied between 9 and 20%. None of these incidences were significant compared to the vehicle control group. The historical control incidence of combined adenoma/adenocarcinomas was 32/210 (15.2%, range 12–17%).

In interim sacrifice animals, 2 of 26 animals (8% incidence) from the 0.05 μg EE_2_/kg bw/day dose group had adenocarcinomas (Table 53). For the terminal sacrifice EE_2_ treatment groups, there was a significant dose trend (p < 0.001) and a significant increase in adenocarcinomas in the 0.5 μg EE_2_/kg bw/day dose group (38% versus 8%, p < 0.001).

Adenocarcinomas and/or adenomas were also observed in the terminal stop-dose females (Table 54). In the terminal sacrifice stop-dose females, vehicle controls had 6% animals with adenocarcinomas and 8% with adenomas or adenocarcinomas. The 2.5 μg BPA/kg bw/day stop-dose group had a significantly higher incidence of adenocarcinomas (22% versus 6%, p = 0.016) or adenomas and adenocarcinomas combined (24% versus 8%, p = 0.018).

#### Mammary gland, non-neoplastic lesions

Non-neoplastic lesions in the mammary glands of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA treatments are shown in Table 55, Table 56, and Table 57, respectively.

Table 55 Non-Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Atypical focus | Interim | Incidence | 0/23 (0%) | 3/22^^^ (14%) | 2/22 (9%) | 2/24 (8%) | 0/20 (0%) | 0/24 (0%)
| | Severity Profile | – | 1\|2\|0\|0 (1.7) | 0\|2\|0\|0 (2.0) | 2\|0\|0\|0 (1.0) | – | –
| Terminal | Incidence | 2/50 (4%) | 7/48^^^ (15%) | 1/46 (2%) | 5/49 (10%) | 3/50 (6%) | 3/46 (6%)
| | Severity Profile | 0\|2\|0\|0 (2.0) | 3\|2\|2\|0 (1.9) | 0\|1\|0\|0 (2.0) | 0\|5\|0\|0 (2.0) | 1\|2\|0\|0 (1.7) | 1\|2\|0\|0 (1.7)
| | Poly-3 Incidence | 2/34.4 (6%) | 7/33.6 (21%) | 1/28.2 (4%) | 5/33.3 (15%) | 3/29.7 (10%) | 3/31.7 (10%)
Dilatation, duct | Interim | Incidence | 2/23 (9%) | 2/22 (9%) | 7/22^^^^ (32%) | 1/24 (4%) | 2/20 (10%) | 2/24 (8%)
| | Severity Profile | 1\|1\|0\|0 (1.5) | 0\|0\|0\|2 (4.0) | 2\|4\|1\|0 1.9) | 0\|0\|1\|0 (3.0) | 1\|0\|1\|0 (2.0) | 1\|0\|1\|0 (2.0)
| Terminal | Incidence | 15/50 (30%) | 16/48 (33%) | 7/46^^ N^ (15%) | 9/49 (18%) | 9/50 (18%) | 14/46 (30%)
| | Severity Profile | 0\|10\|5\|0 (2.3) | 0\|12\|2\|2 (2.4) | 0\|6\|1\|0 (2.1) | 0\|6\|3\|0 (2.3) | 0\|4\|5\|0 (2.6) | 2\|9\|3\|0 (2.1)
| | Poly-3 Incidence | 15/38.1 (39%) | 16/39.4 (41%) | 7/31.9 (22%) | 9/35.7 (25%) | 9/33.1 (27%) | 14/36.4 (38%)
Hyperplasia, lobular | Interim | Incidence | 10/23 (44%) | 14/22 (64%) | 13/22 (59%) | 15/24 (62%) | 13/20 (65%) | 12/24 (50%)
| | Severity Profile | 5\|5\|0\|0 (1.5) | 7\|7\|0\|0 (1.5) | 7\|6\|0\|0 (1.5) | 11\|3\|1\|0 (1.3) | 10\|2\|0\|1 (1.4) | 9\|1\|1\|1 (1.5)
| Terminal | Incidence | 43/50 (86%) | 41/48 (85%) | 30/46^^^ N^ (65%) | 38/49 (78%) | 40/50^^ N^ (80%) | 37/46 (80%)
| | Severity Profile | 1\|8\|13\|21 (3.3) | 1\|7\|11\|22 (3.3) | 1\|7\|10\|12 (3.1) | 0\|7\|17\|14 (3.2) | 1\|14\|11\|14 (3.0) | 4\|9\|5\|19 (3.1)
| | Poly-3 Incidence | 43/45.4^* N^ (95%) | 41/42.5 (96%) | 30/36.7^* N^ (82%) | 38/43.7 (87%) | 40/43.2 (93%) | 37/43.4 (85%)
Dilatation, alveolus^b^ | Terminal | Incidence | 9/50 (18%) | 14/48 (29%) | 5/46 (11%) | 7/49 (14%) | 7/50 (14%) | 11/46 (24%)
| | Severity Profile | 1\|7\|1\|0 (2.0) | 1\|11\|2\|0 (2.1) | 0\|5\|0\|0 (2.0) | 0\|7\|0\|0 (2.0) | 0\|6\|1\|0 (2.1) | 0\|9\|2\|0 (2.2)
| | Poly-3 Incidence | 9/36.0 (25%) | 14/38.0 (37%) | 5/30.9 (16%) | 7/35.2 (20%) | 7/32.3 (22%) | 11/34.6 (32%)

^a^ BPA doses are μg/kg bw/day. Statistical analyses were conducted for any lesion that was diagnosed in two animals in any dose group in the interim sacrifice groups or in the EE_2_ terminal sacrifice groups or four animals in the control and BPA groups in the terminal sacrifice. A complete tabulation of all non-neoplastic lesions is found in Supplemental Appendix XXXII and complete results of the statistical analyses are found in Supplemental Appendices XXXIII (interim sacrifice) and XXXIV (terminal sacrifice). Details of the statistical methods are found in Materials and Methods and in Supplemental Appendices XXXIII and XXXIV. Selected non-neoplastic lesions are tabulated in this report. Data are presented as follows: Incidence, lesions observed/number of animals examined microscopically, with percent animals affected in parentheses; Severity Profile, number of animals diagnosed with minimal/ mild/ moderate/ marked lesions, with the average severity in affected animals given in parentheses, based upon severity scores of 1, minimal; 2, mild; 3, moderate; and 4, marked.; Poly-3 Incidence, Poly-3 adjusted lesion incidence after adjustment for intercurrent mortality in the terminal sacrifice animals. Lesions in interim sacrifice animals were analyzed by the CAFE test (Cochran-Armitage trend test and Fisher’s exact test to compare the incidence in each dose group to the vehicle control) and by the Jonckheere-Terpstra (JT) trend test/Shirley-Williams (SW) pairwise comparison test to incorporate severity scores. Because the JT/SW test enforces an assumption of a monotonic response, a relative treatment effect (RTE) analysis that also incorporates severity scores, but does not enforce monotonicity, was also conducted. Significant JT/SW results that violated the monotonicity requirement are not shown in the tables, but are reported in Supplemental Appendices XXXIII and XXXIV. Lesions in terminal sacrifice animals were analyzed by the Poly-3 test to adjust for intercurrent mortality, as well as by the JT/SW and RTE tests. All pairwise tests were one-sided and not corrected for multiple comparisons. Significant trends are shown in the vehicle column, while significant pairwise comparisons to the vehicle control are shown in BPA or EE_2_ dose group columns. The CAFE or Poly-3 tests for interim and terminal sacrifice animals, respectively, were considered as the primary statistical tests and positive significant results for those tests are shown with asterisks. Pound and caret signs indicate results from the JT/SW and RTE tests, respectively. *, #, ^, p < 0.05; **, ##, ^^, p < 0.01; ***, ###, ^^^, p < 0.001. “N” superscript next to significance markers indicates a result that is a negative trend or negative relative to control.

^b^ No alveolar dilatation was diagnosed in interim sacrifice females.

Table 56 Non-Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Atypical focus^c^ | Terminal | Incidence | 2/50 (4%) | 2/26 (8%) | 3/26 (12%)
| | Severity Profile | 0\|2\|0\|0 (2.0) | 1\|1\|0\|0 (1.5) | 2\|1\|0\|0 (1.3)
| | Poly-3 Incidence | 2/34.4 (6%) | 2/16.1 (12%) | 3/16.2 (19%)
Dilatation, duct | Interim | Incidence | 2/23^***, ###, ^^^^ (9%) | 3/26 (12%) | 22/26^***, ###, ^^^^ (85%)
| | Severity Profile | 1\|1\|0\|0 (1.5) | 1\|2\|0\|0 (1.7) | 6\|12\|2\|2 (2.0)
| Terminal | Incidence | 15/50^###, ^^^^ (30%) | 6/26 (23%) | 21/26^###, ^^^^ (81%)
| | Severity Profile | 0\|10\|5\|0 (2.3) | 0\|3\|3\|0 (2.5) | 0\|10\|7\|4 (2.7)
| | Poly-3 Incidence | 15/38.1*** (39%) | 6/19.0 (32%) | 21/24.2*** (87%)
Hyperplasia, lobular | Interim | Incidence | 10/23^***, ##, ^^^ (44%) | 13/26 (50%) | 23/26^***, ##, ^^^ (88%)
| | Severity Profile | 5\|5\|0\|0 (1.5) | 6\|6\|1\|0 (1.6) | 11\|11\|1\|0 (1.6)
| Terminal | Incidence | 43/50 (86%) | 24/26 (92%) | 23/26 (88%)
| | Severity Profile | 1\|8\|13\|21 (3.3) | 1\|8\|4\|11 (3.0) | 1\|10\|4\|8 (2.8)
| | Poly-3 Incidence | 43/45.4 (95%) | 24/24.5 (98%) | 23/25.1 (92%)
Dilatation, alveolus^d^ | Terminal | Incidence | 9/50^###, ^^^^ (18%) | 5/26 (19%) | 22/26^###, ^^^^ (85%)
| | Severity Profile | 1\|7\|1\|0 (2.0) | 0\|5\|0\|0 (2.0) | 0\|18\|4\|0 (2.2)
| | Poly-3 Incidence | 9/36.0*** (25%) | 5/18.8 (27%) | 22/24.1*** (91%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 or description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 55.

^c^ There were no atypical foci diagnosed in the interim vehicle, 0.05, or 0.5 μg EE_2_/kg bw/day groups (0/23, 0/26, and 0/26, respectively), so there is no tabulation of data for the interim sacrifice animals for this lesion.

^d^ No alveolar dilatation was diagnosed in interim sacrifice females.

Table 57 Non-Neoplastic Lesions in the Mammary Gland of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Atypical focus^b^ | Terminal | Incidence | 6/50 (12%) | 2/50 (4%) | 6/48 (12%) | 8/49 (16%) | 7/50 (14%) | 5/46 (11%)
| | Severity Profile | 1\|4\|1\|0 (2.0) | 0\|1\|1\|0 (2.5) | 1\|5\|0\|0 (1.8) | 3\|4\|1\|0 (1.8) | 0\|5\|0\|2 (2.6) | 2\|3\|0\|0 (1.6)
| | Poly-3 Incidence | 6/33.0 (18%) | 2/32.0 (6%) | 6/32.4 (18%) | 8/36.2 (22%) | 7/35.8 (20%) | 5/32.6 (15%)
Dilatation, duct | Interim | Incidence | 4/20^*, #, ^ N^ (20%) | 2/22 (9%) | 1/20 (5%) | 1/22^^ N^ (4%) | 1/20 (5%) | 1/22^#, ^ N^ (4%)
| | Severity Profile | 2\|1\|1\|0 (1.8) | 1\|1\|0\|0 (1.5) | 0\|1\|0\|0 (2.0) | 1\|0\|0\|0 (1.0) | 0\|1\|0\|0 (2.0) | 1\|0\|0\|0 (1.0)
| Terminal | Incidence | 16/50 (32%) | 5/50^##, ^^ N^ (10%) | 9/48^#, ^ N^ (19%) | 9/49^#, ^ N^ (18%) | 7/50^##, ^^ N^ (14%) | 11/46^# N^ (24%)
| | Severity Profile | 0\|9\|4\|3 (2.6) | 0\|5\|0\|0 (2.0) | 2\|4\|2\|1 (2.2) | 0\|6\|3\|0 (2.3) | 0\|6\|1\|0 (2.1) | 0\|7\|4\|0 (2.4)
| | Poly-3 Incidence | 16/37.0 (43%) | 5/34.5^** N^ (14%) | 9/33.7 (27%) | 9/35.3 (26%) | 7/36.4^* N^ (19%) | 11/36.2 (30%)
Hyperplasia, lobular | Interim | Incidence | 15/20 (75%) | 12/22 (54%) | 8/20^*, ^ N^ (40%) | 12/22 (54%) | 7/20^*, ^ N^ (35%) | 12/22 (54%)
| | Severity Profile | 10\|4\|1\|0 (1.4) | 8\|3\|1\|0 (1.4) | 5\|1\|2\|0 (1.6) | 8\|3\|1\|0 (1.4) | 4\|3\|0\|0 (1.4) | 6\|4\|2\|0 (1.7)
| Terminal | Incidence | 41/50 (82%) | 40/50 (80%) | 39/48 (81%) | 39/49 (80%) | 36/50 (72%) | 38/46 (83%)
| | Severity Profile | 1\|8\|15\|17 (3.2) | 0\|8\|12\|20 (3.3) | 3\|14\|11\|11 (2.8) | 2\|9\|13\|15 (3.1) | 3\|5\|7\|21 (3.3) | 2\|10\|9\|17 (3.1)
| | Poly-3 Incidence | 41/45.5 (90%) | 40/46.1 (87%) | 39/42.7 (91%) | 39/45.0 (87%) | 36/45.4 (79%) | 38/41.6 (91%)
Dilatation, alveolus^c^ | Terminal | Incidence | 8/50 (16%) | 4/50 (8%) | 4/48 (8%) | 8/49 (16%) | 3/50^^ N^ (6%) | 7/46 (15%)
Dilatation, alveolus^c^ | | Severity Profile | 0\|4\|4\|0 (2.5) | 0\|4\|0\|0 (2.0) | 0\|2\|2\|0 (2.5) | 0\|6\|2\|0 (2.3) | 1\|2\|0\|0 (1.7) | 1\|6\|0\|0 (1.9)
Dilatation, alveolus^c^ | | Poly-3 Incidence | 8/34.8 (23%) | 4/33.7 (12%) | 4/30.5 (13%) | 8/34.9 (23%) | 3/35.7 (8%) | 7/34.9 (20%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ There was a 5% incidence (1/20) of atypical focus in the mammary gland of female stop-dose vehicle control interim sacrifice animals and all BPA dose interim sacrifice dose groups had a 0% incidence (0/22, 0/20, 0/22, 0/20, 0/22 for 2.5, 25, 250, 2,500, and 25,000 μg BPA/kg bw/day, respectively).

^c^ No alveolar dilatation was diagnosed in interim sacrifice females.

In the continuous-dose BPA groups, in both the interim and terminal sacrifice females, the incidences of atypical foci were higher in some treatment groups than in vehicle controls, and this was significant (by the RTE test only) for the 2.5 μg BPA/kg bw/day dose group in both the interim (14% versus 0%) and terminal (15% versus 4%) females (Table 55). In the interim sacrifice animals, there was a significantly increased incidence (RTE test only) of ductal dilatation (32% versus 9%) in the 25 μg BPA/kg bw/day dose group, but this was not the case in the terminal sacrifice females, where the incidence in the dose group was decreased relative to the vehicle controls (15% versus 30%).

In the continuous-dose EE_2_ treatments, there were several significant trends and high dose treatment effects observed by all statistical tests applied (Table 56). In both interim and terminal animals, there was a significant trend and a significant pairwise comparison of the 0.5 μg EE_2_/kg bw/day dose group and vehicle control for ductal dilatation (85% versus 9%, interim; 81% versus 30%, terminal). In interim sacrifice animals, there was a significant trend and a significant pairwise comparison of the 0.5 μg EE_2_/kg bw/day dose group and vehicle control for lobular hyperplasia (88% versus 44%). In terminal sacrifice animals, there was a significant trend and a significant pairwise comparison of the 0.5 μg EE_2_/kg bw/day dose group and vehicle control for alveolar dilatation (85% versus 18%).

In the stop-dose BPA treatments, there were no statistically significant increased mammary gland non-neoplastic lesion incidences in BPA dose groups relative to vehicle controls, although multiple cases of decreased incidences in BPA groups relative to vehicle were observed (Table 57).

#### Uterus, neoplastic lesions

Stromal polyps were found in interim and terminal females and their incidences are shown for continuous BPA and EE2 and stop-dose BPA in Table 58, Table 59, and Table 60, respectively.

Table 58 Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Stromal polyps | Interim | Incidence | 1/23 (4%) | 0/22 (0%) | 1/21 (5%) | 0/24 (0%) | 3/20 (15%) | 3/24 (12%)
| | Terminal Incidence | 1/21 (5%) | 0/22 (0%) | 1/21 (5%) | 0/22 (0%) | 3/20 (15%) | 3/24 (12%)
| | Time-to-First | 362 (T) | – | 360 (T) | – | 362 (T) | 362 (T)
| | CAFE p-value | 0.037* | 0.511^N^ | 0.733 | 0.489^N^ | 0.252 | 0.321
| Terminal | Incidence | 5/50 (10%) | 3/48 (6%) | 7/45 (16%) | 2/49 (4%) | 4/48 (8%) | 3/46 (6%)
| | Poly-3 Incidence | 5/36.4 (14%) | 3/34.6 (9%) | 7/29.5 (24%) | 2/33.5 (6%) | 4/29.2 (14%) | 3/32.2 (9%)
| | Terminal Incidence | 1/16 (6%) | 0/19 (0%) | 4/14 (29%) | 0/13 (0%) | 0/10 (0%) | 0/8 (0%)
| | Time-to-First | 506 | 321 | 441 | 542 | 673 | 569
| | Poly-3 p-value | 0.333^N^ | 0.383^N^ | 0.231 | 0.247^N^ | 0.638^N^ | 0.424^N^

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. There were no statistically significant effects in the terminal sacrifice animals. There was a significant trend across BPA dose levels in the interim sacrifice animals.

Table 59 Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Stromal polyps | Terminal | Incidence | 5/50 (10%) | 3/26 (12%) | 1/26 (4%)
| | Poly-3 Incidence | 5/36.4 (14%) | 3/17.4 (17%) | 1/15.7 (6%)
| | Terminal Incidence | 1/16 (6%) | 0/7 (0%) | 0/4 (0%)
| | Time-to-First | 506 | 485 | 527
| | Poly-3 p-value | 0.383^N^ | 0.529 | 0.389^N^

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. There were no statistically significant effects in the terminal sacrifice animals. Interim sacrifice animals are not tabulated as no group had two or more lesions.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 58.

Table 60 Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Stromal polyps | Terminal | Incidence | 7/49 (14%) | 4/49 (8%) | 5/48 (10%) | 6/49 (12%) | 4/49 (8%) | 1/46 (2%)
| | Poly-3 Incidence | 7/33.0 (21%) | 4/32.3 (12%) | 5/32.5 (15%) | 6/35.9 (17%) | 4/35.8 (11%) | 1/31.0 (3%)
| | Terminal Incidence | 2/11 (18.2%) | 1/12 (8%) | 1/13 (8%) | 1/13 (8%) | 1/17 (6%) | 0/13 (0%)
| | Time-to-First | 467 | 446 | 461 | 497 | 539 | 706
| | Poly-3 p-value | 0.041^* N^ | 0.263^N^ | 0.384^N^ | 0.433^N^ | 0.207^N^ | 0.032^* N^

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. Interim sacrifice animals are not tabulated as no group had two or more lesions.

There was a significant dose trend in the interim sacrifice females treated continuously with BPA (Table 58). The incidence for the vehicle control group was 1/23 (4%) compared to 3/20 (15%) for the 2,500 μg BPA/kg bw/day group and 3/24 (12%) for the 25,000 μg BPA/kg bw/day group, but these differences were not statistically significant. This trend toward increased incidence at the higher BPA dose groups was not observed in the terminal sacrifice animals, where the control unadjusted incidence was 5/50 (10%) and incidences in BPA treatment groups varied from 4–16%, with 4/48 (8%) and 3/46 (6%) in the 2,500 and 25,000 μg BPA/kg bw/day groups, respectively.

There were no significant effects of continuous EE_2_ treatment (Table 59).

In the stop-dose terminal females, the vehicle control incidence of stromal polyps was 14%, and a negative trend was observed along with a reduced incidence in the 25,000 μg BPA/kg bw/day dose group relative to the vehicle control (14% versus 2%, Table 60). There were no other statistically significant neoplastic effects observed in interim or terminal sacrifice BPA continuous or stop-dose treatments in the uterus.

#### Uterus, non-neoplastic lesions

Non-neoplastic lesions in the uteri of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA treatments are shown in Table 61, Table 62, and Table 63, respectively.

Table 61 Non-Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Apoptosis | Interim | Incidence | 2/23^**, ##, ^^^ (9%) | 1/22 (4%) | 4/21 (19%) | 5/24 (21%) | 5/20 (25%) | 9/24^*, #, ^^^ (38%)
| | Severity Profile | 0/0/0/2 (4.0) | 0/0/0/1 (4.0) | 0/1/1/2 (3.2) | 0/1/0/4 (3.6) | 0/0/3/2 (3.4) | 0/1/5/3 (3.2)
Hyperplasia, cystic, endometrium | Interim | Incidence | 5/23 (22%) | 1/22 (4%) | 4/21 (19%) | 3/24 (12%) | 7/20 (35%) | 4/24 (17%)
| | Severity Profile | 1\|2\|1\|1 (2.4) | 1\|0\|0\|0 (1.0) | 1\|2\|1\|0 (2.0) | 1\|1\|1\|0 (2.0) | 0\|6\|1\|0 (2.1) | 0\|3\|0\|1 (2.5)
| Terminal | Incidence | 30/50 (60%) | 20/48^^ N^ (42%) | 26/45 (58%) | 23/49 (47%) | 22/48 (46%) | 26/46 (56%)
| | Severity Profile | 4\|18\|5\|3 (2.2) | 2\|13\|5\|0 (2.2) | 0\|16\|7\|3 (2.5) | 4\|12\|6\|1 (2.2) | 4\|8\|8\|2 (2.4) | 1\|14\|10\|1 (2.4)
| | Poly-3 incidence | 30/41.9 (72%) | 20/40.1^* N^ (50%) | 26/36.9 (70%) | 23/40.6 (57%) | 22/35.8 (61%) | 26/39.2 (66%)
Hyperplasia, endometrium | Interim | Incidence | 2/23 (9%) | 7/22^^^ (32%) | 5/21 (24%) | 7/24^^^ (29%) | 5/20 (25%) | 2/24 (8%)
| | Severity Profile | 0\|2\|0\|0 (2.0) | 3\|3\|1\|0 (1.7) | 0\|4\|1\|0 (2.2) | 2\|4\|1\|0 (1.9) | 1\|2\|2\|0 (2.2) | 0\|2\|0\|0 (2.0)
| Terminal | Incidence | 10/50 (20%) | 15/48 (31%) | 12/45 (27%) | 15/49 (31%) | 15/48 (31%) | 12/46 (26%)
| | Severity Profile | 2\|8\|0\|0 (1.8) | 5\|8\|2\|0 (1.8) | 2\|8\|2\|0 (2.0) | 6\|7\|0\|2 (1.9) | 10\|5\|0\|0 (1.3) | 2\|7\|1\|2 (2.2)
| | Poly-3 incidence | 10/39.1 (26%) | 15/36.4 (41%) | 12/31.9 (38%) | 15/37.1 (40%) | 15/35.9 (42%) | 12/36.2 (33%)
Metaplasia, squamous | Interim | Incidence | 1/23^*, #, ^^ (4%) | 1/22 (4%) | 4/21 (19%) | 3/24 (12%) | 3/20 (15%) | 5/24^b^ (21%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 0\|1\|0\|0 (2.0) | 3\|1\|0\|0 (1.2) | 3\|0\|0\|0 (1.0) | 2\|0\|1\|0 (1.7) | 5\|0\|0\|0 (1.0)
| Terminal | Incidence | 2/50 (4%) | 4/48 (8%) | 4/45 (9%) | 1/49 (2%) | 4/48 (8%) | 6/46 (13%)
| | Severity Profile | 1\|1\|0\|0 (1.5) | 2\|2\|0\|0 (1.5) | 1\|2\|0\|1 (2.2) | 1\|0\|0\|0 (1.0) | 1\|3\|0\|0 (1.8) | 4\|1\|1\|0 (1.5)
| | Poly-3 incidence | 2/35.7 (6%) | 4/35 (11%) | 4/29.5 (14%) | 1/32.8 (3%) | 4/31.1 (13%) | 6/33.9 (18%)
Dilatation, lumen | Interim | Incidence | 0/23 (0%) | 1/22 (4%) | 2/21 (10%) | 2/24 (8%) | 1/20 (5%) | 2/24 (8%)
| | Severity Profile | - | 0\|0\|1\|0 (3.0) | 0\|0\|0\|2 (4.0) | 0\|0\|0\|2 (4.0) | 0\|0\|0\|1 (4.0) | 0\|0\|0\|2 (4.0)
| Terminal | Incidence | 2/50^#, ^^ (4%) | 2/48 (4%) | 3/45 (7%) | 4/49 (8%) | 5/48 (10%) | 6/46 (13%)
| | Severity Profile | 0\|0\|0\|2 (4.0) | 0\|0\|0\|2 (4.0) | 0\|0\|0\|3 (4.0) | 0\|0\|1\|3 (3.8) | 0\|0\|0\|5 4.0) | 0\|0\|1\|5 (3.8)
| | Poly-3 incidence | 2/35.6* (6%) | 2/33.5 (6%) | 3/28.5 (10%) | 4/34.5 (12%) | 5/30.1 (17%) | 6/33.0^c^ (18%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant (p = 0.048) difference for the CAFE test for the pairwise comparison of the 25,000 μg BPA/kg bw/day group to the vehicle control (squamous metaplasia, 5/20 (25%) versus 0/15 (0%)).

^c^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.035) for the pairwise comparison of the 25,000 μg BPA/kg bw/day group to the vehicle control group (lumen dilatation, Poly-3 incidences, 5/26.8 (19%) versus 0/24 (0%)).

Table 62 Non-Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 0.05 EE_2_ | 0.5 EE_2_
Apoptosis | Interim | Incidence | 2/23^***, ###, ^^^^ (9%) | 6/25 (24%) | 18/26^***, ###, ^^^^ (69%)
| | Severity Profile | 0\|0\|0\|2 (4.0) | 0\|1\|2\|3 (3.3) | 0\|2\|6\|10 (3.4)
Hyperplasia, cystic, endometrium | Interim | Incidence | 5/23^*, ##, ^^ (22%) | 6/25 (24%) | 14/26^*, #, ^^ (54%)
| | Severity Profile | 1\|2\|1\|1 (2.4) | 3\|3\|0\|0 (1.5) | 4\|6\|2\|2 (2.1)
| Terminal | Incidence | 30/50 (60%) | 14/26 (54%) | 14/26 (54%)
| | Severity Profile | 4\|18\|5\|3 (2.2) | 1\|7\|4\|2 (2.5) | 1\|8\|2\|3 (2.5)
| | Poly-3 Incidence | 30/41.9 (72%) | 14/21.8 (64%) | 14/20.2 (69%)
Hyperplasia, endometrium | Interim | Incidence | 2/23 (9%) | 4/25 (16%) | 0/26 (0%)
| | Severity Profile | 0\|2\|0\|0 (2.0) | 0\|4\|0\|0 (2.0) | –
| Terminal | Incidence | 10/50 (20%) | 10/26^^^ (38%) | 2/26 (8%)
| | Severity Profile | 2\|8\|0\|0 (1.8) | 3\|6\|0\|1 (1.9) | 1\|1\|0\|0 (1.5)
| | Poly-3 Incidence | 10/39.1 (26%) | 10/19.4* (52%) | 2/16.2 (12%)
Metaplasia, squamous | Interim | Incidence | 1/23^***, ###, ^^^^ (4%) | 2/25 (8%) | 14/26^***, ###, ^^^^ (54%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 1\|0\|1\|0 (2.0) | 8\|4\|2\|0 (1.6)
| Terminal | Incidence | 2/50^#^ (4%) | 2/26 (8%) | 4/26 (15%)
| | Severity Profile | 1\|1\|0\|0 (1.5) | 0\|2\|0\|0 (2.0) | 3\|0\|1\|0 (1.5)
| | Poly-3 Incidence | 2/35.7* (6%) | 2/16.1 (12%) | 4/16.9 (24%)
Dilatation, lumen | Interim | Incidence | 0/23 (0%) | 1/25 (4%) | 0/26 (0%)
| | Severity Profile | – | 0/0/0/1 (4.0) | –
| Terminal | Incidence | 2/50 (4%) | 2/26 (8%) | 3/26 (12%)
| | Severity Profile | 0\|0\|0\|2 (4.0) | 0\|0\|0\|2 (4.0) | 0\|0\|0\|3 (4.0)
| | Poly-3 Incidence^b^ | 2/35.6 (6%) | 2/16.9 (12%) | 3/16.0^c^ (19%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 61.

^c^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant EE_2_ dose trend (p = 0.008) and a significant pairwise comparison (p = 0.013) for the 0.5 μg EE_2_/kg bw/day dose group versus the vehicle control group (lumen dilatation, Poly-3 incidences 3/10.5 (29%) versus 0/24 (0%)).

Table 63 Non-Neoplastic Lesions in the Uterus of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Apoptosis | Interim | Incidence | 2/20 (10%) | 3/22 (14%) | 2/20 (10%) | 2/22 (9%) | 1/20 (5%) | 6/22 (27%)
| | Severity Profile | 0\|0\|0\|2 (4.0) | 0\|1\|0\|2 (3.3) | 0\|0\|1\|1 (3.5) | 0\|0\|2\|0 (3.0) | 0\|0\|0\|1 (4.0) | 0\|1\|0\|5 (3.7)
Hyperplasia, cystic, endometrium | Interim | Incidence | 2/20 (10%) | 4/22 (18%) | 2/20 (10%) | 2/22 (9%) | 1/20 (5%) | 7/22^#, ^^ (32%)
| | Severity Profile | 0\|1\|0\|1 (3.0) | 0\|2\|2\|0 (2.5) | 0\|2\|0\|0 (2.0) | 0\|2\|0\|0 (2.0) | 0\|0\|0\|1 (4.0) | 2\|4\|0\|1 (2.0)
| Terminal | Incidence | 18/49^#, ^^ (37%) | 23/49 (47%) | 22/48 (46%) | 25/49 (51%) | 28/49^#, ^^ (57%) | 24/46^#^ (52%)
| | Severity Profile | 3\|8\|5\|2 (2.3) | 1\|18\|4\|0 (2.1) | 1\|15\|5\|1 (2.3) | 3\|15\|6\|1 (2.2) | 0\|18\|6\|4 (2.5) | 4\|11\|6\|3 (2.3)
| | Poly-3 Incidence | 18/38.3 (47%) | 23/38.1 (60%) | 22/37.1 (59%) | 25/41.6 (60%) | 28/42.5^b^ (66%) | 24/38.6 (62%)
Hyperplasia, endometrium | Interim | Incidence | 6/20 (30%) | 9/22 (41%) | 5/20 (25%) | 7/22 (32%) | 6/20 (30%) | 9/22 (41%)
| | Severity Profile | 1\|4\|1\|0 (2.0) | 1\|6\|2\|0 (2.1) | 2\|2\|1\|0 (1.8) | 2\|4\|1\|0 (1.9) | 0\|6\|0\|0 (2.0) | 0\|7\|2\|0 (2.2)
| Terminal | Incidence | 18/49 (37%) | 14/49 (29%) | 17/48 (35%) | 14/49 (29%) | 12/49 (24%) | 10/46 (22%)
| | Severity Profile | 6\|12\|0\|0 (1.7) | 8\|6\|0\|0 (1.4) | 7\|9\|0\|1 (1.7) | 6\|7\|1\|0 (1.6) | 2\|10\|0\|0 (1.8) | 1\|8\|1\|0 (2.0)
| | Poly-3 Incidence | 18/38.8^* N^ (46%) | 14/37.4 (38%) | 17/37.0 (46%) | 14/39.2 (36%) | 12/38.5 (31%) | 10/33.6 (30%)
Metaplasia, squamous | Interim | Incidence | 0/20 (0%) | 2/22 (9%) | 1/20 (5%) | 1/22 (4%) | 0/20 (0%) | 4/22^##, ^^^ (18%)
| | Severity Profile | – | 2\|0\|0\|0 (1.0) | 0\|1\|0\|0 (2.0) | 1\|0\|0\|0 (1.0) | – | 1\|3\|0\|0 (1.8)
| Terminal | Incidence | 5/49 (10%) | 1/49^^ N^ (2%) | 2/48 (4%) | 2/49 (4%) | 4/49 (8%) | 3/46 (6%)
| | Severity Profile | 3\|2\|0\|0 (1.4) | 1\|0\|0\|0 (1.0) | 1\|1\|0\|0 (1.5) | 0\|2\|0\|0 (2.0) | 3\|1\|0\|0 (1.2) | 3\|0\|0\|0 (1.0)
| | Poly-3 Incidence | 5/33.1 (15%) | 1/31.7 (3%) | 2/30.8 (6%) | 2/34.8 (6%) | 4/36.2 (11%) | 3/32.6 (9%)
Dilatation, lumen | Interim | Incidence | 1/20 (5%) | 0/22 (0%) | 1/20 (5%) | 4/22^^^ (18%) | 1/20 (5%) | 0/22 (0%)
| | Severity Profile | 0\|0\|0\|1 (4.0) | – | 0\|0\|0\|1 (4.0) | 0\|0\|1\|3 (3.8) | 0\|0\|1\|0 (3.0) | –
| Terminal | Incidence | 3/49^#, ^ N^ (6%) | 6/49 (12%) | 2/48 (4%) | 4/49 (8%) | 2/49 (4%) | 0/46 (0%)
| | Severity Profile | 0\|0\|1\|2 (3.7) | 0\|0\|0\|6 (4.0) | 0\|0\|0\|2 (4.0) | 0\|0\|0\|4 (4.0) | 0\|0\|1\|1 (3.5) | –
| | Poly-3 Incidence | 3/32.5^* N^ (9%) | 6/33.0 (18%) | 2/31.3 (6%) | 4/33.8 (12%) | 2/35.2 (6%) | 0/30.9 (0%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.038) for the comparison of 2,500 μg BPA/kg bw/day group to vehicle control (endometrial cystic hyperplasia, Poly-3 incidences, 23/43.3 (53%) versus 12/28.2 (43%)).

In interim sacrifice, continuous-dose BPA females, there was a significant dose trend for apoptosis in the luminal epithelial cells of the endometrium for all statistical analyses applied, with the incidence in the 25,000 μg BPA/kg bw/day dose group significantly higher than the vehicle controls (38% versus 9%, Table 61). Endometrial hyperplasia was significantly increased in the interim continuous-dose 2.5 and 250 μg BPA/kg bw/day dose groups (RTE test only, 32% versus 9% and 29% versus 9%, respectively). There were also significant dose trends for squamous metaplasia and dilatation of the lumen in the interim and terminal sacrifice continuous-dose BPA females, respectively, with no significant pairwise comparisons for any dose group to vehicle controls (Table 61).

In the continuous EE_2_-treated interim sacrifice females, there were increased trends and significant pairwise comparisons of the 0.5 μg EE_2_/kg bw/day dose group to the vehicle control detected in all statistical tests applied for uterine apoptosis (69% versus 9%), cystic endometrial hyperplasia (54% versus 22%), and squamous metaplasia (54% versus 4%) (Table 62). In the terminal animals, a trend was detected for squamous metaplasia in both the Poly-3 and JT/SW tests (incidences of 4%, 8%, and 15% in the vehicle control, low and high EE_2_ dose groups, respectively).

In the stop-dose females, the incidence of apoptosis in the 25,000 μg BPA/kg bw/day dose group was higher than that in vehicle controls (27% versus 10%), but this difference was not statistically significant (Table 63). In stop-dose BPA-treated females, there was a significant increase in cystic endometrial hyperplasia relative to vehicle controls in the 25,000 μg BPA/kg bw/day dose group (32% versus 10%, JT/SW and RTE tests) at interim sacrifice, while in the terminal sacrifice females there was a significant dose trend and the incidences in the 2,500 and 25,000 μg BPA/kg bw/day dose groups were significantly higher than that in the vehicle control (57% and 52%, respectively, versus 37%). Additional statistically significant differences in BPA stop-dose interim sacrifice animals versus controls were an increased incidence of squamous metaplasia in the 25,000 μg BPA/kg bw/day dose group (JT/SW and RTE tests, 18% versus 0%) and an increased incidence of dilatation of the lumen in the 250 μg BPA/kg bw/day dose group (RTE test only, 18% versus 5%) (Table 63).

#### Ovary, non-neoplastic lesions

Non-neoplastic lesions in the interim and terminal sacrifice animals for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 64, Table 65, and Table 66, respectively.

Table 64 Non-Neoplastic Lesions in the Ovary of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Atrophy | Interim | Incidence | 10/23 (44%) | 7/22 (32%) | 9/22 (41%) | 14/24 (58%) | 11/20 (55%) | 11/24 (46%)
| | Severity Profile | 1\|4\|0\|5 (2.9) | 0\|3\|0\|4 (3.1) | 0\|2\|0\|7 (3.6) | 6\|4\|0\|4 (2.1) | 2\|1\|0\|8 (3.3) | 0\|2\|0\|9 (3.6)
| Terminal | Incidence | 47/50 (94%) | 45/48 (94%) | 44/46 (96%) | 46/49 (94%) | 45/50 (90.0%) | 46/46 (100%)
| | Severity Profile | 0\|24\|15\|8 (2.7) | 1\|27\|9\|8 (2.5) | 1\|25\|8\|10 (2.6) | 0\|27\|11\|8 (2.6) | 0\|26\|7\|12 (2.7) | 0\|23\|12\|11 (2.7)
| | Poly-3 Incidence | 47/48.7 (96%) | 45/45.1 (100%) | 44/44.2 (100%) | 46/47.0 (98%) | 45/45.8 (98%) | 46/46.0 (100%)
Cyst, follicle | Interim | Incidence | 8/23 (35%) | 4/22 (18%) | 10/22 (46%) | 5/24 (21%) | 10/20 (50%) | 11/24 (46%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 3/50 (6%) | 3/48 (6%) | 2/46 (4%) | 7/49 (14%) | 6/50 (12%) | 4/46 (9%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 Incidence | 3/35.7 (8%) | 3/33.4 (9%) | 2/28.9 (7%) | 7/34.5 (20%) | 6/30.8 (20%) | 4/32.3 (12%)
Depletion, Corpus luteum | Interim | Incidence | 4/23* (17%) | 4/22 (18%) | 7/22 (32%) | 4/24 (17%) | 8/20 (40%) | 9/24 (38%)
| | Severity Profile | –^b^ | – | – | – | – | –
Hypertrophy, Interstitial cell | Interim | Incidence | 4/23^*, #, ^^ (17%) | 4/22 (18%) | 6/22 (27%) | 3/24 (12%) | 8/20^^^ (40%) | 9/24 (38%)
| | Severity Profile | 0\|4\|0\|0 (2.0) | 0\|3\|1\|0 (2.2) | 0\|2\|4\|0 (2.7) | 0\|0\|2\|1 (3.3) | 0\|6\|2\|0 (2.2) | 1\|7\|1\|0 (2.0)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion.

Table 65 Non-Neoplastic Lesions in the Ovary of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Atrophy | Interim | Incidence | 10/23^***, ###, ^^^^ (44%) | 9/25 (36%) | 26/26^***, ###, ^^^^ (100%)
| | Severity Profile | 1\|4\|0\|5 (2.9) | 0\|3\|0\|6 (3.3) | 0\|0\|0\|26 (4.0)
| Terminal | Incidence | 47/50^###, ^^^^ (94%) | 25/26 (96%) | 26/26^###, ^^^^ (100%)
| | Severity Profile | 0\|24\|15\|8 (2.7) | 0\|12\|7\|6 (2.8) | 0\|1\|1\|24 (3.9)
| | Poly-3 Incidence | 47/48.7 (96%) | 25/26.0 (96%) | 26/26.0 (100%)
Cyst, follicle | Interim | Incidence | 8/23*** (35%) | 9/25 (36%) | 26/26*** (100%)
| | Severity Profile | –^c^ | – | –
| Terminal | Incidence | 3/50 (6%) | 0/26 (0%) | 3/26 (12%)
| | Severity Profile | –^c^ | – | –
| | Poly-3 Incidence | 3/35.7 (8%) | 0/15.9 (0%) | 3/16.1 (19%)
Depletion, Corpus luteum | Interim | Incidence | 4/23*** (17%) | 6/25 (24%) | 26/26*** (100%)
| | Severity Profile | –^c^ | – | –
Hypertrophy, Interstitial cell | Interim | Incidence | 4/23^***, ###, ^^^^ (17%) | 5/25 (20.0%) | 26/26^***, ###, ^^^^ (100%)
| | Severity Profile | 0\|4\|0\|0 (2.0) | 0\|4\|1\|0 (2.2) | 1\|13\|10\|2 (2.5)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 64.

^c^ Severity scores were not assigned for this lesion.

Table 66 Non-Neoplastic Lesions in the Ovary of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Atrophy | Interim | Incidence | 10/20 (50%) | 9/22 (41%) | 11/20 (55%) | 6/22 (27%) | 12/20 (60%) | 15/22 (68%)
| | Severity Profile | 2\|6\|0\|2 (2.2) | 1\|4\|0\|4 (2.8) | 8\|1\|0\|2 (1.6) | 1\|3\|0\|2 (2.5) | 5\|4\|0\|3 (2.1) | 4\|5\|0\|6 (2.5)
| Terminal | Incidence | 47/49 (96%) | 48/49 (98%) | 46/47 (98%) | 50/50 (100%) | 49/50 (98%) | 44/46 (96%)
| | Severity Profile | 1\|23\|16\|7 (2.6) | 0\|34\|11\|3 (2.4) | 1\|28\|11\|6 (2.5) | 1\|33\|7\|9 (2.5) | 0\|25\|16\|8 (2.7) | 0\|23\|12\|9 (2.7)
| | Poly-3 Incidence | 47/47.5 (99%) | 48/48.1 (100%) | 46/46.1 (100%) | 50/50.0 (100%) | 49/49.0 (100%) | 44/44.8 (98%)
Cyst, follicle | Interim | Incidence | 5/20*** (25%) | 6/22 (27%) | 4/20 (20%) | 7/22 (32%) | 11/20 (55%) | 18/22*** (82%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 4/49 (8%) | 4/49 (8%) | 2/47 (4%) | 1/50 (2%) | 2/50 (4%) | 4/46 (9%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 Incidence | 4/32.0 12%) | 4/33.5 (12%) | 2/30.2 (7%) | 1/34.6 (3%) | 2/35.7 (6%) | 4/32.4 (12%)
Depletion, Corpus luteum | Interim | Incidence | 2/20 (10%) | 4/22 (18%) | 2/20 (10%) | 2/22 (9%) | 3/20 (15%) | 6/22 (27%)
| | Severity Profile | –^b^ | – | – | – | – | –
Hypertrophy, Interstitial cell | Interim | Incidence | 4/20 (20%) | 3/22 (14%) | 1/20 (5%) | 2/22 (9%) | 3/20 (15%) | 5/22 (23%)
| | Severity Profile | 0\|1\|3\|0 (2.8) | 0\|2\|1\|0 (2.3) | 0\|1\|0\|0 (2.0) | 0\|2\|0\|0 (2.0) | 0\|3\|0\|0 (2.0) | 0\|4\|1\|0 (2.2)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion.

There were no statistically significant BPA treatment-related effects in the continuous-dose terminal sacrifice females. Females in the interim sacrifice continuous BPA dose arm showed significant dose trends for depletion of corpora lutea and interstitial cell hypertrophy (Table 64). For interstitial cell hypertrophy, the 2,500 μg BPA/kg bw/day dose group was significantly different from the vehicle control incidence (RTE test only, 40% versus 17%). The 25,000 μg BPA/kg bw/day dose group had an incidence of 38% (p = 0.068).

In the ovaries of continuous EE_2_-treated interim sacrifice females, there were significant dose trends and significant pairwise comparisons of the 0.5 μg EE_2_/kg bw/day dose group to the vehicle control detected in all statistical tests applied for atrophy (100% versus 44%), follicular cysts (100% versus 35%), depleted corpora lutea (100% versus 17%), and interstitial cell hypertrophy (100% versus 17%) (Table 65). In the terminal sacrifice females, there was a 94% incidence of ovarian atrophy in vehicle controls and 100% atrophy in the high EE_2_ dose group, with greater severity in the EE_2_-treated group that was significantly greater than controls by both tests that incorporate severity scores (JT/SW and RTE, p < 0.001 for both).

There were no statistically significant BPA treatment-related effects in the stop-dose terminal sacrifice females. In the stop-dose BPA-treated interim sacrifice animals, there was a significant dose trend (p < 0.001) for follicular cysts and the 25,000 μg BPA/kg bw/day dose group had a higher incidence than vehicle controls (82% versus 25%) (Table 66). The 2,500 μg BPA/kg bw/day dose group had an incidence of 55% (p = 0.053). There were no continuous-dose BPA groups with significantly higher follicular cyst incidence than the vehicle controls (Table 64).

#### Vagina, non-neoplastic lesions

Non-neoplastic lesions in the vaginas of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 67, Table 68, and Table 69, respectively.

Table 67 Non-Neoplastic Lesions in the Vagina of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, epithelium | Interim | Incidence | 3/23^**, ##, ^^^ (13%) | 2/22 (9%) | 2/21 (10%) | 4/24 (17%) | 6/20 (30%) | 8/24^#, ^^ (33%)
| | Severity Profile | 0\|1\|2\|0 (2.7) | 0\|1\|1\|0 (2.5) | 0\|1\|1\|0 (2.5) | 0\|0\|4\|0 (3.0) | 0\|1\|5\|0 (2.8) | 0\|1\|7\|0 (2.9)
| Terminal | Incidence | 4/49^##, ^^^ (8%) | 5/48 (10%) | 12/45^##, ^^ (27%) | 10/49^#^ (20%) | 11/50^#, ^^ (22%) | 12/46^#, ^^ (26%)
| | Severity Profile | 0\|1\|2\|1 ((3.0) | 0\|1\|4\|0 (2.8) | 1\|3\|6\|2 (2.8) | 0\|7\|3\|0 (2.3) | 0\|3\|5\|3 (3.0) | 0\|6\|4\|2 (2.7)
| | Poly-3 Incidence | 4/35.2** (11%) | 5/35.3 (14%) | 12/33.7* (36%) | 10/36.5 (27%) | 11/33.4* (33%) | 12/36.8* (33%)
Mucification, epithelium | Interim | Incidence | 10/23 (44%) | 12/22 (54%) | 7/21 (33%) | 9/24 (38%) | 7/20 (35%) | 8/24 (33%)
| | Severity Profile | 0\|6\|1\|3 (2.7) | 0\|7\|4\|1 (2.5) | 0\|0\|3\|4 (3.6) | 0\|1\|5\|3 (3.2) | 0\|0\|2\|5 (3.7) | 1\|3\|1\|3 (2.8)
| Terminal | Incidence | 46/49 (94%) | 37/48 (77%) | 34/45 (76%) | 39/49 (80%) | 34/50^^ N^ (68%) | 40/46 (87%)
| | Severity Profile | 0\|13\|12\|21 (3.2) | 0\|7\|8\|22 (3.4) | 0\|7\|11\|16 (3.3) | 0\|4\|14\|21 (3.4) | 0\|8\|9\|17 (3.3) | 1\|10\|8\|21 (3.2)
| | Poly-3 Incidence | 46/47.2 (97%) | 37/42.0 (88%) | 34/39.3^* N^ (87%) | 39/45.2^* N^ (86%) | 34/42.8^** N^ (79%) | 40/43.6 (92%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 68 Non-Neoplastic Lesions in the Vagina of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, epithelium | Interim | Incidence | 3/23^***, ###, ^^^^ (13%) | 7/25 (28%) | 20/26^***, ###, ^^^^ (77%)
| | Severity Profile | 0\|1\|2\|0 (2.7) | 0\|4\|3\|0 (2.4) | 0\|9\|11\|0 (2.6)
| Terminal | Incidence | 4/49 (8%) | 5/26 (19%) | 2/26 (8%)
| | Severity Profile | 0\|1\|2\|1 (3.0) | 0\|1\|2\|2 (3.2) | 0\|1\|1\|0 (2.5)
| | Poly-3 Incidence | 4/35.2 (11%) | 5/18.6 (27%) | 2/15.8 (13%)
Mucification, epithelium | Interim | Incidence | 10/23^*, #, ^^ (44%) | 15/25 (60%) | 18/26^#, ^^ (69%)
| | Severity Profile | 0\|6\|1\|3 (2.7) | 0\|5\|1\|9 (3.3) | 1\|4\|6\|7 (3.1)
| Terminal | Incidence | 46/49 (94%) | 21/26 (81%) | 23/26 (88%)
| | Severity Profile | 0\|13\|12\|21 (3.2) | 0\|4\|5\|12 (3.4) | 0\|6\|8\|9 (3.1)
| | Poly-3 Incidence | 46/47.2 (97%) | 21/24.0 (87%) | 23/24.8 (93%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 67.

Table 69 Non-Neoplastic Lesions in the Vagina of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a, b^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, epithelium | Interim | Incidence | 2/20 (10%) | 4/22 (18%) | 2/20 (10%) | 1/22 (4%) | 2/20 (10%) | 6/22 (27%)
| | Severity Profile | 0\|0\|2\|0 (3.0) | 0\|0\|4\|0 (3.0) | 0\|0\|2\|0 (3.0) | 0\|0\|0\|1 (4.0) | 0\|1\|1\|0 (2.5) | 0\|1\|5\|0 (2.8)
| Terminal | Incidence | 6/49 (12%) | 10/50 (20%) | 3/47 (6%) | 7/49 (14%) | 7/49 (14%) | 7/46 (15%)
| | Severity Profile | 0\|3\|2\|1 (2.7) | 0\|5\|4\|1 (2.6) | 0\|1\|1\|1 (3.0) | 0\|2\|4\|1 (2.9) | 0\|1\|5\|1 (3.0) | 0\|0\|5\|2 (3.3)
| | Poly-3 Incidence | 6/33.7 (18%) | 10/35.4 (28%) | 3/31.8 (9%) | 7/35.9 (20%) | 7/37.6 (19%) | 7/34.6 (20%)
Mucification, epithelium | Interim | Incidence | 8/20 (40%) | 11/22 (50%) | 9/20 (45%) | 11/22 (50%) | 8/20 (40%) | 10/22 (45%)
| | Severity Profile | 1\|2\|1\|4 (3.0) | 0\|3\|4\|4 (3.1) | 0\|3\|4\|2 (2.9) | 0\|6\|2\|3 (2.7) | 0\|1\|3\|4 (3.4) | 0\|2\|3\|5 (3.3)
| Terminal | Incidence | 40/49 (82%) | 46/50 (92%) | 37/47 (79%) | 44/49 (90%) | 39/49 (80%) | 34/46 (74%)
| | Severity Profile | 0\|7\|12\|21 (3.4) | 1\|7\|15\|23 (3.3) | 0\|9\|9\|19 (3.3) | 2\|12\|12\|18 (3.0) | 0\|8\|9\|22 (3.4) | 1\|5\|11\|17 (3.3)
| | Poly-3 Incidence | 40/45.8 (87%) | 46/48.1 (96%) | 37/42.4 (87%) | 44/47.9 (92%) | 39/44.6 (88%) | 34/39.7 (86%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was also a significant Poly-3 dose trend (p = 0.029) for polymorphonuclear cellular infiltration (not shown in Table). The p-value for trend with all animals included was 0.136.

Statistically significant effects were observed in both the interim and terminal sacrifice BPA-treated animals for epithelial hyperplasia for the continuous-dose arm (Table 67). For the interim sacrifice animals, there was a significant dose trend (all statistical tests) and the 25,000 μg BPA/kg bw/day dose group had a significantly higher incidence of hyperplasia than the vehicle controls (JT/SW and RTE tests, 33% versus 13%). The incidence in the 2,500 μg BPA/kg bw/day continuous-dose group was 30% (p = 0.074 and 0.067 for the JT/SW and RTE tests, respectively). In the terminal sacrifice females, there was a significant dose trend (all statistical tests) and significant pairwise comparisons to control for 25–25,000 μg BPA/kg bw/day dose groups, although the response was similar across dose groups (incidences of 8% in vehicle controls and 27%, 20%, 22%, and 26% for the 25, 250, 2,500, and 25,000 μg BPA/kg bw/day dose groups, respectively). The Poly-3 and RTE tests were not significant for the 250 μg BPA/kg bw/day dose group.

In the vaginas of females treated continuously with EE_2_, statistically significant effects were observed in the interim sacrifice animals, but not in terminal sacrifice animals. For all statistical tests applied, there was a dose trend for epithelial hyperplasia and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (77% versus 13%) (Table 68). There was also a trend toward increased epithelial mucification (all statistical tests) and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (69% versus 44%, JT/SW and RTE tests).

In the stop-dose arm, there were no statistically significant BPA effects in the interim or terminal sacrifice females, although the incidence of epithelial hyperplasia was 27% in the 25,000 μg BPA/kg bw/day dose group versus 10% in the vehicle control (p = 0.064) in the interim sacrifice animals (Table 69).

#### Pituitary, neoplastic and non-neoplastic lesions

Neoplastic lesions in the pituitaries of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 70, Table 71, and Table 72, respectively. Adenomas or carcinomas of the pars distalis were observed at low incidence in interim animals, and higher incidences, primarily of adenomas, were observed in terminal animals. There were no statistically significant effects in BPA continuous- or stop-dose interim or terminal sacrifice animals (Table 70 and Table 72). In the terminal EE_2_ females, the incidence of combined adenomas and carcinomas of the pars distalis was increased in the 0.5 μg/kg bw/day dose group (77% versus 44%, Table 71).

Table 70 Neoplastic Lesions in the Pituitary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenoma, pars distalis | Interim^b^ | Incidence | 0/23 | 0/22 | 1/22 | 1/24 | 0/20 | 0/24
Adenoma, pars distalis | Terminal | Incidence | 21/50 (42%) | 22/48 (46%) | 12/46 (26%) | 20/49 (41%) | 19/49 (39%) | 21/46 (46%)
| | Poly-3 Incidence | 21/39.9 (53%) | 22/37.1 (59%) | 12/31.4 (38%) | 20/36.6 (55%) | 19/34.1 (56%) | 21/35.4 (59%)
| | Terminal Incidence | 7/16 (44%) | 12/19 (63%) | 4/14 (29%) | 8/13 (62%) | 5/10 (50%) | 4/8 (50%)
| | Time-to-First | 477 | 497 | 434 | 561 | 456 | 510
| | Poly-3 p-value | 0.313 | 0.356 | 0.153N | 0.523 | 0.487 | 0.356
Adenoma or carcinoma, pars distalis | Terminal | Incidence | 22/50 (44%) | 23/48 (48%) | 12/46 (26%) | 20/49 (41%) | 19/49 (39%) | 21/46 (46%)
| | Poly-3 Incidence | 22/40.3 (55%) | 23/37.7 (61%) | 12/31.4 (38%) | 20/36.6 (55%) | 19/34.1 (56%) | 21/35.4 (59%)
| | Terminal Incidence | 7/16 (44%) | 12/19 (63%) | 4/14 (29%) | 8/13 (62%) | 5/10 (50%) | 4/8 (50.0%)
| | Time-to-First | 477 | 497 | 434 | 561 | 456 | 510
| | Poly-3 p-value | 0.408 | 0.361 | 0.115N | 0.595 | 0.559 | 0.425

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. There were no significant increases relative to vehicle control.

^b^ No statistical analysis of lesions in interim animals was conducted since no group had two or more lesions.

Table 71 Neoplastic Lesions in the Pituitary Gland of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 0.05 EE_2_ | 0.5 EE_2_
Adenoma, pars distalis | Interim^b^ | Incidence | 0/23 | 1/25 | 1/26
Adenoma, pars distalis | Terminal | Incidence | 21/50 (42%) | 10/26 (38%) | 17/26 (65%)
| | Poly-3 Incidence | 21/39.9 (53%) | 10/18.3 (55%) | 17/23.2 (73%)
| | Terminal Incidence | 7/16 (44%) | 4/7 (57%) | 2/4 (50%)
| | Time-to-First | 477 | 484 | 360
| | Poly-3 p-value | 0.055 | 0.561 | 0.068
Carcinoma, pars distalis | Terminal | Incidence Poly-3 Incidence Terminal Incidence Time-to-First Poly-3 p-value | 1/50 (2%) | 0/26 (0%) | 3/26 (12%)
| | Incidence Poly-3 Incidence Terminal Incidence Time-to-First Poly-3 p-value | 1/34.6 (3%) | 0/15.9 (0%) | 3/16.1 (19%)
| | Incidence Poly-3 Incidence Terminal Incidence Time-to-First Poly-3 p-value | 0/16 (0%) | 0/7 (0%) | 0/4 (0%)
| | Incidence Poly-3 Incidence Terminal Incidence Time-to-First Poly-3 p-value | 615 | – | 610
| | Incidence Poly-3 Incidence Terminal Incidence Time-to-First Poly-3 p-value | 0.053 | 0.652N | 0.084
Adenoma or carcinoma, pars distalis | Terminal | Incidence | 22/50 (44%) | 10/26 (38%) | 20/26 (77%)
| | Poly-3 Incidence | 22/40.3 (55%) | 10/18.3 (55%) | 20/24.2 (83%)
| | Terminal Incidence | 7/16 (44%) | 4/7 (57%) | 2/4 (50%)
| | Time-to-First | 477 | 484 | 360
| | Poly-3 p-value | 0.009** | 0.615N | 0.011*

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation.

^b^ No statistical analysis of lesions in interim animals was conducted since no group had two or more lesions.

Table 72 Neoplastic Lesions in the Pituitary Gland of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenoma or carcinoma, pars distalis | Interim | Incidence | 0/20 (0%) | 0/22 (0%) | 2/20 (10%)^b^ | 0/22 (0%) | 0/20 (0%) | 0/22 (0%)
| | Terminal Incidence | 0/20 (0%) | 0/22 (0%) | 2/20 (10%) | 0/22 (0%) | 0/20 (0%) | 0/22 (0%)
| | Time-to-First | – | – | 364 (T) | – | – | –
| | CAFE p-value | 0.408N | – | 0.244 | – | – | –
Adenoma, pars distalis | Terminal | Incidence | 23/49 (47%) | 16/50 (32%) | 14/48 (29%) | 20/50 (40%) | 20/50 (40%) | 20/46 (43%)
| | Poly-3 Incidence | 23/38.5 (60%) | 16/36.3 (44%) | 14/33.5 (42%) | 20/39.4 (51%) | 20/38.5 (52%) | 20/35.5 (56%)
| | Terminal Incidence | 7/11 (64%) | 5/12 (42%) | 8/13 (62%) | 6/13 (46%) | 9/17 (53%) | 6/13 (46%)
| | Time-to-First | 502 | 397 | 442 | 448 | 520 | 445
| | Poly-3 p-value | 0.470 | 0.112N | 0.081N | 0.271N | 0.308N | 0.469N
Adenoma or carcinoma, pars distalis | Terminal | Incidence | 23/49 (47%) | 16/50 (32%) | 14/48 (29%) | 21/50 (42%) | 20/50 (40%) | 21/46 (46%)
| | Poly-3 Incidence | 23/38.5 (60%) | 16/36.3 (44%) | 14/33.5 (42%) | 21/39.7 (53%) | 20/38.5 (52%) | 21/35.5 (59%)
| | Terminal Incidence | 7/11 (64%) | 5/12 (42%) | 8/13 (62%) | 6/13 (46%) | 9/17 (53%) | 7/13 (54%)
| | Time-to-First | 502 | 397 | 442 | 448 | 520 | 445
| | Poly-3 p-value | 0.373 | 0.112N | 0.081N | 0.340N | 0.308N | 0.574N

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation. There were no significant increases relative to vehicle control.

^b^ One adenoma and one carcinoma.

Non-neoplastic lesions in the pituitaries of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 73, Table 74, and Table 75, respectively.

Table 73 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, pars distalis | Interim | Incidence | 18/23 (78%) | 17/22 (77%) | 18/22 (82%) | 15/24 (62%) | 16/20 (80%) | 20/24 (83%)
| | Severity Profile | 8\|6\|3\|1 (1.8) | 7\|6\|3\|1 (1.9) | 7\|4\|5\|2 (2.1) | 8\|4\|2\|1 (1.7) | 8\|6\|1\|1 (1.7) | 7\|8\|4\|1 (2.0)
| Terminal | Incidence | 27/50 (54%) | 22/48 (46%) | 32/46 (70%) | 26/49 (53%) | 29/49 (59%) | 23/46 (50%)
| | Severity Profile | 0\|3\|12\|12 (3.3) | 1\|2\|5\|14 (3.5) | 0\|4\|12\|16 (3.4) | 1\|5\|7\|13 (3.2) | 3\|10\|4\|12 (2.9) | 1\|6\|6\|10 (3.1)
| | Poly-3 Incidence | 27/43.6 (62%) | 22/40.2 (55%) | 32/40.6^b^ (79%) | 26/44.2 (59%) | 29/42.7 (68%) | 23/39.7 (58%)
Angiectasis | Interim^c^ | Incidence | 1/23 (4%) | 0/22 (0%) | 1/22 (5%) | 0/24 (0%) | 0/20 (0%) | 0/24 (0%)
| | Severity Profile | 0/1/0/0 (2.0) | – | 0/1/0/0 (2.0) | – | – | –
| Terminal | Incidence | 10/50 (20%) | 8/48 (17%) | 4/46 (9%) | 9/49 (18%) | 9/49 (18%) | 9/46 (20%)
| | Severity Profile | 0\|1\|1\|8 (3.7) | 0\|0\|0\|8 (4.0) | 0\|0\|0\|4 (4.0) | 0\|0\|2\|7 (3.8) | 0\|2\|2\|5 (3.3) | 0\|1\|1\|7 (3.7)
| | Poly-3 Incidence | 10/37.5 (27%) | 8/35.4 (23%) | 4/29.1 (14%) | 9/34.8 (26%) | 9/31.3 (29%) | 9/32.2 (28%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.027) for the pairwise comparison of the 25 μg BPA/kg bw/day group to the vehicle control (hyperplasia of the pars distalis, Poly-3 incidences 30/37.0 (81%) versus 18/30.8 (58%)).

^c^ This lesion was not statistically analyzed and is not included in Supplemental Appendix XXXIII since no dose group had two or more lesions. The data are found in Supplemental Appendix XXXII.

Table 74 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, pars distalis | Interim | Incidence | 18/23^##, ^^^ (78%) | 20/25 (80%) | 25/26^##, ^^^ (96%)
| | Severity Profile | 8\|6\|3\|1 (1.8) | 10\|7\|3\|0 (1.6) | 4\|11\|6\|4 (2.4)
| Terminal | Incidence | 27/50^#, ^^ N^ (54%) | 16/26 (62%) | 6/26^##, ^^ N^ (23%)
| | Severity Profile | 0\|3\|12\|12 (3.3) | 0\|3\|5\|8 (3.3) | 0\|1\|2\|3 (3.3)
| | Poly-3 Incidence | 27/43.6 (62%) | 16/23.6 (68%) | 6/16.9 (36%)
Angiectasis | Interim | Incidence | 1/23^*, #, ^^ (4%) | 2/25 (8%) | 6/26^#, ^^ (23%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 0\|1\|0\|1 (3.0) | 0\|4\|1\|1 (2.5)
| Terminal | Incidence | 10/50^###, ^^^^ (20%) | 5/26 (19%) | 17/26^###, ^^^^ (65%)
| | Severity Profile | 0\|1\|1\|8 (3.7) | 0\|0\|0\|5 (4.0) | 0\|0\|0\|17 (4.0)
| | Poly-3 Incidence | 10/37.5*** (27%) | 5/17.1 (29%) | 17/22.0*** (77%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 73.

Table 75 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, pars distalis | Interim | Incidence | 18/20 (90%) | 16/22 (73%) | 14/20 (70%) | 20/22 (91%) | 16/20 (80%) | 18/22 (82%)
| | Severity Profile | 10\|8\|0\|0 (1.4) | 10\|4\|2\|0 (1.5) | 5\|5\|4\|0 (1.9) | 10\|9\|1\|0 (1.6) | 6\|7\|3\|0 (1.8) | 9\|8\|1\|0 (1.6)
| Terminal | Incidence | 25/49 (51%) | 32/50^^^ (64%) | 34/48^^^ (71%) | 26/50 (52%) | 28/50 (56%) | 21/46 (46%)
| | Severity Profile | 3\|7\|7\|8 (2.8) | 0\|5\|11\|16 (3.3) | 2\|6\|14\|12 (3.1) | 0\|6\|9\|11 (3.2) | 3\|7\|5\|13 (3.0) | 1\|3\|7\|10 (3.2)
| | Poly-3 Incidence | 25/42.2 (59%) | 32/43.5 (74%) | 34/45.0 (76%) | 26/43.3 (60%) | 28/45.3 (62%) | 21/39.1 (54%)
Angiectasis | Interim | Incidence | 0/20 (0%) | 2/22^^^ (9%) | 1/20 (5%) | 0/22 (0%) | 0/20 (0%) | 0/22 (0%)
| | Severity Profile | – | 0\|1\|1\|0 (2.5) | 0\|1\|0\|0 (2.0) | – | – | –
| Terminal | Incidence | 12/49 (24%) | 11/50 (22%) | 8/48 (17%) | 12/50 (24%) | 14/50 (28%) | 11/46 (24%)
| | Severity Profile | 0\|0\|0\|12 (4.0) | 0\|0\|1\|10 (3.9) | 0\|1\|2\|5 (3.5) | 0\|3\|1\|8 (3.4) | 0\|1\|2\|11 (3.7) | 0\|2\|5\|4 (3.2)
| | Poly-3 Incidence | 12/35.3 (34%) | 11/34.5 (32%) | 8/32.7 (24%) | 12/38.4 (31%) | 14/37.6 (37%) | 11/33.9 (32%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

There were no statistically significant treatment effects in the pituitaries of continuous BPA dose arm interim or terminal sacrifice females (Table 73).

In the pituitaries of females treated continuously with EE_2_, increased lesion incidences relative to vehicle controls were observed in the interim and terminal sacrifice animals (Table 74). In the interim sacrifice animals, there was a significant increasing trend for hyperplasia in the pars distalis and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to the high incidence in the vehicle control (96% versus 78%, JT/SW and RTE tests). There was also a significant trend for angiectasis in the interim sacrifice females (all statistical tests) and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (23% versus 4%, JT/SW and RTE tests). Similar trends and pairwise comparisons of the high EE_2_ dose group to vehicle control were seen in the terminal sacrifice females (65% versus 20%, all statistical tests).

There were few statistically significant increased incidences over vehicle control in the stop-dose BPA arm, all indicated only by the RTE test (Table 75). In the interim sacrifice females, there was an increase in angiectasis (dilated vasculature) in the 2.5 μg BPA/kg bw/day stop-dose group (9% versus 0%). In the stop-dose terminal sacrifice females, the incidence of hyperplasia in the pars distalis was increased in the 2.5 and 25 μg BPA/kg bw/day stop-dose groups (64% and 71%, respectively, versus 51%) (Table 75). In the terminal sacrifice continuous-dose females, the incidences of the same lesion in the vehicle control, 2.5 and 25 μg BPA/kg bw/day stop-dose groups were 54%, 46%, and 70%, respectively, with no statistically significant comparisons (Table 73).

#### Heart, non-neoplastic lesions

Cardiomyopathy is a high-incidence background lesion in this rat strain, which increases with aging in both sexes. The lower incidences in females than in males allowed for a better evaluation of any potential treatment effects. Incidences and severity scores for cardiomyopathy in interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 76, Table 77, and Table 78, respectively.

Table 76 Non-Neoplastic Lesions in the Heart of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Cardiomyopathy | Interim | Incidence | 7/23 (30%) | 10/22 (46%) | 9/22 (41%) | 8/24 (33%) | 9/20 (45%) | 7/24 (29%)
| | Severity Profile | 6\|1\|0\|0 (1.1) | 8\|2\|0\|0 (1.2) | 7\|2\|0\|0 (1.2) | 8\|0\|0\|0 (1.0) | 8\|1\|0\|0 (1.1) | 6\|1\|0\|0 (1.1)
| Terminal | Incidence | 35/50 (70%) | 30/48 (62%) | 24/46^^ N^ (52%) | 35/49 (71%) | 33/50 (66%) | 33/46 (72%)
| | Severity Profile | 24\|10\|1\|0 (1.3) | 18\|7\|4\|1 (1.6) | 18\|5\|1\|0 (1.3) | 25\|9\|1\|0 (1.3) | 24\|7\|1\|1 (1.4) | 23\|9\|0\|1 (1.4)
| | Poly-3 Incidence | 35/43.5 (81%) | 30/39.0 (77%) | 24/34.6 (69%) | 35/42.3 (83%) | 33/38.4 (86%) | 33/39.4 (84%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 77 Non-Neoplastic Lesions in the Heart of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Cardiomyopathy | Interim | Incidence | 7/23^**, ##, ^^^ (30%) | 8/26 (30.8%) | 17/26^*, ##, ^^^ (65%)
| | Severity Profile | 6\|1\|0\|0 (1.1) | 8\|0\|0\|0 (1.0) | 13\|4\|0\|0 (1.2)
| Terminal | Incidence | 35/50^^^ (70%) | 19/26 (73%) | 22/26^#, ^^ (85%)
| | Severity Profile | 24\|10\|1\|0 (1.3) | 14\|5\|0\|0 (1.3) | 12\|9\|1\|0 (1.5)
| | Poly-3 Incidence | 35/43.5 (81%) | 19/22.6 (84%) | 22/24.0 (92%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 76.

Table 78 Non-Neoplastic Lesions in the Heart of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Cardiomyopathy | Interim | Incidence | 6/20 (30%) | 8/22 (36%) | 7/20 (35%) | 7/22 (32%) | 6/20 (30%) | 7/22 (32%)
| | Severity Profile | 6\|0\|0\|0 (1.0) | 8\|0\|0\|0 (1.0) | 6\|1\|0\|0 (1.1) | 5\|2\|0\|0 (1.3) | 6\|0\|0\|0 (1.0) | 5\|2\|0\|0 (1.3)
| Terminal | Incidence | 32/50^##, ^^^ (64%) | 37/50^^^ (74%) | 38/48 (79%) | 37/50^#, ^^ (74%) | 35/50^#, ^^ (70%) | 35/46^##, ^^^ (76%)
| | Severity Profile | 26\|3\|3\|0 (1.3) | 22\|13\|2\|0 (1.5) | 29\|7\|2\|0 (1.3) | 21\|14\|2\|0 (1.5) | 17\|13\|5\|0 (1.7) | 16\|14\|5\|0 (1.7)
| | Poly-3 Incidence | 32/42.9 (74%) | 37/42.9 (86%) | 38/43.1 (88%) | 37/44.0 (84%) | 35/44.0 (80%) | 35/39.7^b^ (88%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.049) for the comparison of the 25,000 μg BPA/kg bw/day dose group to the vehicle controls (Poly-3 incidences 27/30.8 (88%) versus 22/31.6 (70%)).

There were no statistically significant positive effects observed in female rats dosed continuously with BPA (Table 76). In the terminal sacrifice continuous-dose females, the vehicle control incidence of cardiomyopathy was 70%, with a reduced incidence (52%) in the 25 μg BPA/kg bw/day dose group.

In interim sacrifice females dosed continuously with EE_2_, all three statistical tests applied indicated a significant dose trend and a significant increase in the incidence of cardiomyopathy in the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (65% versus 30%) (Table 77). The JT/SW and RTE tests also detected an increase in the terminal sacrifice females (85% in the 0.5 μg EE_2_/kg bw/day dose group versus 70% in the vehicle control group). The RTE test also indicated a significant increasing trend in terminal sacrifice EE_2_ females.

In stop-dose BPA animals, no effects were observed in interim sacrifice females (Table 78). In terminal sacrifice stop-dose females, the statistical tests that incorporate severity scores along with incidence (JT/SW and RTE) detected a dose trend, and there were significant pairwise comparisons for 2.5, 250, 2,500, and 25,000 μg BPA/kg bw/day dose groups relative to the vehicle control (incidences of 74%, 74%, 70%, and 76%, respectively, versus 64%). The mean severity scores varied from 1.5 to 1.7 in the significantly different BPA groups versus 1.3 in the vehicle control, mostly due to an increased percentage of lesions diagnosed as mild rather than minimal in those groups.

#### Kidney, non-neoplastic lesions

Non-neoplastic lesions in the kidneys of interim and terminal sacrifice females for continuous BPA, EE_2_, and stop-dose BPA are shown in Table 79, Table 80, and Table 81, respectively.

Table 79 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Nephropathy | Interim | Incidence | 6/23 (26%) | 7/22 (32%) | 11/22^^^ (50%) | 8/24 (33%) | 11/20^^^ (55%) | 7/24 (29%)
| | Severity Profile | 4\|1\|0\|1(1.7) | 5\|1\|1\|0 (1.4) | 6\|2\|0\|3 (2.0) | 6\|1\|0\|1 (1.5) | 9\|0\|2\|0 (1.4) | 3\|2\|1\|1 (2.0)
| Terminal | Incidence | 19/50 (38%) | 28/48^^^^ (58%) | 21/46 (46%) | 21/49 (43%) | 21/50 (42%) | 25/46^#, ^^ (54%)
| | Severity Profile | 18\|0\|1\|0 (1.1) | 16\|9\|0\|3 (1.6) | 17\|2\|1\|1 (1.3) | 12\|5\|2\|2 (1.7) | 12\|4\|3\|2 (1.8) | 18\|3\|1\|3 (1.6)
| | Poly-3 Incidence | 19/39.9 (48%) | 28/40.6* (69%) | 21/34.4 (61%) | 21/38.5 (54%) | 21/35.5 (59%) | 25/38.2 (65%)
Cyst, renal tubule | Interim | Incidence | 0/23 (0%) | 7/22** (32%) | 3/22 (14%) | 3/24 (12%) | 3/20 (15%) | 1/24 (4%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 9/50 (18%) | 8/48 (17%) | 12/46 (26%) | 15/49 (31%) | 12/50 (24%) | 6/46 (13%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 Incidence | 9/36.2 (25%) | 8/34.3 (23%) | 12/32.1 (37%) | 15/36.1^c^ (42%) | 12/33.9 (35%) | 6/33.4 (18%)
Mineralization | Interim | Incidence | 11/23^*, ##, ^^^ (48%) | 5/22 (23%) | 11/22 (50%) | 12/24 (50%) | 11/20 (55%) | 16/24^#, ^^ (67%)
| | Severity Profile | 11\|0\|0\|0 (1.0) | 3\|1\|1\|0 (1.6) | 7\|2\|1\|1 (1.6) | 11\|1\|0\|0 (1.1) | 8\|3\|0\|0 (1.3) | 10\|3\|3\|0 (1.6)
| Terminal | Incidence | 30/50 (60%) | 23/48 (48%) | 25/46 (54%) | 25/49 (51%) | 24/50 (48%) | 26/46 (57%)
| | Severity Profile | 21\|8\|1\|0 (1.3) | 20\|3\|0\|0 (1.1) | 18\|7\|0\|0 (1.3) | 18\|7\|0\|0 (1.3) | 17\|5\|2\|0 (1.4) | 16\|7\|2\|1 (1.5)
| | Poly-3 Incidence | 30/42.9 (70%) | 23/37.8 (61%) | 25/40.3 (62%) | 25/40.6 (62%) | 24/39.3 (61%) | 26/38.6 (67%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion.

^c^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.033) for the pairwise comparison of the 250 μg BPA/kg bw/day dose group to the vehicle control group (renal tubule cyst, Poly-3 incidences 15/32.9 (46%) versus 5/24.8 (20%)).

Table 80 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Nephropathy | Interim | Incidence | 6/23^*, #, ^^ (26%) | 13/26 (50%) | 15/26^*, #, ^^ (58%)
| | Severity Profile | 4\|1\|0\|1 (1.7) | 8\|5\|0\|0 (1.4) | 10\|4\|1\|0 (1.4)
| Terminal | Incidence | 19/50^##, ^^^ (38%) | 14/26^#^ (54%) | 15/26^##, ^^^ (58%)
| | Severity Profile | 18\|0\|1\|0 (1.1) | 10\|3\|1\|0 (1.4) | 6\|5\|3\|1 (1.9)
| | Poly-3 Incidence | 19/39.9* (48%) | 14/21.0 (67%) | 15/21.6 (70%)
Cyst, renal tubule | Interim | Incidence | 0/23 (0%) | 5/26* (19%) | 4/26 (15%)
| | Severity Profile | – ^c^ | – | –
| Terminal | Incidence | 9/50 (18%) | 5/26 (19%) | 6/26 (23%)
| | Severity Profile | – ^c^ | – | –
| | Poly-3 Incidence | 9/36.2 (25%) | 5/18.3 (27%) | 6/17.6 (34%)
Mineralization | Interim | Incidence | 11/23 (48%) | 17/26^^^ (65%) | 14/26 (54%)
| | Severity Profile | 11\|0\|0\|0 (1.0) | 10\|6\|1\|0 (1.5) | 7\|5\|1\|1 (1.7)
| Terminal | Incidence | 30/50 (60%) | 10/26 (38%) | 17/26 (65%)
| | Severity Profile | 21\|8\|1\|0 (1.3) | 4\|5\|1\|0 (1.7) | 10\|7\|0\|0 (1.4)
| | Poly-3 Incidence | 30/42.9 (70%) | 10/20.7 (48%) | 17/22.0 (77%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 79.

^c^ Severity scores were not assigned for this lesion.

Table 81 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Nephropathy | Interim | Incidence | 10/20 (50%) | 10/22 (46%) | 10/20 (50%) | 11/22 (50%) | 12/20 (60%) | 13/22 (59%)
| | Severity Profile | 7\|2\|1\|0 (1.4) | 7\|2\|1\|0 (1.4) | 9\|1\|0\|0 (1.1) | 7\|3\|1\|0 (1.5) | 7\|5\|0\|0 (1.4) | 10\|1\|1\|1 (1.5)
| Terminal | Incidence | 28/49^##, ^^^ (57%) | 25/50 (50%) | 25/47 (53%) | 29/49 (59%) | 33/50 (66%) | 30/46^^^ (65%)
| | Severity Profile | 17\|8\|1\|2 (1.6) | 16\|4\|2\|3 (1.7) | 17\|3\|5\|0 (1.5) | 22\|5\|1\|1 (1.3) | 15\|11\|3\|4 (1.9) | 10\|11\|6\|3 (2.1)
| | Poly-3 Incidence | 28/39.2 (71%) | 25/41.3 (60%) | 25/38.4 (65%) | 29/40.9 (71%) | 33/43.3 (76%) | 30/39.9 (75%)
Cyst, renal tubule | Interim | Incidence | 4/20 (20%) | 3/22 (14%) | 4/20 (20%) | 4/22 (18%) | 6/20 (30%) | 5/22 (23%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 7/49 (14%) | 15/50 (30%) | 11/47 (23%) | 8/49 (16%) | 16/50 (32%) | 11/46 (24%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 Incidence | 7/33.6 (21%) | 15/34.9* (43%) | 11/34.3 (32%) | 8/36.1 (22%) | 16/39.6 (40%) | 11/34.4 (32%)
Mineralization | Interim | Incidence | 13/20 (65%) | 11/22 (50%) | 11/20 (55%) | 14/22 (64%) | 13/20 (65%) | 11/22 (50%)
| | Severity Profile | 8\|4\|0\|1 (1.5) | 9\|2\|0\|0 (1.2) | 6\|4\|0\|1 (1.6) | 8\|6\|0\|0 (1.4) | 6\|6\|1\|0 (1.6) | 8\|3\|0\|0 (1.3)
| Terminal | Incidence | 28/49 (57%) | 22/50 (44%) | 28/47 (60%) | 26/49 (53%) | 23/50 (46%) | 23/46 (50%)
| | Severity Profile | 20\|7\|0\|1 (1.4) | 14\|7\|1\|0 (1.4) | 18\|9\|0\|1 (1.4) | 17\|8\|1\|0 (1.4) | 11\|9\|3\|0 (1.7) | 13\|9\|1\|0 (1.5)
| | Poly-3 Incidence | 28/40.7 (69%) | 22/39.1 (56%) | 28/38.9 (72%) | 26/42.4 (61%) | 23/42.4 (54%) | 23/39.1 (59%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion.

The incidence of nephropathy was high and highly variable between continuous- and stop-dose vehicle controls (continuous interim and terminal controls, 26% and 38% (Table 79), respectively; stop-dose interim and terminal controls, 50% and 57% (Table 81), respectively).

For interim sacrifice females dosed continuously with BPA, the RTE test indicated an increased incidence of nephropathy in the 25 and 2,500 μg BPA/kg bw/day dose groups relative to the vehicle control (50% and 55%, respectively, versus 26%) (Table 79). In the terminal sacrifice females in the continuous BPA dose arm, both the Poly-3 and RTE tests detected increased incidences of nephropathy in the 2.5 μg BPA/kg bw/day group (58% versus 38%). In addition, the JT/SW and RTE tests detected an increased incidence in the 25,000 μg BPA/kg bw/day dose group relative to vehicle control (54% versus 38%). Additional statistically significant effects in the continuous BPA dose groups in the interim sacrifice animals were an increase in renal tubular cysts in the 2.5 μg BPA/kg bw/day group relative to vehicle controls (32% versus 0%, CAFE test; the control incidence in stop-dose group was 20% (Table 81) and an increased dose trend (all statistical tests applied) of mineralization, with a greater incidence in the 25,000 μg BPA/kg bw/day group relative to the vehicle control group (67% versus 48%, JT/SW and RTE tests only).

In females dosed continuously with EE_2_, statistically significant increased incidences of kidney lesions relative to vehicle controls were also observed (Table 80). In interim sacrifice females, all statistical tests applied indicated a dose trend and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control for nephropathy (58% versus 26%). This trend was also evident in the terminal sacrifice females (all statistical tests applied), and the JT/SW and/or RTE tests indicated significantly increased incidences in both the low and high EE_2_ dose groups (54% and 58%, respectively, versus 38%). In the interim female 0.05 μg EE_2_/kg bw/day dose group, there was an increase in renal tubule cysts (19% versus 0%) and mineralization (RTE test only, 65% versus 48%).

In terminal stop-dose females, renal tubular cysts were increased in the 2.5 μg BPA/kg bw/day group relative to the vehicle control group (43% versus 21%) (Table 81).

#### Liver, non-neoplastic lesions

Non-neoplastic lesions in the livers of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 82, Table 83, and Table 84, respectively.

Table 82 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, Mononuclear cells | Interim | Incidence | 4/23 (17%) | 6/22 (27%) | 4/22 (18%) | 5/24 (21%) | 5/20 (25%) | 4/24 (17%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 5\|1\|0\|0 (1.2) | 4\|0\|0\|0 (1.0) | 5\|0\|0\|0 (1.0) | 5\|0\|0\|0 (1.0) | 4\|0\|0\|0 (1.0)
| Terminal | Incidence | 37/50^##, ^^ N^ (74%) | 28/48 (58%) | 35/46 (76%) | 29/49^#, ^ N^ (59%) | 26/50^##, ^^ N^ (52%) | 24/46^#, ^ N^ (52%)
| | Severity Profile | 27\|9\|1\|0 (1.3) | 20\|8\|0\|0 (1.3) | 29\|6\|0\|0 (1.2) | 24\|5\|0\|0 (1.2) | 21\|5\|0\|0 (1.2) | 19\|4\|1\|0 (1.2)
| | Poly-3 Incidence | 37/44.3^** N^ (83%) | 28/38.1 (74%) | 35/38.7 (90%) | 29/41.9 (69%) | 26/38.7^* N^ (67%) | 24/37.9^* N^ (63%)
Cystic degeneration | Terminal | Incidence | 4/50 (8%) | 3/48 (6%) | 6/46 (13%) | 3/49 (6%) | 5/50 (10%) | 1/46 (2%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 3\|0\|0\|0 (1.0) | 6\|0\|0\|0 (1.0) | 3\|0\|0\|0 (1.0) | 4\|1\|0\|0 (1.2) | 1\|0\|0\|0 (1.0)
| | Poly-3 Incidence | 4/34.9 (12%) | 3/33.3 (9%) | 6/29.8 (20%) | 3/33.2 (9%) | 5/29.6 (17%) | 1/31.2 (3%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 83 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Infiltration, Mononuclear cells | Interim | Incidence | 4/23 (17%) | 7/26 (27%) | 2/26 (8%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 7\|0\|0\|0 (1.0) | 2\|0\|0\|0 (1.0)
| Terminal | Incidence | 37/50##, ^^^ N (74%) | 17/26 (65%) | 10/26##, ^^^ N (38%)
| | Severity Profile | 27\|9\|1\|0 (1.3) | 15\|2\|0\|0 (1.1) | 8\|2\|0\|0 (1.2)
| | Poly-3 Incidence | 37/44.3** N (83%) | 17/21.6 (79%) | 10/18.7** N (54%)
Cystic degeneration | Terminal | Incidence | 4/50 (8%) | 4/26 (15%) | 2/26 (8%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 4\|0\|0\|0 (1.0) | 1\|1\|0\|0 (1.5)
| | Poly-3 Incidence | 4/34.9 (12%) | 4/17.3 (23%) | 2/15.2 (13%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 82.

Table 84 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a, b^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, Mononuclear cells | Interim | Incidence | 2/20 (10%) | 10/22^*, ^^^ (46%) | 7/20 (35%) | 7/22 (32%) | 2/20 (10%) | 8/22^*, #, ^^ (36%)
| | Severity Profile | 1\|1\|0\|0 (1.5) | 10\|0\|0\|0 (1.0) | 7\|0\|0\|0 (1.0) | 7\|0\|0\|0 (1.0) | 2\|0\|0\|0 (1.0) | 8\|0\|0\|0 (1.0)
| Terminal | Incidence | 29/49 (59%) | 28/50 (56%) | 33/48 (69%) | 25/50 (50%) | 31/50 (62%) | 31/46 (67%)
| | Severity Profile | 22\|6\|1\|0 (1.3) | 18\|10\|0\|0 (1.4) | 26\|7\|0\|0 (1.2) | 16\|9\|0\|0 (1.4) | 25\|5\|1\|0 (1.2) | 23\|8\|0\|0 (1.3)
| | Poly-3 Incidence | 29/39.7 (73%) | 28/38.9 (72%) | 33/41.5 (80%) | 25/39.8 (63%) | 31/41.0 (76%) | 31/37.2 (83%)
Cystic degeneration | Terminal | Incidence | 2/49^##, ^^^ (4%) | 1/50 (2%) | 6/48 (12%) | 5/50 (10%) | 8/50^#, ^^ (16%) | 7/46^#, ^^ (15%)
| | Severity Profile | 2\|0\|0\|0 (1.0) | 1\|0\|0\|0 (1.0) | 6\|0\|0\|0 (1.0) | 5\|0\|0\|0 (1.0) | 6\|2\|0\|0 (1.2) | 7\|0\|0\|0 (1.0)
| | Poly-3 Incidence | 2/32.0** (6%) | 1/31.7 (3%) | 6/32.0 (19%) | 5/35.3 (14%) | 8/37.5 (21%) | 7/32.3 (22%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a statistically significant Poly-3 dose trend (p = 0.036; in the analysis that included all animals, p = 0.222) for mixed cell foci in terminal sacrifice animals (not shown in Table).

No statistically significant positive treatment-related effects were observed in continuous BPA or EE_2_ treatment groups (Table 82 and Table 83).

In the stop-dose BPA treatments in interim sacrifice females, mononuclear cell infiltration showed an increased incidence in several dose groups that was statistically significant for the 2.5 (CAFE and RTE tests) and 25,000 μg BPA/kg bw/day stop-dose groups (all statistical tests applied; 46% and 36%, respectively, versus 10%) (Table 84). In the terminal sacrifice females, there was a trend toward an increased incidence of cystic degeneration (all statistical tests applied) and significant pairwise comparisons (JT/SW and RTE tests) for 2,500 and 25,000 μg BPA/kg bw/day stop-dose groups (16% and 15%, respectively, versus 4%).

#### Thyroid, non-neoplastic lesions

Non-neoplastic lesions in the thyroid glands of interim and terminal sacrifice females for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 85, Table 86, and Table 87, respectively.

Table 85 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Female Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, C-cell | Interim | Incidence | 14/23 (61%) | 11/22 (50%) | 15/21 (71%) | 12/24 (50%) | 8/20 (40%) | 16/24 (67%)
| | Severity Profile | 8\|6\|0\|0 (1.4) | 9\|2\|0\|0 (1.2) | 12\|3\|0\|0 (1.2) | 9\|3\|0\|0 (1.2) | 4\|3\|1\|0 (1.6) | 12\|3\|1\|0 (1.3)
| Terminal | Incidence | 22/50 (44%) | 17/48 (35%) | 22/46 (48%) | 18/49 (37%) | 20/50 (40%) | 17/46 (37%)
| | Severity Profile | 11\|9\|2\|0 (1.6) | 12\|3\|2\|0 (1.4) | 13\|7\|2\|0 (1.5) | 11\|7\|0\|0 (1.4) | 8\|10\|2\|0 (1.7) | 7\|8\|2\|0 (1.7)
| | Poly-3 Incidence | 22/40.7 (54%) | 17/37.3 (46%) | 22/36.0 (61%) | 18/38.4 (47%) | 20/35.9 (56%) | 17/36.6 (46%)
Hyperplasia, Follicular cell^b^ | Terminal | Incidence | 1/50 (2%) | 6/48^^^ (12%) | 4/46 (9%) | 3/49 (6%) | 1/50 (2%) | 4/46 (9%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 0\|2\|4\|0 (2.7) | 0\|2\|1\|1 (2.8) | 0\|2\|1\|0 (2.3) | 0\|0\|0\|1 (4.0) | 0\|2\|2\|0 (2.5)
| | Poly-3 Incidence | 1/34.2 (3%) | 6/34.1 (18%) | 4/30.1 (13%) | 3/33.3 (9%) | 1/29.1 (3%) | 4/32.9 (12%)
Ultimobranchial cyst | Interim | Incidence | 7/23 (30%) | 7/22 (32%) | 5/21 (24%) | 8/24 (33%) | 6/20 (30%) | 11/24 (46%)
| | Severity Profile | –^c^ | – | – | – | – | –
| Terminal | Incidence | 8/50 (16%) | 2/48 (4%) | 6/46 (13%) | 3/49 (6%) | 4/50 (8%) | 7/46 (15%)
| | Severity Profile | –^c^ | – | – | – | – | –
| | Poly-3 Incidence | 8/36.4 (22%) | 2/33.5 (6%) | 6/30.2 (20%) | 3/33.3 (9%) | 4/30.2 (13%) | 7/32.8 (21%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Data for follicular cell hyperplasia are not tabulated for interim sacrifice animals since no dose groups had two or more diagnoses of this lesion.

^c^ No severity scores were assigned for ultimobranchial cysts.

Table 86 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Female Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, C-cell | Interim | Incidence | 14/23 (61%) | 11/26 (42%) | 13/26 (50%)
| | Severity Profile | 8\|6\|0\|0 (1.4) | 7\|4\|0\|0 (1.4) | 11\|1\|1\|0 (1.2)
| Terminal | Incidence | 22/50 (44%) | 7/26 (27%) | 9/25 (36%)
| | Severity Profile | 11\|9\|2\|0 (1.6) | 2\|5\|0\|0 (1.7) | 6\|2\|0\|1 (1.6)
| | Poly-3 Incidence | 22/40.7 (54%) | 7/18.7 (37%) | 9/18.1 (50%)
Hyperplasia, Follicular cell^c^ | Terminal | Incidence | 1/50 (2%) | 4/26 ^^^^ (15%) | 0/25 (0%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 0\|1\|3\|0 (2.8) | –
| | Poly-3 Incidence | 1/34.2 (3%) | 4/17.9* (22%) | 0/14.7 (0%)
Ultimobranchial cyst | Interim | Incidence | 7/23 (30%) | 7/26 (27%) | 11/26 (42%)
| | Severity Profile | –^d^ | – | –
| Terminal | Incidence | 8/50 (16%) | 5/26 (19%) | 8/25 (32%)
| | Severity Profile | –^d^ | – | –
| | Poly-3 Incidence | 8/36.4* (22%) | 5/17.5 (29%) | 8/17.4 (46%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 85.

^c^ Data for follicular cell hyperplasia are not tabulated for interim sacrifice animals since no dose groups had two or more diagnoses of this lesion.

^d^ No severity scores were assigned for ultimobranchial cysts.

Table 87 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Female Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, C-cell | Interim | Incidence | 10/20 (50%) | 16/22^^^ (73%) | 11/20 (55%) | 12/22 (54%) | 13/20 (65%) | 9/22 (41%)
| | Severity Profile | 10\|0\|0\|0 (1.0) | 11\|4\|1\|0 (1.4) | 8\|3\|0\|0 (1.3) | 8\|4\|0\|0 (1.3) | 11\|2\|0\|0 (1.2) | 8\|1\|0\|0 (1.1)
| Terminal | Incidence | 26/48 (54%) | 29/49 (59%) | 17/45 (38%) | 23/48 (48%) | 28/50 (56%) | 24/46 (52%)
| | Severity Profile | 8\|15\|2\|1 (1.8) | 15\|11\|1\|2 (1.7) | 11\|5\|0\|1 (1.5) | 15\|7\|1\|0 (1.4) | 10\|12\|4\|2 (1.9) | 11\|11\|2\|0 (1.6)
| | Poly-3 Incidence | 26/40.5 (64%) | 29/42.0 (69%) | 17/34.9 (49%) | 23/39.8 (58%) | 28/42.6 (66%) | 24/38.9 (62%)
Hyperplasia, Follicular cell^b^ | Terminal | Incidence | 4/48 (8%) | 4/49 (8%) | 7/45 (16%) | 6/48 (12%) | 5/50 (10%) | 4/46 (9%)
| | Severity Profile | 0\|2\|2\|0 (2.5) | 1\|3\|0\|0 (1.8) | 0\|5\|2\|0 (2.3) | 0\|4\|2\|0 (2.3) | 0\|3\|2\|0 (2.4) | 0\|3\|1\|0 (2.2)
| | Poly-3 Incidence | 4/32.8 (12%) | 4/32.0 (12%) | 7/31.6 (22%) | 6/35.4 (17%) | 5/35.9 (14%) | 4/33.2 (12%)
Ultimobranchial cyst | Interim | Incidence | 4/20 (20%) | 6/22 (27%) | 7/20 (35%) | 4/22 (18%) | 6/20 (30%) | 6/22 (27%)
| | Severity Profile | –^c^ | – | – | – | – | –
| Terminal | Incidence | 2/48 (4%) | 7/49 (14%) | 2/45 (4%) | 9/48 (19%) | 11/50 (22%) | 3/46 (6%)
| | Severity Profile | –^c^ | – | – | – | – | –
| | Poly-3 Incidence | 2/31.4 (6%) | 7/33.4 (21%) | 2/29.5 (7%) | 9/36.1* (25%) | 11/38.6* (28%) | 3/32.1 (9%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Data for follicular cell hyperplasia are not tabulated for interim sacrifice animals since no dose groups had two or more diagnoses of this lesion.

^c^ No severity scores were assigned for ultimobranchial cysts.

In the continuous-dose BPA terminal sacrifice females, the sole significant effect was an elevated incidence (RTE test only) of follicular cell hyperplasia in the 2.5 μg BPA/kg bw/day dose group relative to the vehicle control (12% versus 2%) (Table 85). The vehicle control incidence of follicular cell hyperplasia in the terminal sacrifice stop-dose vehicle control was 8% (Table 87).

The only statistically significant effects in females treated continuously with EE_2_ were an elevation (Poly-3 and RTE tests) of the incidence of follicular cell hyperplasia in the 0.05 μg EE_2_/kg bw/day dose group relative to vehicle control (15% versus 2%) and an increasing trend for ultimobranchial cysts in terminal sacrifice animals (Table 86).

In stop-dose BPA interim sacrifice females, the 2.5 μg BPA/kg bw/day stop-dose group had a higher incidence of C-cell hyperplasia than controls (RTE test only; 73% versus 50%) (Table 87). In stop-dose BPA terminal sacrifice females, the incidence of ultimobranchial cysts was elevated in the 250 and 2,500 μg BPA/kg bw/day stop-dose groups relative to vehicle controls (19% and 22%, respectively, versus 4%) (Table 87).

### Males

No statistically significant differences versus control were found regarding organ-specific neoplasms in males in any BPA treatment group. There was an increased trend (p-values ranging from 0.002 to 0.009) for systemic lymphoma that presented in multiple organs (liver, dorsal/lateral prostate, bone marrow, spleen, and kidney) in terminal sacrifice animals of the stop-dose BPA arm (Supplemental Appendix XXXII and XXXIV). The incidence of lymphoma in the dorsal/lateral prostate was increased in the 25,000 μg BPA/kg bw/day stop-dose group (9% versus 0%, Supplemental Appendix XXXIV). Selected neoplastic and non-neoplastic lesions are presented below.

#### Epididymis, non-neoplastic lesions

Non-neoplastic lesions in the epididymides of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 88, Table 89, and Table 90, respectively.

Table 88 Non-Neoplastic Lesions in the Epididymis of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Exfoliated germ cells | Interim | Incidence | 1/22^*, #, ^^ (4%) | 1/22 (4%) | 1/20 (5%) | 1/24 (4%) | 0/20 (0%) | 6/22^*, ##, ^^^ (27%)
| | Severity Profile | 1\|0\|0\|0 (1.0) | 1\|0\|0\|0 (1.0) | 0\|1\|0\|0 (2.0) | 1\|0\|0\|0 (1.0) | - | 6\|0\|0\|0 (1.0)
| Terminal | Incidence | 10/49 (20%) | 8/48 (17%) | 10/48 (21%) | 12/50 (24%) | 13/50 (26%) | 6/46 (13%)
| | Severity Profile | 5\|3\|1\|1 (1.8) | 5\|1\|2\|0 (1.6) | 1\|9\|0\|0 (1.9) | 4\|5\|2\|1 (2.0) | 4\|7\|2\|0 (1.8) | 4\|0\|2\|0 (1.7)
| | Poly-3 Incidence | 10/36.5 (27%) | 8/35.5 (23%) | 10/35.4 (28%) | 12/37.4 (32%) | 13/38.0 (34%) | 6/30.1 (20%)
Infiltration, cellular, lymphocyte | Interim | Incidence | 0/22^*, #, ^^ (0%) | 1/22 (4%) | 3/20 (15%) | 2/24 (8%) | 0/20 (0%) | 5/22^*, ##, ^^^ (23%)
| | Severity Profile | - | 0\|1\|0\|0 (2.0) | 3\|0\|0\|0 (1.0) | 2\|0\|0\|0 (1.0) | - | 5\|0\|0\|0 (1.0)
| Terminal | Incidence | 10/49 (20%) | 12/48 (25%) | 13/48 (27%) | 15/50 (30%) | 14/50 (28%) | 15/46 (33%)
| | Severity Profile | 8\|2\|0\|0 (1.2) | 12\|0\|0\|0 (1.0) | 11\|2\|0\|0 (1.2) | 13\|2\|0\|0 (1.1) | 12\|2\|0\|0 (1.1) | 13\|2\|0\|0 (1.1)
| | Poly-3 Incidence | 10/35.5 (28%) | 12/36.5 (33%) | 13/34.4 (38%) | 15/36.2 (41%) | 14/36.0 (39%) | 15/34.1 (44%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 89 Non-Neoplastic Lesions in the Epididymis of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic^b^ | Vehicle | 0.05 EE_2_ | 0.5 EE_2_
Exfoliated germ cells | Interim | Incidence | 1/22 (4%) | 4/26 (15%) | 2/26 (8%)
| | Severity Profile | 1\|0\|0\|0 (1.0) | 3\|1\|0\|0 (1.2) | 2\|0\|0\|0 (1.0)
| Terminal | Incidence | 10/49 (20%) | 6/26 (23%) | 4/26 (15%)
| | Severity Profile | 5\|3\|1\|1 (1.8) | 4\|1\|1\|0 (1.5) | 3\|1\|0\|0 (1.2)
| | Poly-3 Incidence | 10/36.5 (27%) | 6/18.3 (33%) | 4/20.4 (20%)
Infiltration, cellular, lymphocyte | Interim | Incidence | 0/22^#, ^^ (0%) | 1/26 (4%) | 3/26^#, ^^ (12%)
| | Severity Profile | –- | 1\|0\|0\|0 (1.0) | 3\|0\|0\|0 (1.0)
| Terminal | Incidence | 10/49^^^ (20%) | 5/26 (19%) | 10/26^^^ (38%)
| | Severity Profile | 8\|2\|0\|0 (1.2) | 4\|1\|0\|0 (1.2) | 8\|2\|0\|0 (1.2)
| | Poly-3 Incidence | 10/35.5 (28%) | 5/18.3 (27%) | 10/20.4 (49%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 88.

Table 90 Non-Neoplastic Lesions in the Epididymis of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Exfoliated germ cells | Interim | Incidence | 0/20 (0%) | 3/20^^^ (15%) | 1/20 (5%) | 2/19 (10%) | 1/20 (5%) | 1/22 (4%)
| | Severity Profile | – | 1\|2\|0\|0 (1.7) | 0\|1\|0\|0 (2.0) | 2\|0\|0\|0 (1.0) | 0\|1\|0\|0 (2.0) | 1\|0\|0\|0 (1.0)
| Terminal | Incidence | 12/49 (24%) | 15/48 (31%) | 11/48 (23%) | 13/50 (26%) | 17/50 (34%) | 9/46 (20%)
| | Severity Profile | 3\|6\|3\|0 (2.0) | 5\|7\|3\|0 (1.9) | 3\|7\|1\|0 (1.8) | 3\|9\|1\|0 (1.8) | 5\|5\|6\|1 (2.2) | 4\|4\|1\|0 (1.7)
| | Poly-3 Incidence | 12/39.0 (31%) | 15/38.3 (39%) | 11/37.9 (29%) | 13/36.1 (36%) | 17/39.8 ^b^ (43%) | 9/29.5 (30%)
Infiltration, cellular, lymphocyte | Interim | Incidence | 1/20 (5%) | 1/20 (5%) | 4/20 (20%) | 1/19 (5%) | 2/20 (10%) | 2/22 (9%)
| | Severity Profile | 1\|0\|0\|0 (1.0) | 1\|0\|0\|0 (1.0) | 4\|0\|0\|0 (1.0) | 1\|0\|0\|0 (1.0) | 2\|0\|0\|0 (1.0) | 2\|0\|0\|0 (1.0)
| Terminal | Incidence | 14/49 (29%) | 16/48 (33%) | 16/48 (33%) | 14/50 (28%) | 12/50 (24%) | 13/46 (28%)
| | Severity Profile | 9\|5\|0\|0 (1.4) | 13\|3\|0\|0 (1.2) | 14\|2\|0\|0 (1.1) | 11\|3\|0\|0 (1.2) | 10\|2\|0\|0 (1.2) | 12\|1\|0\|0 (1.1)
| | Poly-3 Incidence | 14/40.2 (35%) | 16/36.8 (44%) | 16/38.3 (42%) | 14/35.3 (40%) | 12/39.9 (30%) | 13/29.6 (44%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a statistically significant (p = 0.046) difference in the pairwise comparison between the 2,500 μg BPA/kg bw/day dose group and the vehicle control (exfoliated germ cells, Poly-3 incidences 16/32.4 (49%) versus 7/27.3 (26%)).

In the continuous-dose BPA interim sacrifice males, there were significant trends (all statistical tests applied) for exfoliated germ cells and lymphocyte infiltration (Table 88). With both lesions, the incidence in the 25,000 μg BPA/kg bw/day dose group was significantly higher than that in the vehicle control group (all statistical tests applied; 27% versus 4% for exfoliated germ cells, 23% versus 0% for lymphocyte infiltration). There were no significant BPA treatment effects in the terminal sacrifice males in the continuous BPA dose groups.

In males dosed continuously with EE_2_, there were increased trends for lymphocyte infiltration in interim (JT/SW and RTE tests) and terminal (RTE test only) sacrifice animals and significant pairwise comparisons for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (12% versus 0% for interim animals, 38% versus 20% for terminal animals) (Table 89).

The sole statistically significant effect in the stop BPA dose males was an increase in exfoliated germ cells in the 2.5 μg BPA/kg bw/day dose group (RTE test only; 15% versus 0%) (Table 90).

#### Dorsal/Lateral and ventral prostate, neoplastic and non-neoplastic lesions

Non-neoplastic lesions in the dorsal/lateral prostates of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 91, Table 92, and Table 93, respectively.

Table 91 Non-Neoplastic Lesions in the Dorsal/Lateral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, cellular, lymphocyte | Interim | Incidence | 4/22 (18%) | 10/22^^ b^ (46%) | 5/20 (25%) | 6/24 (25%) | 5/20 (25%) | 7/22 (32%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 9\|1\|0\|0 (1.1) | 5\|0\|0\|0 (1.0) | 5\|1\|0\|0 (1.2) | 5\|0\|0\|0 (1.0) | 5\|2\|0\|0 (1.3)
| Terminal | Incidence | 33/50 (66%) | 26/48 (54%) | 27/48 (56%) | 27/50 (54%) | 27/50 (54%) | 20/46 (44%)
| | Severity Profile | 19\|11\|2\|1 (1.5) | 18\|7\|1\|0 (1.3) | 21\|5\|1\|0 (1.3) | 16\|6\|3\|2 (1.7) | 18\|8\|0\|1 (1.4) | 10\|7\|1\|2 (1.8)
| | Poly-3 Incidence | 33/40.4^* N^ (82%) | 26/38.2 (68%) | 27/38.7 (70%) | 27/39.6 (68%) | 27/38.7 (70%) | 20/33.0 (61%)
Suppurative inflammation | Interim | Incidence | 18/22 (82%) | 20/22^^^ (91%) | 18/20 (90%) | 22/24^^^ (92%) | 18/20^#, ^^ (90%) | 19/22^#^ (86%)
| | Severity Profile | 11\|7\|0\|0 (1.4) | 6\|14\|0\|0 (1.7) | 9\|9\|0\|0 (1.5) | 9\|12\|1\|0 (1.6) | 6\|10\|2\|0 (1.8) | 7\|11\|1\|0 (1.7)
| Terminal | Incidence | 41/50 (82%) | 46/48 (96%) | 47/48 (98%) | 45/50 (90%) | 43/50 (86%) | 41/46 (89%)
| | Severity Profile | 8\|26\|4\|3 (2.0) | 10\|26\|9\|1 (2.0) | 9\|30\|8\|0 (2.0) | 17\|24\|2\|2 (1.8) | 8\|28\|6\|1 (2.0) | 12\|20\|6\|3 (2.0)
| | Poly-3 Incidence | 41/45.6 (90%) | 46/46.2* (100%) | 47/48.0 (98%) | 45/47.7 (94%) | 43/46.5 (92%) | 41/43.3 (95%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), the lymphocyte cellular infiltration in the 2.5 BPA dose group was also significant in the CAFE analysis (lymphocyte cellular infiltration, 9/16 (56%), in treated group versus 3/17 (18%), in controls, p = 0.025).

Table 92 Non-Neoplastic Lesions in the Dorsal/Lateral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Infiltration, cellular, lymphocyte | Interim | Incidence | 4/22 (18%) | 9/26 (35%) | 4/26 (15%)
| | Severity Profile | 4\|0\|0\|0 (1.0) | 9\|0\|0\|0 (1.0) | 4\|0\|0\|0 (1.0)
| Terminal | Incidence | 33/50 (66%) | 17/26 (65%) | 13/25 (52%)
| | Severity Profile | 19\|11\|2\|1 (1.5) | 10\|6\|1\|0 (1.5) | 6\|6\|0\|1 (1.7)
| | Poly-3 Incidence | 33/40.4 (82%) | 17/21.3 (80%) | 13/20.1 (65%)
Suppurative inflammation | Interim | Incidence | 18/22 (82%) | 25/26 (96%) | 25/26 (96%)
| | Severity Profile | 11\|7\|0\|0 (1.4) | 13\|11\|0\|1 (1.6) | 12\|13\|0\|0 (1.5)
| Terminal | Incidence | 41/50 (82%) | 26/26 (100%) | 22/25 (88%)
| | Severity Profile | 8\|26\|4\|3 (2.0) | 8\|16\|1\|1 (1.8) | 6\|12\|3\|1 (2.0)
| | Poly-3 Incidence | 41/45.6 (90%) | 26/26.0 (100%) | 22/23.1 (95%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 91.

Table 93 Non-Neoplastic Lesions in the Dorsal/Lateral Prostate of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, cellular, lymphocyte | Interim | Incidence | 9/20 (45%) | 5/20 (25%) | 4/20 (20%) | 8/18 (44%) | 8/20 (40%) | 6/22 (27%)
| | Severity Profile | 9\|0\|0\|0 (1.0) | 4\|1\|0\|0 (1.2) | 3\|1\|0\|0 (1.2) | 8\|0\|0\|0 (1.0) | 5\|3\|0\|0 (1.4) | 6\|0\|0\|0 (1.0)
| Terminal | Incidence | 31/46 (67%) | 30/48 (62%) | 28/48 (58%) | 27/50 (54%) | 35/49 (71%) | 22/45^#, ^ N^ (49%)
| | Severity Profile | 17\|11\|1\|2 (1.6) | 20\|6\|1\|3 (1.6) | 15\|9\|2\|2 (1.7) | 16\|8\|1\|2 (1.6) | 20\|14\|1\|0 (1.5) | 14\|7\|0\|1 (1.5)
| | Poly-3 Incidence | 31/41.6 (75%) | 30/41.1 (73%) | 28/40.0 (70%) | 27/38.9 (69%) | 35/42.4 (83%) | 22/33.2 (66%)
Suppurative inflammation | Interim | Incidence | 18/20 (90%) | 19/20 (95%) | 16/20 (80%) | 16/18 (89%) | 19/20 (95%) | 18/22 (82%)
| | Severity Profile | 5\|13\|0\|0 (1.7) | 12\|7\|0\|0 (1.4) | 6\|10\|0\|0 (1.6) | 7\|9\|0\|0 (1.6) | 9\|10\|0\|0 (1.5) | 5\|12\|1\|0 (1.8)
| Terminal | Incidence | 39/46 (85%) | 46/48 (96%) | 41/48 (85%) | 42/50 (84%) | 44/49 (90%) | 38/45 (84%)
| | Severity Profile | 7\|22\|7\|3 (2.2) | 14\|21\|8\|3 (2.0) | 14\|20\|5\|2 (1.9) | 10\|20\|9\|3 (2.1) | 12\|21\|11\|0 (2.0) | 6\|25\|6\|1 (2.1)
| | Poly-3 Incidence | 39/43.3 (90%) | 46/46.7 (98%) | 41/45.4 (90%) | 42/45.2 (93%) | 44/46.3 (95%) | 38/41.2 (92%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

There were statistically significant increased incidences relative to vehicle controls of lymphocyte infiltration and suppurative inflammation in continuous-dose BPA groups, primarily in the interim sacrifice males (Table 91). Lymphocyte infiltration was increased (RTE test only) in the 2.5 μg BPA/kg bw/day dose group (46% versus 18%). The incidence of suppurative inflammation was increased (RTE and/or JT/SW tests) over a high background (82% in vehicle control) in the 2.5, 250, 2,500, and 25,000 μg BPA/kg bw/day dose groups (91%, 92%, 90%, and 86%, respectively) in interim sacrifice continuous-dose males (Table 91). The incidence of suppurative inflammation was increased (Poly-3 test) in the 2.5 μg BPA/kg bw/day dose group in terminal sacrifice animals (96% versus 82%; Table 91).

There were no statistically significant differences in lesion incidences in continuous-dose EE_2_ (Table 92) or stop-dose BPA (Table 93) groups relative to their respective vehicle control group.

The incidences of ventral prostate adenomas in terminal sacrifice males were discussed in the narrative pathology report (Supplemental Appendix XXXII) and are shown for continuous BPA and EE_2_ and stop-dose BPA in Table 94, Table 95, and Table 96, respectively. The continuous- and stop-dose vehicle control incidences were 12% and 8%, respectively, and there were no treatment-related differences in any exposure group relative to vehicle controls. Regarding non-neoplastic lesions in the ventral prostate, lower incidences of suppurative inflammation were seen in some treatment groups in continuous BPA (Table 97) or EE_2_ (Table 98), but not stop-dose BPA (Table 99), relative to the vehicle control group.

Table 94 Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenoma | Terminal | Incidence | 6/50 (12%) | 7/48 (15%) | 2/48 (4%) | 4/49 (8%) | 2/49 (4%) | 6/46 (13%)
| | Poly-3 Incidence | 6/34.4 (17%) | 7/34.4 (20%) | 2/32.3 (6%) | 4/32.9 (12%) | 2/33.1 (6%) | 6/29.4 (20%)
| | Terminal Incidence | 3/15 (20%) | 4/16 (25%) | 2/17 (12%) | 2/14 (14%) | 2/16 (12%) | 3/11 (27%)
| | Time-to-First | 603 | 683 | 726 (T) | 713 | 726 (T) | 613
| | Poly-3 p-value | 0.287N | 0.499 | 0.148N | 0.394N | 0.139N | 0.506
| | Multiple Incidence^d^ | 0/50 (0%) | 2/48 (4%) | 0/48 (0%) | 0/49 (0%) | 0/49 (0%) | 3/46 (7%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation.

Table 95 Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.50 EE_2_
Adenoma | Terminal | Incidence | 6/50 (12%) | 2/26 (8%) | 2/26 (8%)
| | Poly-3 Incidence | 6/34.4 (17%) | 2/17.6 (11%) | 2/20.7 (10%)
| | Terminal Incidence | 3/15 (20%) | 2/9 (22%) | 0/12 (0%)
| | Time-to-First | 603 | 725 (T) | 462
| | Poly-3 p-value | 0.287N | 0.433N | 0.344N
| | Multiple Incidence^d^ | 0/50 (0%) | 1/26 (4%) | 0/26 (0%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 52 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 94.

Table 96 Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Adenoma | Terminal | Incidence | 4/48 (8%) | 4/47 (8%) | 4/47 (8%) | 2/50 (4%) | 4/49 (8%) | 6/45 (13%)
| | Poly-3 Incidence | 4/35.7 (11%) | 4/33.0 (12%) | 4/34.1 (12%) | 2/30.8 (6%) | 4/36.5 (11%) | 6/28.7 (21%)
| | Terminal Incidence | 2/17 (12%) | 2/16 (12%) | 4/16 (25%) | 2/13 (15%) | 1/15 (7%) | 1/9 (11%)
| | Time-to-First | 675 | 679 | 724 (T) | 724 (T) | 593 | 530
| | Poly-3 p-value | 0.273 | 0.601 | 0.619 | 0.407N | 0.635N | 0.233
| | Multiple Incidence^d^ | 1/48 (2%) | 2/47 (4%) | 1/47 (2%) | 1/50 (2%) | 2/49 (4%) | 2/45 (4%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 52 for description of data presentation.

Table 97 Non-Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, cellular, lymphocyte | Interim | Incidence | 8/22 (36%) | 10/22 (45%) | 10/20 (50%) | 8/24 (33%) | 9/20 (45%) | 8/22 (36%)
| | Severity Profile | 8\|0\|0\|0 | 8\|2\|0\|0 | 9\|1\|0\|0 | 7\|1\|0\|0 | 8\|1\|0\|0 | 7\|1\|0\|0
| Terminal | Incidence | 25/50 (50%) | 14/48^##, ^^ N^ (29%) | 15/48^##, ^^ N^ (31%) | 15/49^##, ^ N^ (31%) | 20/49^# N^ (41%) | 15/46^#, ^ N^ (33%)
| | Severity Profile | 12\|5\|5\|3 | 9\|4\|1\|0 | 14\|1\|0\|0 | 9\|4\|0\|2 | 15\|3\|1\|1 | 9\|3\|1\|2
| | Poly-3 Incidence | 25/40.8 (61%) | 14/38.2^* N^ (37%) | 15/39.1^* N^ (38%) | 15/39.4^* N^ (38%) | 20/39.0 (51%) | 15/33.3 (45%)
Suppurative inflammation | Interim | Incidence | 10/22^**, ##, ^^ N^ (45%) | 3/22^*, #, ^^ N^ (14%) | 4/20^#, ^ N^ (20%) | 5/24^#, ^ N^ (21%) | 3/20^*, #, ^^ N^ (15%) | 1/22^**, ###, ^^^ N^ (5%)
| | Severity Profile | 9\|1\|0\|0 | 3\|0\|0\|0 | 2\|2\|0\|0 | 4\|1\|0\|0 | 3\|0\|0\|0 | 1\|0\|0\|0
| Terminal | Incidence | 16/50 (32%) | 5/48^##, ^^ N^ (10%) | 5/48^##, ^^ N^ (10%) | 6/49^##, ^^ N^ (12%) | 5/49^##, ^^ N^ (10%) | 11/46^## N^ (24%)
| | Severity Profile | 7\|2\|2\|5 | 3\|2\|0\|0 | 3\|2\|0\|0 | 3\|1\|0\|2 | 1\|2\|1\|1 | 5\|2\|1\|3
| | Poly-3 Incidence | 16/38.1 (42%) | 5/34.6^** N^ (14%) | 5/34.6^** N^ (14%) | 6/35.3^* N^ (17%) | 5/34.9^** N^ (14%) | 11/31.9 (34%)
Hyperplasia, epithelium | Interim | Incidence | 0/22 | 0/22 | 0/20 | 1/24 | 0/20 | 0/22
| | Severity Profile | – | – | – | 0/1/0/0 | – | –
| Terminal | Incidence | 10/50 (20%) | 12/48 (25%) | 10/48 (21%) | 18/49^^^ (37%) | 12/49 (24%) | 8/46 (17%)
| | Severity Profile | 1\|6\|3\|0 | 2\|6\|3\|1 | 2\|4\|4\|0 | 1\|13\|3\|1 | 3\|6\|3\|0 | 2\|2\|2\|2
| | Poly-3 Incidence | 10/34.0 (29%) | 12/36.4 (33%) | 10/35.0 (28%) | 18/36.3 (50%) | 12/34.7 (35%) | 8/30.5 (26%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 98 Non-Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Infiltration, cellular, lymphocyte | Interim | Incidence | 8/22 (36%) | 13/26 (50%) | 13/26 (50%)
| | Severity Profile | 8\|0\|0\|0 | 11\|2\|0\|0 | 12\|1\|0\|0
| Terminal | Incidence | 25/50 (50%) | 6/26^^^ N^ (23%) | 14/26 (54%)
| | Severity Profile | 12\|5\|5\|3 | 5\|0\|1\|0 | 6\|7\|0\|1
| | Poly-3 Incidence | 25/40.8 (61%) | 6/19.2^* N^ (31%) | 14/22.3 (63%)
Suppurative inflammation | Interim | Incidence | 10/22^*, #, ^ N^ (45%) | 4/26^*, #, ^ N^ (15%) | 5/26^#, ^ N^ (19%)
| | Severity Profile | 9\|1\|0\|0 | 3\|1\|0\|0 | 5\|0\|0\|0
| Terminal | Incidence | 16/50 (32%) | 4/26^^ N^ (15%) | 8/26 (31%)
| | Severity Profile | 7\|2\|2\|5 | 3\|0\|0\|1 | 5\|2\|0\|1
| | Poly-3 Incidence | 16/38.1 (42%) | 4/18.7 (21%) | 8/22.2 (36%)
Hyperplasia, epithelium | Interim | Incidence | 0/22 (0%) | 0/26 (0%) | 0/26 (0%)
| | Severity Profile | – | – | –
| Terminal | Incidence | 10/50 (20%) | 4/26 (15%) | 7/26 (27%)
| | Severity Profile | 1\|6\|3\|0 | 0\|1\|2\|1 | 1\|4\|2\|0
| | Poly-3 Incidence | 10/34.0 (29%) | 4/17.6 (23%) | 7/19.9 (35%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 97.

Table 99 Non-Neoplastic Lesions in the Ventral Prostate of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Infiltration, cellular, lymphocyte | Interim | Incidence | 9/20 (45%) | 8/20 (40%) | 9/20 (45%) | 9/18 (50%) | 8/20 (40%) | 9/22 (41%)
| | Severity Profile | 8\|1\|0\|0 | 7\|1\|0\|0 | 8\|1\|0\|0 | 8\|1\|0\|0 | 7\|1\|0\|0 | 9\|0\|0\|0
| Terminal | Incidence | 19/48 (40%) | 17/47 (36%) | 15/47 (32%) | 16/50 (32%) | 20/49 (41%) | 18/45 (40%)
| | Severity Profile | 9\|7\|2\|1 | 11\|3\|0\|3 | 10\|1\|0\|4 | 8\|5\|2\|1 | 14\|5\|1\|0 | 11\|3\|2\|2
| | Poly-3 Incidence | 19/39.2 (48%) | 17/37.7 (45%) | 15/38.4 (39%) | 16/34.5 (46%) | 20/40.9 (49%) | 18/33.2 (54%)
Suppurative inflammation | Interim | Incidence | 3/20 (15%) | 2/20 (10%) | 2/20 (10%) | 6/18 (33%) | 4/20 (20%) | 2/22 (9%)
| | Severity Profile | 2\|1\|0\|0 | 2\|0\|0\|0 | 2\|0\|0\|0 | 6\|0\|0\|0 | 4\|0\|0\|0 | 2\|0\|0\|0
| Terminal | Incidence | 10/48 (21%) | 9/47 (19%) | 9/47 (19%) | 8/50 (16%) | 10/49 (20%) | 9/45 (20%)
| | Severity Profile | 5\|2\|1\|2 | 5\|1\|1\|2 | 3\|2\|0\|4 | 4\|1\|1\|2 | 5\|4\|0\|1 | 4\|2\|2\|1
| | Poly-3 Incidence | 10/36.8 (27%) | 9/35.2 (26%) | 9/37.3 (24%) | 8/33.7 (24%) | 10/38.0 (26%) | 9/30.1 (30%)
Hyperplasia, epithelium | Interim | Incidence | 1/20 (5%) | 1/20 (5%) | 0/20 (0%) | 2/18 (11%) | 0/20 (0%) | 0/22 (0%)
| | Severity Profile | 0\|1\|0\|0 | 0\|1\|0\|0 | – | 2\|0\|0\|0 | – | –
| Terminal | Incidence | 17/48 (35%) | 7/47^## N^ (15%) | 17/47 (36%) | 16/50 (32%) | 14/49 (29%) | 13/45 (29%)
| | Severity Profile | 0\|12\|3\|2 | 2\|3\|1\|1 | 4\|8\|3\|2 | 4\|9\|1\|2 | 1\|13\|0\|0 | 1\|10\|0\|2
| | Poly-3 Incidence | 17/38.9 (44%) | 7/32.9^* N^ (21%) | 17/36.0 (47%) | 16/35.7 (45%) | 14/37.4 (37%) | 13/30.2 (43%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

#### Pituitary, non-neoplastic lesions

Non-neoplastic lesions in the pituitaries of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 100, Table 101, and Table 102, respectively.

Table 100 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, pars distalis | Interim | Incidence | 4/22 (18%) | 6/22 (27%) | 2/20 (10%) | 4/24 (17%) | 2/20 (10%) | 4/22 (18%)
| | Severity Profile | 3\|1\|0\|0 (1.2) | 6\|0\|0\|0 (1.0) | 1\|1\|0\|0 (1.5) | 2\|2\|0\|0 (1.5) | 2\|0\|0\|0 (1.0) | 2\|2\|0\|0 (1.5)
| Terminal | Incidence | 11/48^#, ^^ (23%) | 9/48 (19%) | 19/48^^^ (40%) | 15/50 (30%) | 17/50 (34%) | 19/45^#, ^^ (42%)
| | Severity Profile | 3\|4\|4\|0 (2.1) | 0\|4\|4\|1 (2.7) | 5\|8\|2\|4 (2.3) | 4\|6\|3\|2 (2.2) | 4\|7\|5\|1 (2.2) | 3\|9\|3\|4 (2.4)
| | Poly-3 Incidence | 11/36.2** (30%) | 9/36.3 (25%) | 19/37.8 (50%) | 15/37.8 (40%) | 17/38.5 (44%) | 19/34.2* (56%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 101 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a, b^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^c^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, pars distalis | Interim | Incidence | 4/22 (18%) | 7/26 (27%) | 2/26 (8%)
| | Severity Profile | 3\|1\|0\|0 (1.2) | 4\|2\|1\|0 (1.6) | 1\|1\|0\|0 (1.5)
| Terminal | Incidence | 11/48^#, ^^ (23%) | 10/26 (38%) | 13/26^#, ^^ (50%)
| | Severity Profile | 3\|4\|4\|0 (2.1) | 2\|4\|4\|0 (2.2) | 3\|7\|3\|0 (2.0)
| | Poly-3 Incidence | 11/36.2* (30%) | 10/21.2 (47%) | 13/22.6* (58%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant Poly-3 test (p = 0.042) for the pairwise comparison between the 0.05 μg EE_2_/kg bw/day dose group and the vehicle control group for angiectasis in the pituitary gland (Poly-3 incidences 5/14.2 (35%) versus 2/24.2 (8%); data not shown in Table). In the analysis that included all animals, the Poly-3 incidences were 7/19.1 (37%) in the EE_2_ group versus 6/33.5 (18%) in the vehicle control group.

^c^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 100

Table 102 Non-Neoplastic Lesions in the Pituitary of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a, b, c^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, pars distalis | Interim | Incidence | 8/20 (40%) | 9/20 (45%) | 3/20 (15%) | 4/19 (21%) | 4/20 (20%) | 7/22 (32%)
| | Severity Profile | 8\|0\|0\|0 (1.0) | 7\|1\|0\|1 (1.4) | 0\|3\|0\|0 (2.0) | 4\|0\|0\|0 (1.0) | 4\|0\|0\|0 (1.0) | 6\|1\|0\|0 (1.1)
| Terminal | Incidence | 12/46 (26%) | 16/48 (33%) | 18/48 (38%) | 15/49 (31%) | 19/50 (38%) | 19/43 (44%)
| | Severity Profile | 0\|6\|3\|3 (2.8) | 5\|4\|6\|1 (2.2) | 4\|8\|2\|4 (2.3) | 3\|6\|3\|3 (2.4) | 3\|9\|5\|2 (2.3) | 4\|8\|3\|4 (2.4)
| | Poly-3 Incidence | 12/37.2* (32%) | 16/38.2 (42%) | 18/40.8 (44%) | 15/37.3 (40%) | 19/38.9 (49%) | 19/32.7* (58%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant dose trend (p = 0.048) for pars distalis, cyst (not shown in Table). The p-value for the trend in the analysis including all animals was 0.056.

^c^ Also in the sensitivity analysis mentioned in footnote b, there was a statistically significant pairwise comparison (p = 0.041, Poly-3 test) between the 25,000 μg BPA/kg bw/day dose group and the vehicle control for hypertrophy of the pars distalis (Poly-3 incidences 4/21.7 (18%) versus 0/24.3). In the analysis that included all animals, the Poly-3 incidences were 4/28.5 (14%) versus 1/35.1 (3%), p = 0.118. This lesion is not shown in the Table.

There were no significant treatment effects in interim sacrifice animals in the continuous (Table 100) or stop-dose (Table 102) BPA arms or in the continuous EE_2_ treatments (Table 101).

In terminal sacrifice males treated continuously with BPA, there was a significant dose trend (all statistical tests applied) for hyperplasia in the pars distalis and a significant increase relative to vehicle controls in the 25 μg BPA/kg bw/day dose group (RTE test only, 40% versus 23%) and the 25,000 μg BPA/kg bw/day dose group (all statistical tests applied, incidence 42% versus 23%) (Table 100).

In males continuously dosed with EE_2_, there was an increased trend (all statistical tests applied) for pars distalis hyperplasia in terminal sacrifice animals and a significant pairwise comparison for the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (50% versus 23%) (Table 101).

In stop-dose BPA terminal sacrifice males, the Poly-3 test indicated a significant dose trend for pars distalis hyperplasia and a significant pairwise comparison between the 25,000 μg BPA/kg bw/day dose group and vehicle controls (incidences, 44% versus 26%) (Table 102).

#### Thyroid, non-neoplastic lesions

Non-neoplastic lesions in the thyroid glands of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 103, Table 104, and Table 105, respectively.

Table 103 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, C-cell | Interim | Incidence | 10/22 (46%) | 13/22 (59%) | 9/20 (45%) | 12/24 (50%) | 7/18 (39%) | 10/21 (48%)
| | Severity Profile | 3\|4\|3\|0 (2.0) | 7\|4\|2\|0 (1.6) | 6\|2\|1\|0 (1.4) | 5\|4\|3\|0 (1.8) | 2\|4\|0\|1 (2.0) | 6\|3\|1\|0 (1.5)
| Terminal | Incidence | 9/46 (20%) | 13/40 (32%) | 15/47 (32%) | 15/44 (34%) | 20/44^^^^ (46%) | 11/44 (25%)
| | Severity Profile | 5\|2\|2\|0 (1.7) | 5\|7\|1\|0 (1.7) | 8\|4\|2\|1 (1.7) | 8\|6\|1\|0 (1.5) | 10\|8\|2\|0 (1.6) | 3\|7\|1\|0 (1.8)
| | Poly-3 Incidence | 9/34.9* (26%) | 13/32.8 (40%) | 15/35.5 (42%) | 15/34.1 (44%) | 20/33.8** (59%) | 11/30.5 (36%)
Hyperplasia, follicular cell | Interim | Incidence | 1/22 (4%) | 1/22 (4%) | 2/20 (10%) | 2/24 (8%) | 2/18 (11%) | 1/21 (5%)
| | Severity profile | 0\|1\|0\|0 (2.0) | 0\|0\|1\|0 (3.0) | 1\|0\|1\|0 (2.0) | 0\|1\|1\|0 (2.5) | 0\|0\|2\|0 (3.0) | 0\|0\|1\|0 (3.0)
| Terminal | Incidence | 3/46 (6%) | 2/40 (5%) | 9/47^^^ (19%) | 6/44 (14%) | 3/44 (7%) | 3/44 (7%)
| | Severity Profile | 0\|2\|1\|0 (2.3) | 0\|1\|1\|0 (2.5) | 0\|3\|5\|1 (2.8) | 0\|4\|2\|0 (2.3) | 0\|1\|1\|1 (3.0) | 0\|1\|2\|0 (2.7)
| | Poly-3 Incidence | 3/32.5 (9%) | 2/31.2 (6%) | 9/35.1 (26%) | 6/32.0 (19%) | 3/31.5 (10%) | 3/28.6 (10%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 104 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, C-cell | Interim | Incidence | 10/22 (46%) | 7/25 (28%) | 9/24 (38%)
| | Severity Profile | 3\|4\|3\|0 (2.0) | 4\|2\|1\|0 (1.6) | 4\|5\|0\|0 (1.6)
| Terminal | Incidence | 9/46 (20%) | 12/25^^^^ (48%) | 7/25 (28%)
| | Severity Profile | 5\|2\|2\|0 (1.7) | 4\|8\|0\|0 (1.7) | 5\|1\|1\|0 (1.4)
| | Poly-3 Incidence | 9/34.9 (26%) | 12/20.3** (59%) | 7/20.2 (35%)
Hyperplasia, follicular cell | Interim | Incidence | 1/22 (4%) | 4/25 (16%) | 2/24 (8%)
| | Severity Profile | 0\|1\|0\|0 (2.0) | 0\|0\|4\|0 (3.0) | 0\|0\|2\|0 (3.0)
| Terminal | Incidence | 3/46 (6%) | 2/25 (8%) | 3/25 (12%)
| | Severity Profile | 0\|2\|1\|0 (2.3) | 0\|1\|0\|1 (3.0) | 0\|1\|2\|0 (2.7)
| | Poly-3 Incidence | 3/32.5 (9%) | 2/17.7 (11%) | 3/19.9 (15%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 103.

Table 105 Non-Neoplastic Lesions in the Thyroid of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, C-cell | Interim | Incidence | 13/20 (65%) | 9/20 (45%) | 10/20 (50%) | 11/19 (58%) | 10/20 (50%) | 12/22 (54%)
| | Severity Profile | 5\|7\|1\|0 (1.7) | 1\|4\|4\|0 (2.3) | 6\|2\|2\|0 (1.6) | 3\|7\|1\|0 (1.8) | 7\|2\|1\|0 (1.4) | 5\|5\|2\|0 (1.8)
| Terminal | Incidence | 12/43 (28%) | 18/45 (40%) | 11/44 (25%) | 19/45 (42%) | 18/48 (38%) | 13/42 (31%)
| | Severity Profile | 4\|7\|1\|0 (1.8) | 10\|6\|2\|0 (1.6) | 4\|5\|1\|1 (1.9) | 11\|6\|2\|0 (1.4) | 10\|7\|1\|0 (1.5) | 5\|6\|1\|1 (1.8)
| | Poly-3 Incidence | 12/36.4 (33%) | 18/35.2 (51%) | 11/33.8 (33%) | 19/35.2 (54%) | 18/39.3 (46%) | 13/31.0 (42%)
Hyperplasia, follicular cell | Interim | Incidence | 1/20 (5%) | 1/20 (5%) | 4/20 (20%) | 1/19 (5%) | 0/20 (0%) | 3/22 (14%)
| | Severity Profile | 0\|0\|1\|0 (3.0) | 0\|0\|1\|0 (3.0) | 0\|1\|3\|0 (2.8) | 0\|0\|1\|0 (3.0) | - | 0\|0\|3\|0 (3.0)
| Terminal | Incidence | 6/43 (14%) | 6/45 (13%) | 9/44 (20%) | 10/45 (22%) | 6/48 (12%) | 7/42 (17%)
| | Severity Profile | 0\|3\|3\|0 (2.5) | 0\|2\|4\|0 (2.7) | 0\|2\|6\|1 (2.9) | 0\|3\|7\|0 (2.7) | 0\|3\|3\|0 (2.5) | 0\|3\|4\|0 (2.6)
| | Poly-3 Incidence | 6/34.7 (17%) | 6/34.0 (18%) | 9/35.5 (25%) | 10/32.3 (31%) | 6/36.6 (16%) | 7/28.9 (24%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

There were no statistically significant treatment effects in the thyroid gland of continuous-dose interim sacrifice males (Table 103). In terminal sacrifice males continuously dosed with BPA, there was a significant dose trend (Poly-3 test), and the 2,500 μg BPA/kg bw/day dose group had a higher hyperplasia incidence than vehicle controls (Poly-3 and RTE tests, 46% versus 20%). Follicular cell hyperplasia was increased at 25 μg BPA/kg bw/day relative to the vehicle control group (19% versus 6%, RTE test only).

In males continuously dosed with EE_2_, the incidence of C-cell hyperplasia was significantly higher in the 0.05 μg EE_2_/kg bw/day dose group relative to vehicle control (Poly-3 and RTE tests, 48% versus 20%) (Table 104).

There were no statistically significant effects in the thyroid of stop-dose BPA interim or terminal sacrifice males (Table 105).

#### Parathyroid, non-neoplastic lesions

Non-neoplastic lesions in the parathyroid glands of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 106, Table 107, and Table 108, respectively.

Table 106 Non-Neoplastic Lesions in the Parathyroid Gland of Interim and Terminal Sacrifice Male Rats: Continuous BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia | Interim | Incidence | 7/22^*, #, ^ N^ (32%) | 5/21 (24%) | 7/19 (37%) | 5/24 (21%) | 2/19 (10%) | 2/21^^ N^ (10%)
| | Severity Profile | 3\|4\|0\|0 (1.6) | 2\|3\|0\|0 (1.6) | 3\|3\|1\|0 (1.7) | 1\|4\|0\|0 (1.8) | 0\|2\|0\|0 (2.0) | 1\|1\|0\|0 (1.5)
| Terminal | Incidence | 11/49 (22%) | 11/46 (24%) | 23/47^^^^^ (49%) | 18/50^^^ (36%) | 18/50 (36%) | 12/46 (26%)
| | Severity Profile | 3\|7\|0\|1 (1.9) | 7\|3\|0\|1 (1.5) | 1\|13\|6\|3 (2.5) | 2\|9\|3\|4 (2.5) | 9\|5\|2\|2 (1.8) | 4\|5\|3\|0 (1.9)
| | Poly-3 Incidence | 11/36.7 (30%) | 11/33.9 (32%) | 23/37.5** (61%) | 18/38.4 (47%) | 18/39.0 (46%) | 12/32.3 (37%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 107 Non-Neoplastic Lesions in the Parathyroid Gland of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia | Interim | Incidence | 7/22 (32%) | 6/26 (23%) | 4/26 (15%)
| | Severity Profile | 3\|4\|0\|0 (1.6) | 0\|6\|0\|0 (2.0) | 1\|2\|1\|0 (2.0)
| Terminal | Incidence | 11/49^#, ^^ (22%) | 7/25 (28%) | 11/25^#, ^^ (44%)
| | Severity Profile | 3\|7\|0\|1 (1.9) | 2\|3\|1\|1 (2.1) | 3\|5\|1\|2 (1.8)
| | Poly-3 Incidence | 11/36.7^c^ (30%) | 7/18.2 (38%) | 11/20.9 (53%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 106.

^c^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Statistical Methods), there was a significant EE_2_ dose trend (p = 0.046). The p-value for the trend in the analysis that included all animals was 0.051.

Table 108 Non-Neoplastic Lesions in the Parathyroid Gland of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia | Interim | Incidence | 4/20 (20%) | 9/20 (45%) | 3/19 (16%) | 7/19 (37%) | 4/19 (21%) | 8/22 (36%)
| | Severity Profile | 1\|2\|1\|0 (2.0) | 7\|1\|1\|0 (1.7) | 1\|2\|0\|0 (1.7) | 5\|2\|0\|0 (1.3) | 4\|0\|0\|0 (1.0) | 1\|6\|1\|0 (2.0)
| Terminal | Incidence | 22/49 (45%) | 17/46 (37%) | 27/46 (59%) | 23/49 (47%) | 30/50 (60%) | 23/43 (54%)
| | Severity Profile | 1\|8\|7\|6 (2.8) | 2\|10\|0\|5 (2.5) | 4\|15\|5\|3 (2.3) | 8\|8\|5\|2 (2.0) | 3\|12\|6\|9 (2.7) | 7\|7\|5\|4 (2.3)
| | Poly-3 Incidence | 22/41.9* (52%) | 17/36.6 (46%) | 27/39.4 (69%) | 23/38.0 (60%) | 30/44.1 (68%) | 23/34.1 (67%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Statistically significant treatment effects were seen in the terminal sacrifice animals, but not in the interim sacrifice animals. In the males dosed continuously with BPA, the incidence of hyperplasia in the parathyroid gland was increased at 25 μg BPA/kg bw/day (Poly-3 and RTE tests, 49% versus 22%) and at 250 μg BPA/kg bw/day (RTE test only, 36% versus 22%) (Table 106).

In males continuously dosed with EE_2_, there was a significant dose trend (JT/SW and RTE tests) in parathyroid gland hyperplasia, and the incidence in the 0.5 μg EE_2_/kg bw/day dose group was significantly higher than in the vehicle control group (44% versus 22%) (Table 107).

In terminal sacrifice BPA stop-dose males, there was a significant dose trend (Poly-3 test) in the incidence of parathyroid gland hyperplasia (Table 108).

#### Kidney, non-neoplastic lesions

Non-neoplastic lesions in the kidneys of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 109, Table 110, and Table 111, respectively.

Table 109 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, transitional epithelium | Terminal | Incidence | 3/50 (6%) | 4/48 (8%) | 12/48^^^^ (25%) | 7/50 (14%) | 5/50 (10%) | 4/45 (9%)
| | Severity Profile | 1\|1\|1\|0 (2.0) | 1\|3\|0\|0 (1.8) | 5\|6\|1\|0 (1.7) | 5\|1\|0\|1 (1.6) | 2\|2\|1\|0 (1.8) | 1\|1\|1\|1 (2.5)
| | Poly-3 Incidence | 3/34.6 (9%) | 4/34.5 (12%) | 12/34.1** (35%) | 7/34.8 (20%) | 5/34.1 (15%) | 4/28.9 (14%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Table 110 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Hyperplasia, transitional epithelium | Terminal | Incidence | 3/50 (6%) | 2/26 (8%) | 1/26 (4%)
| | Severity Profile | 1\|1\|1\|0 (2.0) | 1\|1\|0\|0 (1.5) | 0\|0\|1\|0 (3.0)
| | Poly-3 Incidence | 3/34.6 (9%) | 2/17.8 (11%) | 1/19.7 (5%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 109.

Table 111 Non-Neoplastic Lesions in the Kidney of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Hyperplasia, transitional epithelium | Terminal | Incidence | 12/50 (24%) | 9/48 (19%) | 12/48 (25%) | 12/50 (24%) | 20/50 (40%) | 10/45 (22%)
| | Severity Profile | 3\|8\|0\|1 (1.9) | 4\|2\|3\|0 (1.9) | 5\|5\|1\|1 (1.8) | 4\|7\|0\|1 (1.8) | 8\|11\|1\|0 (1.6) | 3\|5\|2\|0 (1.9)
| | Poly-3 Incidence | 12/40.0* (30%) | 9/36.7 (24%) | 12/37.2 (32%) | 12/34.9 (34%) | 20/40.6 (49%) | 10/29.4 (34%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

Hyperplasia of the transitional epithelium of the kidney was significantly increased in terminal sacrifice males relative to vehicle controls in the 25 μg BPA/kg bw/day dose group of the continuous BPA dose arm (Poly-3 and RTE tests, 25% versus 6%) (Table 109).

In males continuously dosed with EE_2_, there were no observed statistically significant effects in the kidney (Table 110).

In the BPA stop-dose males in the terminal sacrifice arm, there was a significant dose trend for hyperplasia of the transitional epithelium of the kidney (Poly-3 test) (Table 111). The only dose group that had an apparent, although not statistically significant, increased incidence relative to controls was the 2,500 μg BPA/kg bw/day dose group (40% versus 24%).

#### Liver, non-neoplastic lesions

Non-neoplastic lesions in the livers of interim and terminal sacrifice males for continuous BPA and EE_2_ and stop-dose BPA are shown in Table 112, Table 113, and Table 114, respectively.

Table 112 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Male Rats: Continuous-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Fatty change | Interim | Incidence | 0/22 (0%) | 0/22 (0%) | 2/20^^^ (10%) | 0/24 (0%) | 0/19 (0%) | 0/22 (0%)
| | Severity Profile | – | – | 0\|2\|0\|0 (2.0) | – | – | –
| Terminal | Incidence | 4/50 (8%) | 8/47 (17%) | 5/48 (10%) | 5/50 (10%) | 4/50 (8%) | 2/45 (4%)
| | Severity Profile | 0\|1\|1\|2 (3.3) | 1\|3\|1\|3 (2.8) | 2\|1\|1\|1 (2.2) | 0\|4\|0\|1 (2.4) | 0\|3\|1\|0 (2.2) | 0\|1\|0\|1 (3.0)
| | Poly-3 incidence | 4/35.1 (11%) | 8/36.5 (22%) | 5/33.2 (15%) | 5/35.4 (14%) | 4/34.4 (12%) | 2/29.1 (7%)
Hepatodiaphragmatic Nodule | Interim | Incidence | 0/22 (0%) | 2/22 (9%) | 2/20 (10%) | 3/24 (12%) | 4/19* (21%) | 1/22 (4%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 6/50 (12.0%) | 2/47 (4%) | 4/48 (8%) | 3/50 (6%) | 7/50 (14%) | 5/45 (11%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 incidence | 6/34.6 (17.3%) | 2/34.2 (6%) | 4/32.8 (12%) | 3/34.6 (9%) | 7/35.4 (20%) | 5/30.9 (16%)
Infiltration, cellular, mononuclear cells | Interim | Incidence | 5/22 (23%) | 11/22^^^ (50%) | 9/20 (45%) | 13/24^*, #, ^^ (54%) | 11/19^*, #, ^^ (58%) | 8/22^#^ (36%)
| | Severity Profile | 5\|0\|0\|0 (1.0) | 11\|0\|0\|0 (1.0) | 9\|0\|0\|0 (1.0) | 12\|1\|0\|0 (1.1) | 11\|0\|0\|0 (1.0) | 8\|0\|0\|0 (1.0)
| Terminal | Incidence | 35/50 (70%) | 29/47 (62%) | 37/48 (77%) | 36/50 (72%) | 34/50 (68%) | 28/45 (62%)
| | Severity Profile | 21\|14\|0\|0 (1.4) | 16\|13\|0\|0 (1.4) | 22\|15\|0\|0 (1.4) | 26\|10\|0\|0 (1.3) | 21\|13\|0\|0 (1.4) | 19\|9\|0\|0 (1.3)
| | Poly-3 incidence | 35/42.3 (83%) | 29/40.1 (72%) | 37/42.6 (87%) | 36/42.3 (85%) | 34/40.5 (84%) | 28/35.4 (79%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion.

Table 113 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Male Rats: Continuous-Dose EE_2_^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle^b^ | 0.05 EE_2_ | 0.5 EE_2_
Fatty change | Interim | Incidence | 0/22^*, #, ^^ (0%) | 1/26 (4%) | 4/26^#, ^^ (15%)
| | Severity Profile | – | 0\|0\|1\|0 (3.0) | 0\|1\|3\|0 (2.8)
| Terminal | Incidence | 4/50 (8.0%) | 0/26 (0.0%) | 1/25 (4.0%)
| | Severity Profile | 0\|1\|1\|2 (3.2) | – | 0\|0\|0\|1 (4.0)
| | Poly-3 Incidence | 4/35.1 (11%) | 0/17.6 (0%) | 1/19.9 (5%)
Hepatodiaphragmatic Nodule | Interim | Incidence | 0/22 (0%) | 4/26 (15%) | 4/26 (15%)
| | Severity Profile | –^c^ | – | –
| Terminal | Incidence | 6/50 (12%) | 3/26 (12%) | 1/25 (4%)
| | Severity Profile | –^c^ | – | –
| | Poly-3 Incidence | 6/34.6 (17%) | 3/17.8 (17%) | 1/19.5 (5%)
Infiltration, cellular, mononuclear cells | Interim | Incidence | 5/22 (23%) | 13/26 (50%) | 5/26 (19%)
| | Severity Profile | 5\|0\|0\|0 (1.0) | 13\|0\|0\|0 (1.0) | 5\|0\|0\|0 (1.0)
| Terminal | Incidence | 35/50 (70%) | 22/26 (85%) | 20/25 (80%)
| | Severity Profile | 21\|14\|0\|0 (1.4) | 16\|6\|0\|0 (1.3) | 12\|8\|0\|0 (1.4)
| | Poly-3 Incidence | 35/42.3 (83%) | 22/23.5* (94%) | 20/23.1 (87%)

^a^ EE_2_ doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ The continuous vehicle control group data are the same as those shown for the continuous-dose BPA data in Table 112.

^c^ Severity scores were not assigned for this lesion.

Table 114 Non-Neoplastic Lesions in the Liver of Interim and Terminal Sacrifice Male Rats: Stop-Dose BPA^a^

Lesion | Study Phase (Interim/Terminal) | Statistic | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
Fatty change | Interim | Incidence | 0/20 (0%) | 1/20 (5%) | 1/20 (5%) | 0/19 (0%) | 2/20 (10%) | 1/22 (4%)
| | Severity Profile | – | 0\|1\|0\|0 (2.0) | 0\|0\|1\|0 (3.0) | – | 0\|0\|2\|0 (3.0) | 0\|0\|1\|0 (3.0)
| Terminal | Incidence | 5/50 (10%) | 2/48 (4%) | 7/48 (15%) | 6/50 (12%) | 1/50 (2%) | 1/46 (2%)
| | Severity Profile | 1\|3\|1\|0 (2.0) | 0\|0\|0\|2 (4.0) | 2\|2\|1\|2 (2.4) | 2\|1\|1\|2 (2.5) | 0\|0\|0\|1 (4.0) | 0\|0\|0\|1 (4.0)
| | Poly-3 incidence | 5/38.9 (13%) | 2/34.4 (6%) | 7/36.2 (19%) | 6/33.4 (18%) | 1/36.2 (3%) | 1/28.1 (4%)
Hepatodiaphragmatic Nodule | Interim | Incidence | 1/20 (5%) | 2/20 (10%) | 3/20 (15%) | 3/19 (16%) | 2/20 (10%) | 1/22 (4%)
| | Severity Profile | –^b^ | – | – | – | – | –
| Terminal | Incidence | 3/50 (6%) | 3/48 (6%) | 1/48 (2%) | 5/50 (10%) | 4/50 (8%) | 5/46 (11%)
| | Severity Profile | –^b^ | – | – | – | – | –
| | Poly-3 incidence | 3/37.6 (8%) | 3/34.3 (9%) | 1/35.2 (3%) | 5/33.1 (15%) | 4/37.7 (11%) | 5/28.8 (17%)
Infiltration, cellular, mononuclear cells | Interim | Incidence | 11/20 (55%) | 13/20 (65%) | 9/20 (45%) | 13/19 (68%) | 11/20 (55%) | 15/22 (68%)
| | Severity Profile | 11\|0\|0\|0 (1.0) | 13\|0\|0\|0 (1.0) | 9\|0\|0\|0 (1.0) | 13\|0\|0\|0 (1.0) | 11\|0\|0\|0 (1.0) | 15\|0\|0\|0 (1.0)
| Terminal | Incidence | 34/50 (68%) | 40/48 (83%) | 37/48 (77%) | 33/50 (66%) | 33/50 (66%) | 29/46 (63%)
| | Severity Profile | 19\|15\|0\|0 (1.4) | 27\|13\|0\|0 (1.3) | 19\|18\|0\|0 (1.5) | 26\|7\|0\|0 (1.2) | 23\|10\|0\|0 (1.3) | 15\|13\|1\|0 (1.5)
| | Poly-3 incidence | 34/43.3 (79%) | 40/44.0 (91%) | 37/43.7 (85%) | 33/41.6 (79%) | 33/42.3 (78%) | 29/37.0 (78%)

^a^ BPA doses are μg/kg bw/day. See legend to Table 55 for description of data presentation.

^b^ Severity scores were not assigned for this lesion

In the livers of continuous BPA dose males, statistically significant pairwise comparisons to vehicle controls were noted for fatty change, hepatodiaphragmatic nodules, and mononuclear cell infiltration (Table 112). Two of 20 animals in the 25 μg BPA/kg bw/day interim sacrifice dose group were diagnosed with fatty change; these were the only animals in the interim sacrifice continuous BPA dose group diagnosed with this change, which was statistically significant by the RTE test only. The diagnosis occurred in 4–17% of the terminal sacrifice continuous BPA dose males (vehicle control incidence, 8%), but there was no significant treatment effect.

Stop-dose BPA interim sacrifice males had variable incidences (4–10%) of fatty liver diagnosed in some dose groups, but none were significant and there were similar findings in the terminal sacrifice stop-dose males (Table 114).

Fatty liver was also diagnosed in the interim sacrifice males treated continuously with EE_2_, and there was a significant dose trend (all tests) and a significantly higher incidence in the 0.5 μg EE_2_/kg bw/day dose group relative to vehicle control (15% versus 0%, JT/SW and RTE tests only) (Table 113).

Hepatodiaphragmatic nodule, growth of the median lobe into the diaphragm, is a congenital background lesion. As with fatty liver, there were variable incidences of this lesion diagnosed across treatment groups in both interim and terminal sacrifice males for continuous- and stop-dose BPA and continuous-dose EE_2_. In one case, there was a significantly higher incidence (CAFE test) in the interim sacrifice 2,500 μg BPA/kg bw/day continuous-dose group relative to control (21% versus 0%) (Table 112).

Mononuclear cell infiltration was diagnosed in all dose groups in both interim and terminal sacrifice groups for continuous- and stop-dose BPA and continuous-dose EE_2_. Significant increases over control were noted in multiple continuous BPA dose treatment groups (2.5, 250, 2,500, and 25,000 μg BPA /kg bw/day) relative to vehicle control in interim sacrifice males (Table 112). There were no statistically significant treatment effects in terminal sacrifice BPA-treated males. Mononuclear cell infiltration was increased relative to the vehicle controls in the 0.05 μg EE_2_/kg bw/day terminal sacrifice males (85% versus 70%, Table 113).