# Materials and Methods

## Procurement and Characterization of Bisphenol A

Bisphenol A (BPA, CAS #80-05-7, synonyms: 2,2-bis(4-hydroxyphenyl)propane; 4,4'isopropylidenediphenol) was supplied by TCI America (Portland, OR; product #B0494) as lot #6052012, with a purity assessment on the Certificate of Analysis by Battelle, Inc. (Columbus, OH) of 99.9%. This lot of BPA (original lot designation AOHOK) was purchased by the NTP in 2009 and was characterized for identity and purity by proton nuclear magnetic resonance (NMR) and high performance liquid chromatography with photodiode array detection (HPLC-PDA) at NCTR prior to the start of the BPA subchronic study (NCTR E0217601). Battelle Laboratories extensively characterized this lot of BPA and reported the analysis to be consistent with the manufacturer’s stated purity of 99.9% (Bulk Chemical Limited Analysis Report: Bisphenol A, Battelle Project No. G005430-DSU, October 29, 2010, which was included as part of the NCTR Technical Report for E0217601, July 15, 2013). For the present study, Battelle air milled this same lot of BPA prior to shipment to NCTR and provided a current statement of purity. Purity assessment was conducted at NCTR prior to the study start, at intervals during the study, and after study completion using the technique of HPLC-PDA (spectral purity). A sample of the test article was subjected to HPLC separation at least in triplicate and the PDA was scanned from 200 to 400 nm. A single major peak was obtained at the expected HPLC retention time for BPA and showed 99–100% purity (Supplemental Appendix VII).^a^

a Supplemental Appendices at: h[underlined: ttps://doi.org/10.22427/NTP-DATA-018-00015-0001-000-6] (http://tools.niehs.nih.gov/cebs3/views/?action=main.dataReview&bin_id=3856).

The reference estrogen test article ethinyl estradiol (EE_2_, CAS #57-63-6, product #E4876, lot #071M1492V) was purchased from Sigma-Aldrich Corporation (St. Louis, MO). The stated purity of the EE_2_ was >98%. A sample of this test article was evaluated by HPLC with PDA and electrospray mass spectrometry and found to contain a single peak that contained fragment ions consistent with and matching a reference sample of EE_2_ from Steraloids, Inc. (Newport, RI). Analysis in the same manner as described for BPA showed purity >99% (Supplemental Appendix VII).

CMC (sodium salt; product #C5013, lot #041M0105V) was obtained from Sigma-Aldrich (St. Louis, MO). Aqueous CMC solutions were prepared for use as the vehicle for BPA and EE_2_ by the Diet Preparation Support Group at NCTR as described in Supplemental Appendix IX.

## Preparation and Analysis of Dose Formulations

Dosing solutions or suspensions were prepared by the Diet Preparation Support Group at NCTR (Supplemental Appendix IX). For BPA, the target concentrations of the dose preparations were 0.5, 5, 50, 500, and 5000 μg/mL 0.3% CMC for the 2.5, 25, 250, 2,500, and 25,000 μg/kg bw/day dose groups, respectively. For EE_2_, the target concentrations were 0.01 and 0.1 μg/mL 0.3% CMC for the 0.05 and 0.5 μg/kg bw/day dose groups, respectively. The two high BPA dosing suspensions were mixed by directly adding BPA solid to the vehicle with sonication, and the suspensions were stirred constantly. The three low BPA and the two EE_2_ dosing solutions were mixed by serial dilutions of stock solutions prepared and certified by the NCTR Chemistry Support Group. Stabilities (± 10% of the target) of the low and high dose levels of both BPA and EE_2_ were established for up to 50 days. Homogeneity (± 10% of the target) of the high BPA suspension and both EE_2_ dosing solutions was established (Supplemental Appendix VII).

At the start of the study and approximately every 8–10 weeks over the course of the study, all dose level preparations were assayed by the Chemistry Support Group prior to delivery to the animal rooms and certified to be within 10% of the target concentration with a % CV of ≤10%. In addition, at intervals spaced 4-7 months apart, BPA and EE_2_ dosing preparations from the animal rooms were assayed at the end of their use to verify the dose concentrations. One batch of 0.3% CMC vehicle was found to have a detectable concentration of BPA (0.11 μg/mL) that was approximately 20% of the low BPA dose level (Table 13 in Supplemental Appendix VII). One container of this batch of vehicle was used to dose 16 cages (31 animals; 6 males and 6 females continuous-dose one-year sacrifice and 9 males and 10 females continuous-dose two-year sacrifice) of vehicle control animals ranging in age from PND 139 to PND 141 on a single day before this batch of vehicle was discarded (Supplemental Appendix III, note to study file October 13, 2017). Given the short half-live of BPA and age of the animals, the impact of this event was considered minimal. All affected animals were from the first mating group. Thus, these animals were excluded from the sensitivity analysis described in the Statistical Methods section below. Following the detection of this contaminated batch of vehicle, all batches of vehicle that had been previously used in the study and all subsequent batches of vehicle were assayed and none contained BPA detectable above the analytical background.

## Administration of Dose Formulations and Vehicle

Doses were administered by gavage with modiﬁed Hamilton Microlab® ML511C programmable 115 V pumps (Hamilton Co., Reno, NV). Dosing containers were constantly stirred and dose volume calculation and dispensing were automated.^35^ Four separate dosing stations were used in each animal room: (1) vehicle control; (2) 2.5, 25, and 250 μg BPA/kg bw/day; (3) 2,500 and 25,000 μg BPA/kg bw/day; and (4) 0.05 and 0.5 μg EE_2_/kg bw/day. Dosing was conducted from the lowest to highest dose on any given pump and the Teflon tubing was flushed between dose levels. At the end of each day, each pump was flushed sequentially with water, 70% ethanol, and water. Verification of the accuracy of dose delivery from these pumps had been demonstrated for BPA dosing solutions ranging from 0.5 to 60,000 μg/mL 0.3% CMC and for 0.1 and 1 μg EE_2_/mL 0.3% CMC for the prior NCTR BPA subchronic study (NCTR E0217601); accuracy was verified before the start of this study by chemical analysis for the low dose of EE_2_, which was 10-fold lower than the lowest dose used in the previous experiment (Table 8C in Supplemental Appendix VII). Subsequently, the accuracy of liquid delivery from the pumps was assessed every three months and established to be within 10% of the target volume (Supplemental Appendix XI).

## Diet Assessment: Nutrients and Contaminants, Including Background BPA

Pelleted rodent chow, verified casein diet 10 IF, irradiated, 5K96 (product #1810069, TestDiet, Purina Mills, Richmond, IN) was the diet used in the study. The manufacturer provided analyses for selected nutritive quality attributes (including protein, fat, crude fiber, calcium, phosphorous, and vitamins A, B_1_, and E) and contaminants (including nitrosamines, fumonisins, arsenic, cadmium, lead, mercury, aflatoxins, organochlorine and organophosphate pesticides, butylated hydroxyanisole, butylated hydroxytoluene, and tert-butyl hydroquinone). These analysis reports are found in Supplemental Appendix XII.

On arrival at NCTR, each lot of diet used in the present study was sampled and assayed by the Chemistry Support Group for background BPA and selected phyto- and myco-estrogens (genistein, daidzein, coumestrol, and zearalenone). These results are found in Supplemental Appendix VII. Low (ppb) background levels of BPA above the limit of blank (LOB) had previously been reported in all lots of 5K96 diet used in the prior NCTR BPA subchronic study and in other rodent diets^19,36^ and a rejection limit of 5 ppb BPA in feed was set for both that and the present study. Ten of the 11 lots of diet used in the present study contained detectable levels of BPA, with an average (using 0 for the lot with no BPA detectable above the LOB) of 1.3 ± 0.9 (standard deviation, S.D.) ng/g diet (range 0-3.0). Based on estimates of food consumption (Supplemental Appendix XIIIa and XIIIb) for interim and terminal sacrifice animals, respectively, this resulted in an average consumption over the course of the study of approximately 0.05-0.06 μg BPA/kg bw/day (2-2.5% of the lowest BPA dose tested) at the mean dietary concentration of BPA and approximately 0.12-0.15 μg BPA/kg bw/day (5–6% of the lowest BPA dose tested) at the maximum measured dietary concentration (calculations summarized in Supplemental Appendix XIV). Since younger animals consume higher quantities of food per unit of body weight, younger animals consumed higher background levels of dietary BPA. For example, estimates of food consumption for the week after weaning (week 4) indicate that the amount of BPA consumed per kg bw was approximately 2- to 3-fold higher than the mean value calculated over the entire study (Supplemental Appendix XIV).

The 5K96 diet, which is low in soy-derived phytoestrogens, was selected to ensure a consistent and low level of these phytoestrogens to minimize any impact on the endpoints measured in this study. A goal of 2 ppm total genistein and daidzein was stated in the protocol based on our prior experience with the isoflavone levels attainable in this diet. Although the diet manufacturer indicated that the levels of isoflavones were less than 10 ppm in this diet (page 6 of Supplemental Appendix IX), less than 2 ppm combined genistein and daidzein (measured after hydrolysis of glucosides in the diet) was typical in studies conducted with this diet at NCTR.^13-16,25,36^ Samples of each lot of diet were acid hydrolyzed to convert the glucosides of genistein and daidzein to aglycones that were quantified using HPLC-electrospray ionization-multiple reaction monitoring mass spectrometry. There was variation from lot to lot (Supplemental Appendix VII), but values of genistein and daidzein reported over the course of the study were consistent with the expectation of combined levels less than 2 ppm. After the study concluded and during the preparation of the Chemistry Support Report, however, it was discovered that a calculation error was made and that values of genistein and daidzein were 10-fold higher than those reported during the study. The values reported during the study are reflected in the Diet Preparation Report, Supplemental Appendix IX and the corrected values are found in the Chemistry Support Report, Supplemental Appendix VII. Mean values for genistein and daidzein in the 11 diet lots tested were 1.79 ± 1.94 (S.D.) and 1.66 ± 2.06 (S.D.) ppm, respectively. Although the values of isoflavones in the diet were higher than anticipated based on prior experience with this diet,^13-16,25,36^ the measured levels are low relative to other commonly used chow diets that have been reported to have values ranging from 100 to greater than 600 ppm.^37-40^ The phytoestrogen coumestrol and the mycoestrogen zearalenone were also measured in the diets used in the present study. No rejection level was set for these compounds, although any lot of diet with greater than 0.5 ppm of coumestrol or zearelonone required approval prior to use. Two of the 11 diet lots tested were positive for coumestrol (0.05 and 0.08 ppm) and two lots were positive for zearalenone (0.01 and 0.05 ppm) (Supplemental Appendix VII).

## Assessment of Background BPA in Study Materials Other than Diet

In addition to the dosing vehicle and diet, the rodent drinking water and extracts of animal cages and bedding (hardwood chip and cellulose) were assayed for background BPA levels. These results are reported in Supplemental Appendix VII. For the polysulfone cages (Ancare Corporation, Bellmore, NY) used in this study, previous results from NCTR BPA subchronic study (NCTR E0217601) indicated no BPA detectable above the analytical background (NCTR Technical Report for E0217601, July 15, 2013). For the present study, three previously used polysulfone cages and three newly purchased cages were extracted and the extracts confirmed to have no detectable BPA above the analytical background. Similarly, all drinking water samples and bedding extracts had BPA levels that were less than or close to the analytical limits of the BPA assay.

## Animal Source and Microbiological Surveillance

The NCTR Multigeneration Support System (MGSS), an operator-prompted database system, was used to track the genealogy of all animals in the current study and to collect in-life animal data. For the parental (F_0_) generation, 600 male and 600 female weanling (circa PND 21) Sprague-Dawley/CD23/NctrBR rats were obtained from the NCTR breeding colony in five groups of 120 of each sex. While in the breeding colony, these F_0_ breeders were maintained with their dams under the standard conditions used in the NCTR colony (fed NIH-41 irradiated pellets and housed in polycarbonate cages with hardwood chip bedding and water from polycarbonate bottles). Once assigned to the study at weaning on PND 21, the F_0_ breeders were fed pelleted irradiated TestDiet 5K96 feed, housed two to three per cage in polysulfone cages with hardwood chip bedding, and given water from glass water bottles with silicone stoppers. The rats were held under these conditions until they were individually housed prior to mating for one to two weeks for females, or for 48 hours for males. Animals were 10–15 weeks of age at mating. The animal rooms, water, feed, and health of the animals were monitored during the study in accordance with NCTR’s Sentinel Animal Program; the results are reported in Supplemental Appendix VIII. As noted in a protocol deviation (Supplemental Appendix II), one room was without a sentinel for approximately the last month of the study as the sentinel animal had to be removed as moribund. All 46 sentinel animals evaluated periodically over the course of the study were determined to be free of pathogenic organisms.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals (h[underlined: ttps://grants.nih.gov/grants/olaw/references/phspolicylabanimals.pdf]). The study was conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. The study was approved by the NCTR Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines. NCTR Veterinary Services Staff monitored the health of the animals throughout the study and made recommendations as to the timing of animal removal from the study based on evident distress or discomfort, decreased mobility, or inability to eat or drink. The Veterinary Staff also recommended the transfer of a subset of animals with pododermatitis or ventral masses from hardwood chip bedding that was irritating these lesions to Alpha-Dri cellulose bedding (Shepherd Specialty Papers, Watertown, TN; Supplemental Appendix II and Supplemental Appendix XV, Animals transferred to Alpha-Dri bedding).

## Study Design

A sacriﬁce was conducted at one year of age (PND 365 ± 20) and the terminal sacriﬁce was conducted at two years of age (PND 730 ± 20). The interim (one-year) sacrifice group was included to allow evaluation of long-term exposure effects with less confounding due to background lesions of aging than would be expected at two years. Organ weights and clinical pathology (clinical chemistry and hematology) data were also collected from interim, but not terminal, sacrifice animals given the expected increased moribund removal later in the study and the level of variability in older animals due to age-related disease. A summary of the experimental design and data collected is found in Table 2, and a scheme is shown in Figure 1. The study protocol and all amendments are found in Supplemental Appendix I. Protocol deviations are included in Supplemental Appendix II. Many of these deviations document missing data collections or missed or under- or over-dosing of specific animals on specific days. Cases where missing data affected data analyses are noted in the data summary tables and in the statistical report appendices (Supplemental Appendices XVII-XXXI, XXXIII, and XXXIV).

Table 2 Experimental Design and Materials and Methods in the Two-Year Chronic Gavage Toxicology Study of Bisphenol A (NCTR E0219001), Including Interim (One-Year) Assessment

Experimental Design and Materials and Methods
Study Laboratory | National Center for Toxicological Research (NCTR); Jefferson, AR
Test Article | Bisphenol A (BPA), >99% (CAS #80-05-7), TCI America, Portland, OR [Catalogue #B0494, Lot #6052012, ground to a fine powder by Batelle, Inc., Columbus, OH]
Control Article, Reference Estrogen | Ethinyl estradiol (EE_2_), >98% (CAS #57–63-6), Sigma-Aldrich Corporation, St. Louis, MO [Catalogue #E4876, Lot #071M1492V]
Control Article, Vehicle | Carboxymethylcellulose, sodium salt, Sigma-Aldrich Corporation, St. Louis, MO, [Catalogue #C-5013, Lot #041M0105V] used as a 0.3% (w/w) aqueous solution
Strain and Species | Rats: Sprague-Dawley/CD23/Nctr BR
Animal Source | NCTR breeding colony (Jefferson, AR)
Time Held Before Study | Breeder animals for the study were obtained from the breeding colony at weaning (approximately PND 21) and placed under study conditions (TestDiet low phytoestrogen 5K96 diet, polysulfone rat cages, hardwood chip bedding, glass water bottles with silicone stoppers) until mated at PND 70–100 for females and PND 77– 105 for males.
Age When Exposure Began | Sperm- or in situ vaginal plug-positive females were dosed from GD 6 (sperm or plug detection = GD 0)
Date of First Exposure for F_0_ (GD 6) | Mating #1 09/08/2012 Mating #2 10/06/2012 Mating #3 11/03/2012 Mating #4 12/01/2012 Mating #5 12/29/2012
Route of Exposure | Oral gavage (for pups <PND 5, gavage needle did not enter esophagus)
Duration of Exposure | Dams were dosed daily until start of parturition. There was no dosing on the day of birth (PND 0), and pups were dosed directly from PND 1 until PND 21 for stop-dose group animals and from PND 1 until the day prior to termination for continuous-dose group animals
Date of Last Exposure | 01/14/2015
Age at Necropsy | Scheduled interim necropsy at 1 year (365 ± 20 days of age) Scheduled terminal necropsy at 2 years (104 ± 3 weeks of age) Moribund and dead animals necropsied on removal
Size of Study Groups | For vehicle and BPA dose groups: 20-26 litters in the interim necropsy groups, and 46–50 litters in the terminal necropsy groups For EE_2_ dose groups: 26 litters (interim and terminal necropsy groups)
Method of Animal Allocation | F_0_ females from the NCTR breeding colony were randomly allocated to dose groups prior to mating to give approximately equal mean body weights per dose group. Sires were selected randomly with the specification that there would be no brother/sister or first cousin matings. After the first mating, the numbers of mating pairs assigned to dose groups were adjusted to meet any deficits in pups available in a particular dose group. Pups were randomly culled to a maximum of 5 males and 5 females on PND 1, no fostering was conducted. The minimum litter size for keeping a litter on study was 3 males and 3 females. Up to 3 pups per sex per litter were assigned to the study at weaning; additional pups were assigned to studies conducted by CLARITY-BPA academic investigators and reported elsewhere. The rotating order of assignment of pups of a given sex to the study was as follows: 1) continuous-dose, 2-year sacrifice; 2) stop-dose, 2-year sacrifice; 3) continuous-dose, 1-year sacrifice; 4) continuous-dose, 2-year sacrifice; 5) stop-dose, 2-year sacrifice; and 6) stop-dose, 1-year sacrifice.
Animals per Cage | Pregnant females were housed singly and litters were kept with their dams until weaning at PND 21. Animals were pair housed after weaning in same-sex pairs within dose groups. If an animal died or was removed as moribund, the cage mate remained single housed.
Method of Animal Identification | Tail tattoo; newborns identified by paw tattoo until tail tattoo identification, which occurred within one week of weaning at PND 21
Microbiological Surveillance | Sentinel animals were maintained in each of the animal rooms and animals were removed for surveillance approximately every three months during room occupancy. Animal room supplies (food, water, and bedding) and swabs from the animal rooms were also evaluated.
Diet | Rodent chow, verified casein diet 10 IF, round pellets, irradiated, 5K96 (TestDiet, Purina Mills, Richmond, IN) [Catalogue #1810069] Fed ad libitum
Water | Millipore-filtered tap water (NCTR well water) via water bottle, available ad libitum. Water samples were screened by the Chemistry Support Group, Division of Biochemical Toxicology, NCTR, as part of the normal surveillance procedures of the NCTR.
Cages | Polysulfone (Ancare Corporation, Bellmore, NY) Changed twice weekly, rotated every two weeks.
Bedding | Hardwood chips (P.J. Murphy, Montville, NJ) Changed weekly Alpha-Dri^®^ (Shepherd Specialty Papers, Watertown, TN) was used for animals that developed lower body lesions as recommended by Veterinary Services
Cage Bonnets | Microisolator tops (Ancare Corporation, Bellmore, NY)
Racks | Metal animal cage racks (Allentown Caging Equipment Co., Allentown, NJ). Changed every two weeks and rotated every two weeks.
Animal Room Environment | Temperature: 23°± 3°C Relative humidity: 50% ± 20% Room fluorescent light: 12 hours/day (on 6 AM, off 6 PM) Room air changes: at least 10/hour
Exposure Concentrations | Vehicle control (0.3% CMC) BPA: 2.5, 25, 250, 2,500, and 25,000 μg/kg bw/day EE_2_: 0.05 and 0.5 μg/kg bw/day
Dose administration volume | BPA, EE_2_, and vehicle were administered at a rate of 5 mL/kg bw/day.
Type and Frequency of Observation | Twice daily morbidity/mortality checks, abnormal clinical observations recorded weekly or when a significant clinical observation was noted. Daily body weights for dams from GD 6 through parturition. Pups weighed daily from PND 1 to PND 21. Pups in continuous-dose arm were weighed daily until PND 90 ± 3 and weekly thereafter. Pups in the stop-dose arm were weighed weekly after weaning. Feed consumption was measured weekly for approximately the first 13 weeks and monthly afterwards. Litter parameters: number of pups alive and dead on day of birth (PND 0); number of pups alive and dead and live litter weight by sex on PND 1. Females (26 animals from 13 randomly selected cages per dose group) were monitored daily for vaginal opening from PND 22. Vaginal smears were collected for 14 consecutive days from these same animals beginning at 16 ± 2 weeks of age. One month after these vaginal smears were completed, the same animals had vaginal smears collected for 5 consecutive days monthly until the animal did not show evidence of cycling (three or more consecutive days of estrus (E, E/D or P/E) or five consecutive days that did not include an E) for two consecutive months.
Method of Sacrifice | Asphyxiation with carbon dioxide
Necropsy (F_0_ Dams) | F_0_ dams that were observed to be sperm-positive or had an in situ vaginal plug observed during mating were removed after litters were weaned, after litters that did not meet study criteria were euthanized, or after GD 26 if no litter was delivered. The uterus was removed and implantation sites were counted.
Necropsy (Dead or moribund F_0_ dams and all postweaning F_1_ animals) | Animals underwent a gross examination and complete necropsy as described for interim and terminal sacrifice animals (see below). In addition to tissues designated for processing and/or histopathology in the protocol, the following tissues were examined microscopically to assess possible cause of death in all dead or moribund animals: esophagus, colon, ileum, lung, nose, stomach, trachea, and any gross lesions.
Necropsy (Interim sacrifice, PND 365 ± 20) | Animals were fasted overnight. Animals were anesthetized with carbon dioxide and blood was collected from the retro-orbital sinus prior to euthanasia and complete necropsy. Weighed organs (males): adrenals, brain, epididymides, heart, kidneys, liver, pituitary (after 48-hour fixation), seminal vesicles with coagulating gland, spleen, testes, thymus, thyroid with parathyroid (after 48-hour fixation), epididymal, and retroperitoneal fat pads. Weighed organs (females): adrenals, brain, heart, kidneys, liver, ovaries (with oviducts), pituitary (after 48-hour fixation), spleen, thymus, thyroid with parathyroid (after 48-hour fixation), uterus (blotted), ovarian and parametrial (combined), and retroperitoneal fat pads.
Hematology (Interim sacrifice, PND 365 ± 20) | The following endpoints were evaluated in an aliquot of whole blood: hematocrit, hemoglobin concentration, erythrocyte, leukocyte, reticulocyte, and platelet counts, leukocyte differential count, mean corpuscular volume, and mean corpuscular hemoglobin.
Clinical Chemistry (Interim sacrifice, PND 365 ± 20) | The following endpoints were measured in serum: total protein, albumin, urea nitrogen, creatinine, alanine aminotransferase, gamma glutamyl transpeptidase, sorbitol dehydrogenase, aspartate aminotransferase, alkaline phosphatase, total bile acids, glucose, cholesterol, triglycerides, insulin, leptin, cardiac troponins T and I, T3, T4, and TSH.
Sperm analysis (Interim sacrifice, PND 365 ± 20) | Testicular spermatid head counts (left testis); epididymal sperm counts, morphology, and motility evaluations (left epididymis).
Necropsy and histopathology (Terminal sacrifice, 104 ± 3 weeks) | Procedures were similar to those used for the interim sacrifice, except that the animals were not fasted, blood was not collected, and there were no hematology, clinical chemistry, sperm, or organ weight data collected.
Histopathology (Interim sacrifice, PND 365 ± 20 and terminal sacrifice, 104 ± 3 weeks) | The following organs, as well as all gross lesions, were evaluated microscopically: Males—adrenals, aorta (thoracic), bone marrow (femur), brain, right epididymis, heart, kidneys, liver, 5^th^ left mammary gland (inguinal), pancreas, parathyroid, pituitary, prostate (dorsal/lateral and ventral), seminal vesicles with coagulating gland, spleen, right testis, thymus, and thyroid. For the dorsal/lateral prostate, 6 step sections cut at 100 μm intervals were evaluated. Subsets of intermediate sections were collected and stored unstained for potential additional evaluation. Females—adrenals, aorta (thoracic), bone marrow (femur), brain, heart, kidneys, liver, 5^th^ left mammary gland (inguinal), ovaries, oviduct, pancreas, parathyroid, pituitary, spleen, thymus, thyroid, uterus, and vagina. All tissues, except testes and eyes, were fixed in 10% NBF and stained with H&E for microscopic evaluation. Testes and eyes were fixed in modified Davidson’s fixative and testes were stained with periodic acid-Schiff (PAS) stain. Fixation times for the tissues listed for histopathology, except the brain, were limited to 96–120 hours. Brain remained in fixative until processing.
Tissues removed, fixed in 10% NBF, processed to block and stored (Interim sacrifice, PND 365 ± 20 and terminal sacrifice, 104 ± 3 weeks) | Clitoral gland, esophagus, epididymal fat pad, ovarian/parametrial fat pad, retroperitoneal fat pad, Harderian gland, cecum, colon, rectum, duodenum, ileum, jejunum, lung with bronchi, lymph nodes (mandibular and mesenteric), nose, penis, preputial gland, salivary glands, skin, forestomach, glandular stomach, trachea, and urinary bladder.

Figure 1

Scheme for Chronic BPA Toxicity Study Design

An important component of this study, shown in Figure 1, was the provision of animals from the core study to academic investigators for studies funded by NIEHS as part of the CLARITY-BPA consortium.^11,12^ Results from these academic grantee-conducted studies are not reported here, but are or will be reported in the open literature. All the data collected by the academic grantees as part of the CLARITY-BPA-funded studies will be made available to the public via the NTP website (h[underlined: ttps://ntp.niehs.nih.gov]) and in the NTP’s Chemical Effects in Biological Systems (CEBS) database^b^. The allocation of animals to these studies did impact the allocation of animals to the study reported here, particularly regarding adjustment of the sex distribution for PND 1 culling and the number of animals assigned to the interim sacrifice.

b [underlined: https://doi.org/10.22427/NTP-DATA-018-00015-0001-000-6.]

### Animal Maintenance, Breeding, Randomized Allocation to Study, and Dosing

Animals were housed in rooms with a 12-hour light cycle (lights on at 6 AM and off at 6 PM) and 10 room air changes per hour. For all animals, cages were changed twice weekly. Glass water bottles were changed weekly or as often as necessary to maintain a constant supply of drinking water. Throughout the study, cage racks were changed every two weeks and cage locations on those racks were rotated every two weeks. The study definition documents and startup memos that describe the cage and rack arrangements in the animal rooms are included as Supplemental Appendices IV and V. Animal rooms were maintained at 23 ± 3°C and 50 ± 20% humidity and were monitored so that corrective action could be taken if values went outside these limits. Summary temperature and humidity reports for all animal rooms are in Supplemental Appendix X. In one case, a malfunction of a humidity sensor required movement of animals to another animal room for approximately 11 weeks (Supplemental Appendix II).

Approximately two weeks prior to mating, female breeders were randomized to treatment groups, stratiﬁed by body weight to produce approximately equivalent mean body weights in each group. The weight ranking and pairing information provided by the NCTR Statistical Support Group for each mating are in Supplemental Appendix VI. Male breeders were assigned to breeding pairs with the stipulation that no sibling or ﬁrst cousin mating was permitted. Rats were mated at 10–14 weeks of age for females and 11–15 weeks of age for males. Females were placed in solid-bottomed polysulfone cages with hardwood chip bedding with the assigned males and were assessed daily for up to 10 days for sperm-positive vaginal smears or a copulation plug that precluded a vaginal smear. In three cases, males intended for mating with females in BPA or EE_2_ dose groups died prior to mating and, in two of these cases, males from the vehicle control group that had already been mated with control females were re-mated with these females (Table 3). Dams were separated from the males on the day of sperm/plug detection, which was designated GD 0. If no sperm-positive vaginal smear or copulation plug was detected after 10 days, the pair was removed from the study and euthanized. Mating was conducted in five cohorts spaced four weeks apart. The number of pairs assigned to treatment groups in each mating group is shown in Table 3. While equivalent numbers of breeding pairs were assigned to the vehicle control and all BPA dose groups in the first three cohorts, adjustments were made in the fourth and fifth mating assignments based on the number of pups that had been allocated to the study from the earlier matings. The number of litters produced in each dose group in each mating and the number of litters contributing pups to the study are shown in Table 4 and Table 5, respectively. Mating was conducted prior to the start of dosing on GD 6, and thus breeding success was not an endpoint for analysis in this study.

Table 3 Numbers of F_0_ Breeding Pairs Assigned to Study^a^

Matings | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_ | Total
Mating 1 | 16 | 16 | 16^b^ | 16 | 16 | 16 | 10 | 14 | 120
Mating 2 | 17 | 17 | 17 | 17 | 17 | 17 | 9 | 9 | 120
Mating 3 | 17 | 17 | 17 | 17 | 17 | 17 | 9 | 9 | 120
Mating 4 | 15 | 15 | 17 | 16 | 14^c^ | 14 | 13^c^ | 14 | 118
Mating 5 | 15 | 16 | 20 | 18 | 15 | 11 | 10 | 15 | 120
Total, Matings 1-5^d^ | 80 | 81 | 87 | 84 | 79 | 75 | 51 | 61 | 598

^a^ Doses of BPA and EE_2_ are μg/kg bw/day.

^b^ Only 15 pairs were mated due to the death of a male prior to breeding.

^c^ Due to the deaths of male breeders, one female in each of these groups was mated with a male that had previously mated with a control female.

^d^ The numbers of resulting sperm-positive dams were as follows: vehicle, 78; 2.5 BPA, 74; 25 BPA, 76; 250 BPA, 78; 2500 BPA, 76; 25000 BPA, 71; 0.05 EE_2_, 51; 0.50 EE_2_, 60.

Table 4 Number of Litters Produced Per Mating^a^

Matings | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_ | Total
Mating 1 | 16 | 15 | 8 | 9 | 13 | 12 | 9 | 12 | 94
Mating 2 | 14 | 13 | 10 | 14 | 15 | 16 | 8 | 8 | 98
Mating 3 | 15 | 13 | 13 | 13 | 15 | 16 | 6 | 8 | 99
Mating 4 | 13 | 13 | 13 | 12 | 12 | 11 | 10 | 10 | 94
Mating 5 | 15 | 11 | 17 | 16 | 9 | 10 | 8 | 13 | 99
Total, Matings 1-5 | 73 | 65 | 61 | 64 | 64 | 65 | 41 | 51 | 484

^a^ Doses of BPA and EE_2_ are μg/kg bw/day.

Table 5 Number of Litters Contributing Pups to Interim and/or Terminal Assessments^a^

Matings | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_ | Total
Mating 1 | 16 | 14 | 8 | 7 | 13 | 12 | 6 | 10 | 86
Mating 2 | 13 | 13 | 10 | 14 | 15 | 14 | 7 | 8 | 94
Mating 3 | 15 | 12 | 12 | 11 | 14 | 14 | 4 | 6 | 88
Mating 4 | 12 | 12 | 13 | 11 | 11 | 11 | 8 | 4 | 82
Mating 5 | 15 | 11 | 16 | 16 | 8 | 9 | 2 | 3 | 80
Total, Matings 1-5 | 71 | 62 | 59 | 59 | 61 | 60 | 27 | 31 | 430

^a^ Doses of BPA and EE_2_ are μg/kg bw/day.

Daily gavage dosing of the dams began on GD 6 (GD 0 = sperm- or plug-positive day) and continued until the initiation of parturition. Pups were not dosed on the day of birth (PND 0). Pups without evident malformations were randomly culled to a maximum of ﬁve males and ﬁve females on PND 1. While the post-culling sex ratio was generally balanced, the sex distribution was skewed toward males later in the study because the hypothesis-driven studies conducted by academic investigators required a culling strategy to provide more males than females. Litters with fewer than three pups/sex and live litters born to dams earlier than GD 20 were excluded from the core study, except in the cases of three females in the 25,000 μg/kg bw/day continuous BPA dose group that came from litters that did not have three pups/sex (Supplemental Appendix II). Direct gavage dosing of the pups started on PND 1 after the litter was culled. For animals younger than PND 5, the gavage needle was inserted to the opening of the esophagus, but did not enter the esophagus.^41^ This dosing method for young pups had also been used in the BPA subchronic study conducted at NCTR, where serum levels were measured after dosing in PND 4 animals demonstrating the effectiveness of this dosing procedure.^19,25^ Pups were weighed and dosed daily until weaning at PND 21. After weaning, same-sex pups were housed two per cage and either dosed by gavage with vehicle, BPA, or EE_2_ daily until termination (continuous-dose arm) or maintained without further dosing (stop-dose arm).

At weaning, up to a maximum of three pups/sex/litter were assigned to the chronic study. Same-sex littermates were not assigned to the same combination of study dose arm and time of sacriﬁce so that litter of origin was not a factor to be considered in the statistical analysis of endpoints collected after weaning. Twenty to 26 pups/sex/dose group were assigned to the one-year interim continuous-dose assessment (Table 6); 19 to 22 pups/sex/dose group were assigned to the one-year interim stop-dose assessment (Table 7); 46 to 50 pups/sex/BPA dose group/dose arm and 26 pups/sex/EE_2_ dose group were assigned to the two-year study continuous-dose assessment (Table 8); and 46 to 50 pups/sex/BPA dose group/dose arm were assigned to the two-year study stop-dose assessment (Table 9). The remaining pups from those litters with more than three same-sex pups were assigned to the hypothesis-driven studies of academic investigators. The reason that stop-dose EE_2_ groups were not included in the study was solely an animal facility space and resource consideration, given the number of animals that needed to be provided and housed for both this study and the NIEHS-funded academic CLARITY-BPA grantee studies.

Table 6 Number of Male and Female Pups Represented in Interim (1-Year) Sacrifice from Each Mating, Continuous-Dose^a^

Continuous-Dose | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_ | Total
Males, Mating 1 | 6 | 6 | 4 | 2 | 4 | 4 | 6 | 8 | 40
Males, Mating 2 | 4 | 4 | 4 | 6 | 6 | 6 | 6 | 8 | 44
Males, Mating 3 | 4 | 6 | 4 | 4 | 6 | 6 | 4 | 4 | 38
Males, Mating 4 | 6 | 4 | 4 | 4 | 2 | 4 | 8 | 4 | 36
Males, Mating 5 | 2 | 2 | 4 | 8 | 2 | 2 | 2 | 2 | 24
Total males, Matings 1-5 | 22 | 22 | 20 | 24 | 20 | 22 | 26 | 26 | 182
Females, Mating 1 | 8 | 6 | 4 | 4 | 6 | 4 | 6 | 8 | 46
Females, Mating 2 | 5 | 4 | 4 | 6 | 6 | 6 | 6 | 8 | 45
Females, Mating 3 | 6 | 4 | 4 | 4 | 4 | 6 | 4 | 6 | 38
Females, Mating 4 | 2 | 2 | 4 | 4 | 4 | 4 | 8 | 2 | 30
Females, Mating 5 | 2 | 6 | 6 | 6 | 0 | 4 | 2 | 2 | 28
Total females, Matings 1-5 | 23 | 22 | 22 | 24 | 20 | 24 | 26 | 26 | 187

^a^ Doses of BPA and EE_2_ are μg/kg bw/day.

Table 7 Number of Male and Female Pups Represented in Interim (1 Year) Sacrifice from Each Mating, Stop-Dose^a^

Stop-Dose | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | Total
Males, Mating 1 | 4 | 4 | 2 | 2 | 6 | 6 | 24
Males, Mating 2 | 6 | 4 | 2 | 6 | 6 | 4 | 28
Males, Mating 3 | 6 | 4 | 6 | 4 | 6 | 6 | 32
Males, Mating 4 | 2 | 4 | 6 | 4 | 2 | 4 | 22
Males, Mating 5 | 2 | 4 | 4 | 4 | 0 | 2 | 16
Total males, Matings 1-5 | 20 | 20 | 20 | 20 | 20 | 22 | 122
Females, Mating 1 | 4 | 6 | 2 | 2 | 4 | 6 | 24
Females, Mating 2 | 4 | 6 | 4 | 4 | 6 | 6 | 30
Females, Mating 3 | 6 | 6 | 2 | 4 | 6 | 6 | 30
Females, Mating 4 | 4 | 4 | 6 | 4 | 2 | 4 | 24
Females, Mating 5 | 2 | 0 | 6 | 8 | 2 | 0 | 18
Total females, Matings 1-5 | 20 | 22 | 20 | 22 | 20 | 22 | 126

^a^ Doses of BPA are μg/kg bw/day.

Table 8 Number of Male and Female Pups Represented in Terminal (2 Year) Sacrifice from Each Mating, Continuous-Dose^a^

Continuous-Dose | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.50 EE_2_ | Total
Males, Mating 1 | 13 | 12 | 6 | 6 | 10 | 10 | 6 | 10 | 73
Males, Mating 2 | 11 | 10 | 8 | 12 | 12 | 12 | 6 | 8 | 79
Males, Mating 3 | 12 | 10 | 10 | 8 | 12 | 12 | 4 | 4 | 72
Males, Mating 4 | 12 | 8 | 12 | 10 | 8 | 8 | 8 | 2 | 68
Males, Mating 5 | 2 | 8 | 12 | 14 | 8 | 4 | 2 | 2 | 52
Total males, Matings 1-5 | 50 | 48 | 48 | 50 | 50 | 46 | 26 | 26 | 344
Females, Mating 1 | 14 | 12 | 6 | 6 | 10 | 10 | 6 | 10 | 74
Females, Mating 2 | 10 | 10 | 8 | 12 | 12 | 10 | 6 | 8 | 76
Females, Mating 3 | 12 | 10 | 10 | 8 | 12 | 10 | 4 | 4 | 70
Females, Mating 4 | 10 | 8 | 10 | 10 | 8 | 8 | 8 | 2 | 64
Females, Mating 5 | 4 | 8 | 12 | 14 | 8 | 8 | 2 | 2 | 58
Total females, Matings 1-5 | 50 | 48 | 46 | 50 | 50 | 46 | 26 | 26 | 342

^a^ Doses of BPA and EE_2_ are μg/kg bw/day.

Table 9 Number of Male and Female Pups Represented in Terminal (2 Year) Sacrifice from Each Mating, Stop-Dose^a^

Stop-Dose | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | Total
Males, Mating 1 | 14 | 12 | 6 | 6 | 10 | 10 | 58
Males, Mating 2 | 10 | 10 | 8 | 12 | 12 | 12 | 64
Males, Mating 3 | 12 | 10 | 10 | 8 | 12 | 12 | 64
Males, Mating 4 | 12 | 8 | 12 | 10 | 10 | 8 | 60
Males, Mating 5 | 2 | 8 | 12 | 14 | 6 | 4 | 46
Total males, Matings 1-5 | 50 | 48 | 48 | 50 | 50 | 46 | 292
Females, Mating 1 | 14 | 12 | 6 | 6 | 10 | 10 | 58
Females, Mating 2 | 10 | 10 | 8 | 12 | 12 | 12 | 64
Females, Mating 3 | 12 | 10 | 10 | 8 | 12 | 12 | 64
Females, Mating 4 | 10 | 10 | 12 | 10 | 10 | 8 | 60
Females, Mating 5 | 4 | 8 | 12 | 14 | 6 | 4 | 48
Total females, Matings 1-5 | 50 | 50 | 48 | 50 | 50 | 46 | 294

^a^ Doses of BPA are μg/kg bw/day.

### Animal Identiﬁcation

Prior to mating, all F_0_ females were identiﬁed with their unique cage number by tail tattoo (Animal Identiﬁcation and Marking Systems, Inc., Hornell, NY). F_1_ pups were initially numbered on their backs with an indelible marker after culling on PND 1 and then shortly thereafter with a standard 4-paw tattoo pattern. The paw tattoo pattern and dam identification number (cage number) provided unique identiﬁcation for preweaning pups. Retained F_1_ pups were marked by tail tattoo with their unique identification number (cage number and an additional digit to distinguish cage mates) after weaning on PND 21.

## Data Collected in Interim and Terminal Sacrifice Animals

### In-Life Data Collection

All activities conducted by animal care technicians in the animal rooms were monitored by the MGSS. Morbidity/mortality checks were performed twice daily and clinical observations were recorded weekly or when a signiﬁcant clinical observation was noted. Starting at six months of age, animals were palpated weekly to detect the presence and progress of tissue masses. Body weights were obtained prior to dosing for dams from GD 6 through parturition and similarly for the pups from PND 1, as described above. Feed consumption was measured weekly from the start of dosing for approximately the next 13 weeks and monthly afterward. These data were not analyzed beyond summary statistics that were used to estimate consumption of background dietary BPA as a result of the low (<5 ppb) level of BPA in the feed (Supplemental Appendices XIII a and b, XIV). On the day of birth, PND 0, the number of pups alive and dead was recorded. On PND 1, the number of pups alive and dead, sex ratio, and live litter weight by sex were determined prior to culling. Individual body weights for all retained pups were recorded daily from PND 1 until weaning at PND 21. Animals in the continuous-dose arm were weighed daily through PND 90 ± 3 and weekly thereafter. Weights of animals in the stop-dose arm were recorded weekly after weaning.

All dams that were sperm- or plug-positive were euthanized after litters were weaned, on the litter’s day of birth if the litter had less than three pups/sex, or on GD 26 if no litter was produced. The uterus was removed and stained with 10% ammonium sulfide for enumeration of implantation sites.

Females (26 animals from 13 randomly selected cages per dose group per dose arm from the two-year study arm) were monitored daily for vaginal opening from PND 22. Vaginal smears were collected for 14 consecutive days from these same animals beginning at 16 ± 2 weeks of age. One month after these vaginal smears were completed, the same animals had vaginal smears collected for five consecutive days monthly until the animal did not show evidence of cycling, that is, that showed three or more consecutive days of estrus (including estrus, estrus/diestrus, or proestrus/estrus intermediate stages) or five consecutive days that did not include an estrus smear for two consecutive months.

### Clinical Chemistry and Hematology, Interim Sacrifice Animals

For the one-year interim sacrifice, food, but not water, was removed from cages on the evening before the scheduled necropsy. Animals were anesthetized with gaseous carbon dioxide and blood was collected from the retro-orbital sinus. Hematology and clinical chemistry endpoints evaluated are listed in Table 2. All blood was collected into serum and ethylenediaminetetraacetic acid (EDTA) tubes between 7:00 AM and 12:00 PM. Blood in the serum tubes was allowed to clot and centrifuged at 1000 × g for 10 minutes at room temperature. The serum was removed and aliquoted into two tubes. One tube was used for immediate testing (see below) and the other was frozen at -60°C until additional testing was performed. The EDTA tube was used for hematology testing performed the same day as collection.

Clinical chemistry analyses were conducted on an Alfa Wassermann ALERA (West Caldwell, NJ). Alfa Wassermann reagents were used to quantify glucose, alkaline phosphatase, alanine aminotransferase, aspartate aminotransferase, γ-glutamyl transpeptidase, total protein, albumin, cholesterol, triglycerides, blood urea nitrogen, and creatinine. Catachem (Bridgeport, CT) reagents were used to quantify sorbitol dehydrogenase and total bile acids. All testing was completed on the day of collection. The instrument was calibrated daily and two levels of assayed controls were included in daily analyses as internal controls.

Rat-specific troponin I, troponin T (Life Diagnostics, West Chester, PA), and leptin (Millipore, St. Charles, MO) were quantified using ELISA methods. The plates were read on an ELx800 Universal Microplate Reader (Bio-Tek, Winooski, VT). A standard curve was run with each batch of samples and results were calculated by the instrument’s software. Insulin, triiodothyronine (T3), and thyroxine (T4) were quantified using Siemens (Los Angeles, CA) RIA “Coat-a-Count” method and thyroid-stimulating hormone (TSH) with rat-specific TSH radioimmune assay (Alpco, Salem, NH). The tubes were then counted on a Wizard2 gamma counter (PerkinElmer, Shelton, CT). A standard curve was run with each batch of samples and results were calculated by the instrument’s software. Two levels of assayed controls were included in daily analyses as internal controls.

Complete blood counts were determined on an Pentra 60 C+ analyzer (ABX, Irvine, CA). Maintenance and calibration were done per the manufacturer’s recommendations. Three levels of assayed controls were included in daily analyses as internal controls. Packed cell volume (PCV) analysis was performed by centrifugation in a CritSpin centrifuge (Beckman Coulter, Inc, Indianapolis, IN) and PCV determined by manual read. For determining the percentage of reticulocytes, 1,000 cells per animal were counted on slides prepared from blood collected in EDTA tubes and stained with New Methylene Blue Reticulocyte Stain (Volu-Sol, Salt Lake City, UT).

### Sperm Evaluations, Interim Sacrifice Animals

For sperm motility assessment, the left epididymis was dissected from the testis and weighed. If gross lesions or abnormalities were noted at necropsy with either the left testis or epididymis, the right organ was used for motility studies and the left was sent for histology. The cauda section was dissected and immediately placed in a petri dish containing 40 mL of a solution consisting of 1% bovine serum albumin dissolved in phosphate buffered saline. The solution was prewarmed to a temperature of approximately 37°C. A minimum 2-minute period was allowed for the sperm to swim out. Following the swim-out period, a sperm sample was obtained using an 80 µm deep slide. The slide was immediately loaded into the prewarmed stage of the Hamilton Thorne IVOS automated sperm analyzer. Five fields were automatically selected by the analyzer, and each motion image was recorded and stored on an optical disk. The images were subsequently analyzed and the percent motility determined for each animal. Two eosin-stained slides were also prepared for each animal from the caudal epididymis suspension for evaluation of morphological development; a minimum of 200 sperm cells/animal was examined.

After the motility and morphology samples were collected, the cauda was minced with scissors and mixed. Approximately 1 mL of the suspension was placed in a prelabeled tube and frozen on dry ice for subsequent determination of the total caudal sperm count. The left testis was weighed, placed on dry ice, and stored frozen until evaluation for testicular spermatid head counts. Each frozen epididymis suspension and testis was thawed. The tunic was removed from the testis, and each testis was weighed and homogenized. The suspension was transferred to a vial containing a dye (IDENT, bis-benzimide trihydrochloride, Hamilton Thorne, Inc., Beverly, MA) that uniquely stains the head of sperm. A sample of the stained sperm was placed into a 20 µm deep glass slide that was loaded into the analyzer. Twenty fields were automatically selected by the instrument for each animal, and total sperm counts were determined. The counts were reported adjusted for testis weight (million sperm/g tissue).

### Organ Weights and Histopathology

All animals maintained on study after weaning that survived to the scheduled sacrifice dates or were removed early as dead or moribund were subjected to a full necropsy. All gross lesions were processed for histological evaluation. Selected organs were collected and weighed at the interim sacrifice (Table 2). Weights of the dorsal/lateral and ventral prostate lobes were not collected, because the dissection and trimming procedure necessary to obtain these weights would interfere with the processing of the organ for histopathology (Supplementary Appendix II, Protocol Amendment #7). Organs were not weighed at the terminal sacrifice. Tissues not speciﬁed for microscopic evaluation, which are listed in Table 2, were processed to parafﬁn block and held for potential later evaluation. For tissues speciﬁed for evaluation by the study pathologist (Table 2), tissues from all dose groups were evaluated for both the interim and terminal sacrifice animals. Tissues were processed in accordance with NTP specifications (h[underlined: ttps://ntp.niehs.nih.gov/ntp/test_info/finalntp_reprospecsmay2011_508.pdf], h[underlined: ttps://ntp.niehs.nih.gov/ntp/test_info/finalntp_toxcarspecsjan2011.pdf]), except that six step sections of each prostate were examined. The International Harmonization of Nomenclature and Diagnostic Criteria (INHAND) guidelines (h[underlined: ttps://www.toxpath.org/inhand.asp]) were used as diagnostic criteria for the microscopic evaluations. For the female reproductive tissues, mammary gland, and male reproductive tissues, the diagnostic criteria outlined in Dixon et al. (2014), Rudmann et al. (2012), and Creasy et al. (2012),^42-44^ respectively, were used. Approximately 9% of the animals in the study, represented in all dose groups, were observed to have seizures over the course of the study, mostly during handling procedures (e.g., dosing, cage changes). The brains, spinal cords, and peripheral nerves of these animals were examined by the study pathologist for any histological abnormalities (Supplemental Appendix XXXII). For the two-year sacriﬁce, animals were not fasted, and no clinical chemistry, hematology, organ weights, or sperm evaluations were conducted.

Upon completion of the microscopic evaluations, the data were entered into the NTP’s Toxicology Data Management System Enterprise. Slides, paraffin blocks, and residual wet tissues were sent to the Block and Slide Laboratory for inventory, slide/block match, and wet tissue audit. Individual animal data records and pathology tables were evaluated by an independent quality assessment (QA) group, and QA pathologists evaluated selected histopathology slides. The reviewed slides, along with the diagnoses made by the study pathologist and QA pathologists, were reviewed by the Pathology Working Group (PWG). The QA pathologists served as coordinators of the PWG. Representative histopathology slides containing examples of lesions potentially related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. While tissues from multiple organ systems were selected by the QA pathologists for review by the PWG to allow evaluation and confirmation of the broad spectrum of lesions observed in control and treatment groups, female and male reproductive tissues were emphasized in the review. The PWG consisted of the QA pathologists, the study pathologist, and other pathologists experienced in rodent toxicological pathology. This group examined the tissues with no knowledge of dose groups. When the PWG consensus differed from the opinion of the study pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus of the PWG.

## Statistical Methods

The full statistical analysis reports for all protocol-specified endpoints, including detailed methods and results for each analysis, including the omnibus tests, are found in Supplemental Appendices XVII-XXXI, XXXIII, and XXXIV. The pairwise comparisons to the vehicle control and trend tests are the comparisons of interest that are presented in the tables in this report. The statistical methodology for each endpoint is summarized below. Statistical comparisons were conducted within sex and, for data collected after weaning, within dosing arm (continuous-dose or stop-dose). For pairwise comparisons, the ﬁve BPA dose groups were compared to the vehicle control group. Similarly, the two EE_2_ reference estrogen dose groups were compared to the vehicle control. Tests were conducted at the 0.05 significance level and, in most cases, were two-sided. Exceptions were one-sided tests for the pairwise comparisons of histopathology lesion incidence and severity to vehicle controls and trend tests for abnormal estrous cycles. Although a p-value of <0.05 was used to flag a result as significant, the actual p-values are included in some of the tables in this report and in all the statistical report appendices (Supplemental Appendices XVII-XXXI, XXXIII, and XXXIV) to aid in the further evaluation of the statistical and biological significance of each result. Trend tests for treatment effect (either increased or decreased relative to vehicle control) with increasing dose were conducted only for vehicle control and BPA treatment groups, except for non-neoplastic and neoplastic lesions, where trend tests were also conducted within the vehicle control and EE_2_ groups. Because pups within litter and sex were assigned at weaning to different dosing arms and sacrifice times, litter correlation was not a consideration for endpoints evaluated after weaning in this study.

### Survival Analyses (Supplemental Appendices XX, XXI, and XXII)

Animals with a disposition of dead or moribund were treated as uncensored observations, while those reaching PND 21, one year, or two years were considered censored for the preweaning, interim, and terminal survival analyses, respectively. To compare survival of treatment groups to the control group, Cox proportional hazards regression analysis was performed. For the interim sacrifice survival analysis, several groups had 100% survival. For this situation, a modified Cox proportional hazards regression analysis was performed after adjusting the number of uncensored observations by adding one for each treatment group and sex to allow estimability. Multiple comparisons of treatments to the vehicle control group were adjusted using Holm’s (step-down Bonferroni) method.

### Body Weight Analyses (Supplemental Appendices XVII, XXIII, XXIV, and XXV)

Gestational weight at parturition was analyzed using analysis of covariance (ANOCOVA) with terms for treatment group, dam weight at baseline, and litter size as covariates, and the interaction between treatment and litter size. Data were collected at baseline on GD 0 or GD 1 prior to dosing and daily from GD 6 to parturition. Gestational weight at parturition was defined as the last dam body weight prior to delivery. For preweaning pup body weight data, the analysis was performed using contrasts within sex and PND. The experimental unit was the litter, and a stratified one-way repeated measures, mixed model analysis of variance (ANOVA) was used to test for treatment effect and to account for litter correlation assuming a compound symmetric correlation structure. The cross-sectional analysis was performed on selected PNDs (1, 4, 7, 14, and 21) so that the intra-litter correlation could be accounted for accurately.

For the interim sacrifice and terminal sacrifice postweaning analyses, there were no littermates among the males or females in any dose group within each dosing arm and sacrifice time, so intra-litter correlation was not considered. Body weight data collected from four to 52 weeks (interim sacrifice animals) or four to 104 weeks (terminal sacrifice animals) were analyzed using the last weekly observation for each animal, with PND 21 defined as the first day of week four. Although no formal comparisons were made between the continuous- and stop-dose study arms, for females and males in both the interim and terminal sacrifice phases, the week 4 body weights in the continuous-dose groups appeared to be higher than the week 4 body weights in the stop-dose groups (compare Table 24 and Table 25 with Table 26 and Table 27 for females; compare Table 28 and Table 29 with Table 30 and Table 31 for males). This apparent difference was an artifact of the experimental design and the statistical analysis. After weaning, the continuous-dose groups were weighed daily until PND 90, so that the last body weight of week 4 was PND 27. For the stop-dose groups, weekly body weights were taken after weaning, so the last body weight recorded in week 4 was generally earlier than PND 27. Outliers were identified by comparing observed body weight to predicted body weight using a five-point running median smoother and nearest neighbor interpolation. A threshold for outlier exclusion was set at a difference between observed and predicted weights greater than 35 g for both sexes in the interim analysis, and 60 and 65 g for females and males, respectively, in the terminal analysis. Lists of the outliers are found in Supplemental Appendices XXIV and XXV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA for females and males separately. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure that allows for correlated differences in variability across time points. Pairwise comparisons of each treatment mean to the vehicle control group mean were performed using contrasts with Dunnett’s method of adjustment for multiple comparisons.

Table 24 Female Postwean Body Weights (g), Vehicle, BPA, and EE_2_ Continuous-Dose, Interim (1 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
4 | 76 ± 1 (23) | 77 ± 2 (22) | 76 ± 2 (22) | 74 ± 2 (24) | 73 ± 1 (20) | 75 ± 2 (24) | 75 ± 2 (26) | 81 ± 2 (26)
8 | 196 ± 5 (23) | 203 ± 4 (22) | 205 ± 4 (22) | 196 ± 4 (24) | 196 ± 4 (20) | 197 ± 4 (24) | 201 ± 4 (26) | 209 ± 4 (26)
12 | 268 ± 6 (22) | 277 ± 6 (22) | 278 ± 6 (22) | 266 ± 6 (24) | 262 ± 5 (20) | 262 ± 6 (24) | 273 ± 7 (26) | 262 ± 5 (26)
16 | 302 ± 8 (22) | 314 ± 7 (22) | 317 ± 7 (22) | 299 ± 7 (24) | 293 ± 5 (20) | 293 ± 7 (24) | 308 ± 7 (26) | 291 ± 5 (26)
20 | 322 ± 8 (22) | 342 ± 9 (22) | 345 ± 8 (22) | 316 ± 8 (24) | 311 ± 6 (20) | 316 ± 10 (24) | 332 ± 8 (26) | 312 ± 6 (26)
24 | 340 ± 10 (22) | 363 ± 12 (22) | 362 ± 9 (22) | 331 ± 9 (24) | 331 ± 6 (20) | 332 ± 11 (24) | 352 ± 9 (26) | 330 ± 8 (26)
28 | 354 ± 10 (22) | 382 ± 13 (22) | 380 ± 11 (22) | 344 ± 10 (24) | 346 ± 7 (20) | 351 ± 12 (24) | 365 ± 9 (26) | 348 ± 8 (26)
32 | 370 ± 13 (22) | 403 ± 14 (22) | 395 ± 11 (22) | 360 ± 11 (24) | 362 ± 8 (20) | 366 ± 13 (24) | 384 ± 10 (26) | 367 ± 10 (26)
36 | 384 ± 14 (22) | 422 ± 16b (22) | 410 ± 12 (22) | 374 ± 12 (24) | 376 ± 9 (20) | 378 ± 14 (24) | 398 ± 10 (26) | 384 ± 10 (26)
40 | 396 ± 15 (22) | 439 ± 18^b^ (22) | 422 ± 12 (22) | 377 ± 10 (23) | 394 ± 10 (20) | 396 ± 14 (24) | 417 ± 11 (25) | 397 ± 10 (26)
44 | 410 ± 16 (22) | 455 ± 19^b^ (22) | 434 ± 13 (22) | 389 ± 11 (23) | 409 ± 12 (20) | 409 ± 16 (24) | 434 ± 11 (25) | 412 ± 11 (26)
48 | 421 ± 18 (21) | 476 ± 20^b^ (22) | 447 ± 14 (21) | 408 ± 13 (22) | 424 ± 12 (20) | 428 ± 17 (24) | 449 ± 13 (24) | 427 ± 12 (26)
52 | 436 ± 19 (21) | 494 ± 22^b^ (22) | 460 ± 15 (21) | 427 ± 14 (22) | 436 ± 13 (20) | 441 ± 18 (24) | 468 ± 14 (24) | 440 ± 12 (26)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXIV. Analyses were conducted separately for BPA and EE_2_ dose groups. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIV. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

^b^ Mean body weights at the later time points, weeks 36 to 52, were 10–13% higher than control means in the 2.5 μg BPA/kg bw/day. The Dunnett-corrected p-values were 0.080, 0.058, 0.071, 0.065, and 0.062, for weeks 36, 40, 44, 48, and 52, respectively.

Table 25 Female Postwean Body Weights (g), Vehicle, BPA, and EE_2_ Continuous-Dose, Terminal (2 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
4 | 75 ± 1 (50) | 76 ± 1 (48) | 78 ± 1 (46) | 76 ± 1 (49) | 74 ± 1 (50) | 76 ± 1 (46) | 76 ± 1 (26) | 80 ± 2* (26)
8 | 196 ± 3 (50) | 201 ± 3 (48) | 202 ± 2 (46) | 199 ± 2 (49) | 198 ± 3 (50) | 204 ± 3^b^ (45) | 200 ± 4 (26) | 212 ± 4* (26)
12 | 266 ± 4 (50) | 269 ± 4 (48) | 270 ± 4 (46) | 267 ± 3 (49) | 266 ± 4 (50) | 269 ± 3 (45) | 269 ± 6 (26) | 268 ± 6 (26)
16 | 302 ± 5 (50) | 305 ± 5 (47) | 303 ± 5 (46) | 299 ± 3 (49) | 300 ± 4 (50) | 302 ± 4 (45) | 299 ± 6 (26) | 299 ± 7 (26)
20 | 324 ± 6 (50) | 327 ± 6 (47) | 325 ± 6 (46) | 319 ± 4 (49) | 319 ± 5 (50) | 321 ± 4 (45) | 320 ± 7 (26) | 320 ± 9 (26)
24 | 342 ± 6 (50) | 345 ± 7 (46) | 346 ± 6 (45) | 336 ± 5 (49) | 336 ± 5 (50) | 338 ± 5 (45) | 339 ± 8 (26) | 338 ± 10 (26)
28 | 359 ± 7 (50) | 360 ± 7 (46) | 362 ± 7 (45) | 354 ± 5 (49) | 352 ± 6 (50) | 356 ± 5 (45) | 351 ± 8 (26) | 354 ± 11 (26)
32 | 372 ± 8 (50) | 376 ± 8 (46) | 376 ± 8 (45) | 366 ± 6 (49) | 366 ± 6 (50) | 369 ± 6 (45) | 366 ± 9 (26) | 373 ± 12 (26)
36 | 387 ± 8 (50) | 392 ± 9 (46) | 393 ± 8 (45) | 384 ± 6 (49) | 375 ± 7 (50) | 379 ± 6 (45) | 375 ± 9 (26) | 390 ± 13 (26)
40 | 402 ± 9 (50) | 407 ± 10 (46) | 407 ± 10 (45) | 396 ± 7 (48) | 388 ± 8 (49) | 394 ± 7 (45) | 392 ± 10 (26) | 406 ± 13 (26)
44 | 417 ± 10 (50) | 421 ± 11 (45) | 419 ± 10 (45) | 410 ± 8 (47) | 403 ± 8 (48) | 410 ± 8 (45) | 403 ± 11 (26) | 421 ± 14 (26)
48 | 431 ± 10 (50) | 438 ± 12 (44) | 437 ± 12 (44) | 426 ± 8 (48) | 419 ± 8 (48) | 424 ± 8 (45) | 418 ± 11 (26) | 439 ± 15 (26)
52 | 447 ± 10 (50) | 456 ± 13 (44) | 451 ± 12 (44) | 448 ± 8 (48) | 434 ± 9 (48) | 442 ± 9 (45) | 433 ± 12 (26) | 450 ± 15 (26)
56 | 463 ± 11 (50) | 474 ± 14 (44) | 463 ± 13 (44) | 466 ± 9 (47) | 449 ± 10 (48) | 457 ± 9 (45) | 450 ± 13 (26) | 459 ± 16 (25)
60 | 478 ± 12 (50) | 492 ± 15 (44) | 484 ± 14 (43) | 487 ± 10 (47) | 468 ± 11 (48) | 474 ± 10 (45) | 462 ± 13 (26) | 475 ± 18 (25)
64 | 495 ± 12 (49) | 510 ± 16 (44) | 502 ± 15 (42) | 504 ± 10 (47) | 477 ± 11 (44) | 491 ± 10 (45) | 477 ± 14 (26) | 485 ± 20 (25)
68 | 506 ± 12 (47) | 532 ± 17 (44) | 519 ± 16 (41) | 528 ± 11 (46) | 489 ± 13 (39) | 506 ± 11 (44) | 497 ± 15 (24) | 492 ± 23 (24)
72 | 520 ± 14 (44) | 544 ± 18 (43) | 544 ± 18 (38) | 547 ± 11 (44) | 497 ± 12 (36) | 520 ± 12 (42) | 521 ± 16 (21) | 506 ± 24 (22)
76 | 531 ± 16 (40) | 549 ± 19 (39) | 564 ± 21 (34) | 564 ± 13 (41) | 500 ± 12 (33) | 522 ± 12 (38) | 530 ± 19 (17) | 521 ± 26 (21)
80 | 542 ± 16 (39) | 562 ± 22 (34) | 560 ± 19 (26) | 571 ± 13 (40) | 514 ± 13 (31) | 537 ± 12 (33) | 544 ± 18 (15) | 531 ± 34 (17)
84 | 533 ± 15 (35) | 577 ± 24 (33) | 574 ± 20 (26) | 579 ± 15 (38) | 521 ± 14 (27) | 542 ± 14 (29) | 552 ± 20 (14) | 551 ± 40 (15)
88 | 534 ± 18 (32) | 584 ± 26 (31) | 585 ± 22 (24) | 588 ± 20 (27) | 527 ± 17 (24) | 556 ± 15 (28) | 539 ± 23 (13) | 564 ± 51 (11)
92 | 530 ± 15 (26) | 584 ± 22 (26) | 565 ± 21 (18) | 608 ± 23 (22) | 526 ± 19 (21) | 564 ± 16 (27) | 561 ± 22 (12) | 512 ± 27 (8)
96 | 531 ± 17 (23) | 604 ± 23 (22) | 594 ± 20 (16) | 616 ± 25* (19) | 540 ± 23 (18) | 569 ± 19 (21) | 563 ± 26 (10) | 525 ± 34 (7)
100 | 537 ± 21 (17) | 621 ± 26 (21) | 594 ± 16 (14) | 634 ± 32* (16) | 528 ± 17 (13) | 584 ± 18 (17) | 597 ± 34 (7) | 542 ± 36 (6)
104 | 534 ± 22 (17) | 619 ± 28 (18) | 607 ± 18 (13) | 622 ± 36* (12) | 524 ± 22 (11) | 597 ± 34 (9) | 602 ± 35 (7) | 562 ± 50 (4)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXV. Significant effects are indicated with asterisks (*, p < 0.05).

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods), the mean for week 8, 25,000 μg BPA/kg bw/day was significantly different (p = 0.031) from the vehicle control mean.

Table 26 Female Postwean Body Weights (g), Vehicle and BPA Stop-Dose, Interim (1 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
4 | 58 ± 3 (20) | 54 ± 3 (22) | 55 ± 3 (20) | 54 ± 2 (22) | 55 ± 3 (20) | 51 ± 2 (22)
8 | 192 ± 5 (20) | 184 ± 3 (22) | 190 ± 4 (20) | 190 ± 5 (22) | 188 ± 5 (20) | 184 ± 4 (21)
12 | 270 ± 7 (20) | 263 ± 5 (20) | 270 ± 7 (20) | 266 ± 6 (22) | 272 ± 8 (20) | 262 ± 6 (21)
16 | 304 ± 11 (18) | 302 ± 5 (22) | 305 ± 9 (20) | 305 ± 7 (22) | 310 ± 8 (20) | 303 ± 8 (21)
20 | 331 ± 11 (20) | 329 ± 7 (22) | 328 ± 10 (20) | 330 ± 8 (22) | 338 ± 10 (20) | 326 ± 8 (21)
24 | 351 ± 12 (20) | 350 ± 8 (22) | 344 ± 11 (20) | 348 ± 8 (22) | 358 ± 12 (20) | 344 ± 9 (21)
28 | 369 ± 12 (20) | 366 ± 9 (22) | 360 ± 12 (20) | 368 ± 10 (22) | 373 ± 14 (20) | 361 ± 9 (21)
32 | 386 ± 14 (20) | 391 ± 10 (20) | 374 ± 13 (20) | 381 ± 11 (22) | 392 ± 15 (20) | 374 ± 10 (21)
36 | 400 ± 14 (20) | 399 ± 10 (22) | 389 ± 15 (20) | 399 ± 13 (22) | 404 ± 15 (20) | 386 ± 10 (21)
40 | 410 ± 16 (18) | 419 ± 12 (22) | 404 ± 16 (20) | 418 ± 15 (20) | 421 ± 17 (20) | 407 ± 12 (20)
44 | 439 ± 17 (20) | 433 ± 12 (22) | 419 ± 16 (20) | 431 ± 16 (22) | 438 ± 18 (20) | 420 ± 12 (20)
48 | 459 ± 18 (20) | 453 ± 14 (22) | 436 ± 17 (20) | 449 ± 18 (22) | 452 ± 18 (20) | 440 ± 13 (20)
52 | 477 ± 19 (20) | 468 ± 14 (22) | 450 ± 19 (20) | 468 ± 20 (22) | 466 ± 19 (20) | 455 ± 14 (20)

^a^ BPA doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXIV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIV. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

Table 27 Female Postwean Body Weights (g), Vehicle and BPA Stop-Dose, Terminal (2 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
4 | 57 ± 2* (50) | 56 ± 2 (50) | 54 ± 2 (48) | 53 ± 1 (50) | 52 ± 2^b^ (50) | 54 ± 1 (46)
8 | 190 ± 4 (50) | 190 ± 2 (50) | 189 ± 2 (48) | 193 ± 2 (50) | 187 ± 4 (50) | 190 ± 2 (46)
12 | 270 ± 5 (50) | 270 ± 3 (50) | 268 ± 3 (48) | 271 ± 4 (50) | 267 ± 5 (50) | 270 ± 4 (46)
16 | 312 ± 7 (50) | 312 ± 4 (50) | 307 ± 5 (48) | 310 ± 5 (50) | 305 ± 6 (50) | 311 ± 5 (46)
20 | 338 ± 8 (50) | 339 ± 5 (50) | 330 ± 5 (46) | 334 ± 5 (50) | 330 ± 7 (50) | 338 ± 5 (46)
24 | 359 ± 8 (50) | 361 ± 5 (50) | 349 ± 6 (48) | 353 ± 6 (50) | 350 ± 7 (49) | 358 ± 6 (46)
28 | 379 ± 10 (50) | 375 ± 6 (50) | 365 ± 7 (48) | 370 ± 7 (50) | 366 ± 8 (49) | 376 ± 6 (46)
32 | 393 ± 10 (50) | 393 ± 6 (48) | 380 ± 7 (48) | 384 ± 8 (50) | 381 ± 8 (49) | 392 ± 7 (46)
36 | 409 ± 10 (50) | 409 ± 7 (50) | 397 ± 8 (48) | 403 ± 9 (50) | 394 ± 9 (49) | 409 ± 8 (46)
40 | 420 ± 11 (43) | 428 ± 8 (47) | 414 ± 9 (44) | 418 ± 10 (44) | 411 ± 10 (47) | 427 ± 9 (44)
44 | 436 ± 11 (47) | 446 ± 9 (50) | 426 ± 9 (48) | 435 ± 10 (50) | 426 ± 10 (48) | 445 ± 9 (46)
48 | 457 ± 12 (49) | 466 ± 10 (50) | 446 ± 10 (48) | 451 ± 10 (50) | 444 ± 11 (49) | 463 ± 10 (46)
52 | 479 ± 12 (49) | 489 ± 10 (49) | 462 ± 10 (47) | 474 ± 11 (50) | 459 ± 11 (49) | 477 ± 11 (46)
56 | 497 ± 13 (49) | 506 ± 10 (49) | 482 ± 11 (47) | 496 ± 12 (50) | 480 ± 12 (49) | 495 ± 12 (45)
60 | 516 ± 14 (48) | 524 ± 11 (46) | 502 ± 11 (47) | 515 ± 12 (50) | 496 ± 12 (48) | 513 ± 14 (44)
64 | 536 ± 15 (48) | 549 ± 13 (45) | 520 ± 12 (47) | 537 ± 12 (50) | 517 ± 13 (48) | 533 ± 15 (43)
68 | 558 ± 16 (47) | 573 ± 13 (44) | 540 ± 13 (43) | 546 ± 13 (46) | 537 ± 14 (47) | 550 ± 15 (39)
72 | 571 ± 18 (44) | 580 ± 13 (39) | 552 ± 14 (41) | 561 ± 14 (44) | 556 ± 16 (45) | 552 ± 14 (35)
76 | 570 ± 19 (36) | 598 ± 14 (40) | 568 ± 15 (39) | 574 ± 15 (41) | 568 ± 16 (41) | 575 ± 16 (35)
80 | 576 ± 18 (34) | 619 ± 15 (39) | 575 ± 15 (35) | 586 ± 18 (36) | 580 ± 17 (38) | 589 ± 16 (35)
84 | 588 ± 21 (31) | 633 ± 18 (32) | 601 ± 18 (30) | 605 ± 19 (34) | 591 ± 19 (36) | 604 ± 19 (31)
88 | 595 ± 22 (28) | 624 ± 20 (26) | 599 ± 18 (26) | 614 ± 22 (31) | 606 ± 21 (33) | 613 ± 20 (29)
92 | 591 ± 28 (23) | 626 ± 23 (20) | 590 ± 21 (20) | 626 ± 24 (28) | 609 ± 24 (31) | 625 ± 22 (26)
96 | 600 ± 33 (20) | 608 ± 20 (16) | 595 ± 25 (16) | 651 ± 29 (23) | 633 ± 28 (24) | 616 ± 24 (22)
100 | 600 ± 30 (17) | 625 ± 21 (16) | 614 ± 28 (15) | 650 ± 37 (18) | 614 ± 34 (19) | 610 ± 29 (17)
104 | 608 ± 45 (11) | 631 ± 23 (13) | 595 ± 25 (13) | 630 ± 39 (13) | 641 ± 35 (17) | 623 ± 35 (13)

^a^ BPA doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXV. The only significant effect is indicated with an asterisk (dose trend, week 4, p = 0.037).

^b^ In the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods), the mean for week 4, 2,500 μg BPA/kg bw/day was significantly different (approximately 12% lower, p = 0.016) from the vehicle control mean.

Table 28 Male Postwean Body Weights (g), Vehicle, BPA, and EE_2_ Continuous-Dose, Interim (1 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
4 | 84 ± 2 (22) | 83 ± 2 (22) | 85 ± 2 (20) | 81 ± 2 (24) | 83 ± 2 (20) | 80 ± 1 (22) | 84 ± 2 (26) | 88 ± 2 (26)
8 | 298 ± 7 (22) | 299 ± 7 (22) | 296 ± 7 (20) | 288 ± 7 (24) | 296 ± 8 (20) | 290 ± 5 (21) | 298 ± 7 (26) | 304 ± 5 (26)
12 | 424 ± 9 (22) | 429 ± 8 (22) | 429 ± 10 (20) | 416 ± 8 (24) | 426 ± 11 (20) | 417 ± 8 (21) | 431 ± 9 (26) | 437 ± 6 (26)
16 | 494 ± 10 (22) | 505 ± 9 (22) | 500 ± 11 (20) | 490 ± 8 (24) | 496 ± 12 (20) | 484 ± 9 (21) | 504 ± 10 (26) | 505 ± 8 (26)
20 | 540 ± 10 (22) | 554 ± 11 (22) | 553 ± 13 (19) | 541 ± 10 (24) | 542 ± 13 (20) | 532 ± 10 (21) | 551 ± 12 (25) | 550 ± 10 (24)
24 | 578 ± 12 (22) | 590 ± 12 (22) | 586 ± 14 (19) | 576 ± 12 (24) | 579 ± 14 (20) | 568 ± 12 (21) | 588 ± 13 (25) | 584 ± 9 (26)
28 | 604 ± 13 (21) | 621 ± 12 (22) | 612 ± 15 (19) | 607 ± 12 (24) | 610 ± 16 (20) | 596 ± 13 (21) | 613 ± 14 (25) | 611 ± 10 (26)
32 | 627 ± 14 (21) | 643 ± 13 (22) | 636 ± 16 (19) | 633 ± 12 (24) | 635 ± 18 (20) | 620 ± 14 (21) | 636 ± 14 (25) | 634 ± 10 (26)
36 | 645 ± 15 (21) | 667 ± 14 (22) | 653 ± 17 (19) | 653 ± 13 (24) | 656 ± 19 (20) | 639 ± 14 (21) | 660 ± 15 (25) | 652 ± 12 (25)
40 | 664 ± 17 (20) | 690 ± 16 (22) | 673 ± 18 (19) | 674 ± 14 (24) | 675 ± 21 (19) | 659 ± 15 (21) | 681 ± 16 (24) | 673 ± 13 (25)
44 | 688 ± 16 (19) | 707 ± 17 (22) | 689 ± 19 (19) | 691 ± 14 (24) | 693 ± 21 (19) | 676 ± 17 (21) | 697 ± 17 (25) | 687 ± 13 (25)
48 | 702 ± 18 (19) | 724 ± 20 (22) | 715 ± 20 (18) | 712 ± 15 (24) | 706 ± 24 (18) | 693 ± 17 (21) | 712 ± 19 (24) | 715 ± 14 (23)
52 | 720 ± 20 (18) | 742 ± 21 (22) | 729 ± 22 (18) | 732 ± 16 (24) | 724 ± 26 (18) | 714 ± 19 (21) | 730 ± 21 (22) | 724 ± 16 (23)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXIV. Analyses were conducted separately for BPA and EE_2_ dose groups. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIV. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

Table 29 Male Postwean Body Weights (g), Vehicle, BPA, And EE_2_ Continuous-Dose, Terminal (2 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA | 0.05 EE_2_ | 0.5 EE_2_
4 | 84 ± 1 (50) | 84 ± 1 (48) | 86 ± 1 (48) | 84 ± 1 (50) | 82 ± 1 (50) | 85 ± 1 (46) | 82 ± 2 (26) | 88 ± 2 (26)
8 | 295 ± 4 (50) | 302 ± 4 (48) | 297 ± 4 (48) | 290 ± 4 (50) | 292 ± 4 (50) | 305 ± 4 (46) | 297 ± 5 (26) | 306 ± 5 (26)
12 | 429 ± 7 (49) | 434 ± 5 (47) | 425 ± 5 (48) | 419 ± 5 (50) | 420 ± 5 (50) | 435 ± 5 (46) | 428 ± 8 (26) | 431 ± 8 (26)
16 | 503 ± 10 (49) | 506 ± 6 (47) | 496 ± 6 (48) | 492 ± 6 (50) | 496 ± 6 (50) | 505 ± 6 (46) | 504 ± 10 (26) | 502 ± 10 (26)
20 | 550 ± 11 (49) | 554 ± 7 (45) | 546 ± 8 (48) | 543 ± 6 (50) | 543 ± 7 (50) | 552 ± 6 (46) | 553 ± 11 (26) | 549 ± 12 (26)
24 | 586 ± 12 (49) | 591 ± 7 (47) | 583 ± 8 (48) | 581 ± 7 (50) | 577 ± 8 (50) | 586 ± 7 (46) | 586 ± 13 (26) | 581 ± 11 (26)
28 | 614 ± 14 (49) | 620 ± 8 (46) | 609 ± 9 (48) | 612 ± 7 (50) | 603 ± 9 (50) | 614 ± 8 (46) | 614 ± 13 (26) | 608 ± 13 (24)
32 | 639 ± 16 (49) | 643 ± 9 (46) | 631 ± 10 (48) | 641 ± 8 (50) | 625 ± 9 (50) | 637 ± 8 (46) | 637 ± 14 (26) | 632 ± 13 (26)
36 | 647 ± 10 (48) | 663 ± 10 (46) | 654 ± 10 (47) | 661 ± 9 (50) | 643 ± 9 (50) | 656 ± 9 (46) | 658 ± 16 (26) | 655 ± 14 (26)
40 | 667 ± 10 (48) | 685 ± 10 (46) | 672 ± 11 (48) | 682 ± 10 (49) | 660 ± 9 (50) | 674 ± 9 (46) | 678 ± 16 (26) | 673 ± 15 (26)
44 | 684 ± 11 (47) | 700 ± 10 (45) | 691 ± 12 (47) | 703 ± 11 (49) | 678 ± 10 (49) | 687 ± 10 (46) | 696 ± 17 (26) | 692 ± 16 (26)
48 | 700 ± 12 (47) | 717 ± 11 (45) | 707 ± 13 (47) | 729 ± 11 (48) | 696 ± 10 (49) | 707 ± 10 (44) | 712 ± 18 (26) | 710 ± 17 (26)
52 | 719 ± 13 (47) | 732 ± 12 (45) | 719 ± 12 (44) | 746 ± 10 (47) | 712 ± 11 (48) | 727 ± 11 (43) | 726 ± 20 (26) | 726 ± 18 (26)
56 | 736 ± 13 (47) | 750 ± 13 (45) | 745 ± 14 (46) | 765 ± 11 (46) | 726 ± 12 (47) | 750 ± 12 (41) | 754 ± 20 (24) | 742 ± 18 (26)
60 | 748 ± 13 (47) | 768 ± 13 (45) | 756 ± 16 (45) | 784 ± 12 (45) | 743 ± 12 (46) | 770 ± 13 (40) | 783 ± 19 (23) | 760 ± 18 (26)
64 | 765 ± 14 (46) | 791 ± 14 (44) | 779 ± 17 (44) | 803 ± 13 (45) | 755 ± 14 (46) | 791 ± 14 (40) | 803 ± 21 (23) | 771 ± 20 (25)
68 | 783 ± 15 (45) | 805 ± 14 (42) | 800 ± 19 (44) | 818 ± 14 (43) | 784 ± 15 (43) | 815 ± 16 (37) | 828 ± 22 (22) | 788 ± 26 (24)
72 | 792 ± 17 (42) | 821 ± 15 (41) | 822 ± 20 (40) | 838 ± 15 (40) | 799 ± 16 (42) | 832 ± 17 (37) | 848 ± 24 (22) | 806 ± 24 (22)
76 | 801 ± 19 (41) | 840 ± 16 (40) | 842 ± 20 (39) | 858 ± 15 (39) | 817 ± 17 (40) | 848 ± 19 (34) | 864 ± 24 (22) | 832 ± 24 (21)
80 | 819 ± 19 (38) | 858 ± 18 (38) | 846 ± 22 (36) | 868 ± 17 (39) | 828 ± 17 (37) | 862 ± 20 (31) | 873 ± 27 (20) | 855 ± 25 (20)
84 | 827 ± 21 (34) | 867 ± 19 (37) | 858 ± 25 (29) | 890 ± 19 (36) | 833 ± 16 (33) | 875 ± 21 (29) | 889 ± 29 (18) | 854 ± 25 (19)
88 | 826 ± 23 (30) | 865 ± 19 (35) | 867 ± 25 (27) | 894 ± 20 (31) | 829 ± 18 (30) | 871 ± 21 (25) | 917 ± 28 (15) | 870 ± 27 (16)
92 | 823 ± 27 (26) | 858 ± 22 (31) | 873 ± 26 (25) | 905 ± 24 (24) | 819 ± 17 (27) | 868 ± 22 (24) | 925 ± 31 (14) | 872 ± 27 (17)
96 | 831 ± 30 (23) | 864 ± 24 (25) | 883 ± 23 (22) | 914 ± 24 (24) | 834 ± 19 (24) | 860 ± 27 (16) | 925 ± 34 (13) | 873 ± 28 (16)
100 | 823 ± 36 (20) | 854 ± 26 (21) | 856 ± 25 (19) | 904 ± 29 (22) | 846 ± 22 (20) | 894 ± 23 (14) | 926 ± 42 (10) | 888 ± 30 (15)
104 | 818 ± 40 (18) | 877 ± 25 (16) | 847 ± 30 (17) | 946 ± 36 (14) | 842 ± 22 (16) | 864 ± 12 (12) | 901 ± 53 (9) | 853 ± 23 (13)

^a^ BPA and EE_2_ doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXV. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

Table 30 Male Postwean Body Weights (g), Vehicle and BPA Stop-Dose, Interim (1 Year) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
4 | 61 ± 2 (20) | 58 ± 3 (20) | 59 ± 3 (20) | 60 ± 3 (19) | 57 ± 3 (20) | 61 ± 2 (22)
8 | 274 ± 7 (20) | 269 ± 8 (20) | 271 ± 6 (20) | 270 ± 9 (19) | 261 ± 6 (20) | 277 ± 4 (22)
12 | 424 ± 11 (20) | 432 ± 9 (20) | 426 ± 7 (20) | 430 ± 12 (19) | 413 ± 8 (20) | 436 ± 8 (22)
16 | 505 ± 14 (20) | 529 ± 12 (20) | 512 ± 9 (20) | 515 ± 14 (19) | 503 ± 11 (20) | 522 ± 9 (22)
20 | 561 ± 15 (20) | 587 ± 14 (20) | 572 ± 11 (19) | 566 ± 15 (19) | 560 ± 12 (20) | 581 ± 10 (22)
24 | 597 ± 16 (20) | 628 ± 16 (20) | 610 ± 12 (19) | 603 ± 16 (19) | 593 ± 11 (20) | 618 ± 11 (22)
28 | 627 ± 18 (20) | 658 ± 17 (20) | 642 ± 14 (18) | 630 ± 17 (19) | 623 ± 14 (20) | 645 ± 12 (22)
32 | 652 ± 19 (20) | 685 ± 18 (20) | 671 ± 15 (19) | 655 ± 18 (19) | 651 ± 15 (20) | 667 ± 12 (22)
36 | 675 ± 21 (20) | 710 ± 19 (20) | 701 ± 18 (17) | 677 ± 19 (19) | 674 ± 17 (20) | 685 ± 13 (22)
40 | 684 ± 22 (18) | 737 ± 21 (19) | 717 ± 18 (19) | 687 ± 18 (18) | 692 ± 18 (20) | 709 ± 14 (22)
44 | 717 ± 23 (20) | 761 ± 21 (20) | 738 ± 19 (19) | 716 ± 20 (19) | 712 ± 19 (20) | 726 ± 15 (22)
48 | 731 ± 25 (20) | 783 ± 23 (19) | 758 ± 22 (19) | 735 ± 22 (19) | 735 ± 20 (20) | 743 ± 16 (22)
52 | 753 ± 26 (20) | 803 ± 23 (20) | 775 ± 23 (19) | 743 ± 23 (18) | 751 ± 22 (20) | 759 ± 17 (22)

^a^ BPA doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXIV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXIV. There were no statistically significant trends or pairwise comparisons to controls. There were also no significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

Table 31 Male Postwean Body Weights (g), Vehicle and BPA Stop-Dose, Terminal (2 Years) Sacrifice (Mean ± S.E.M.)^a^

Week | Vehicle | 2.5 BPA | 25 BPA | 250 BPA | 2500 BPA | 25000 BPA
4 | 61 ± 2* (50) | 60 ± 2 (48) | 59 ± 2 (48) | 56 ± 2 (50) | 58 ± 2 (50) | 57 ± 2 (46)
8 | 270 ± 4 (49) | 273 ± 5 (48) | 281 ± 4 (48) | 279 ± 4 (50) | 271 ± 4 (50) | 268 ± 5 (46)
12 | 428 ± 5 (49) | 425 ± 6 (48) | 437 ± 6 (48) | 433 ± 5 (50) | 426 ± 6 (50) | 428 ± 7 (46)
16 | 509 ± 6 (49) | 508 ± 7 (48) | 522 ± 8 (48) | 515 ± 7 (50) | 511 ± 6 (50) | 515 ± 8 (46)
20 | 567 ± 6 (49) | 564 ± 8 (48) | 582 ± 10 (48) | 572 ± 8 (50) | 569 ± 7 (50) | 574 ± 9 (43)
24 | 606 ± 7 (49) | 602 ± 9 (48) | 619 ± 10 (48) | 613 ± 9 (50) | 608 ± 8 (49) | 612 ± 10 (45)
28 | 637 ± 8 (48) | 630 ± 10 (48) | 648 ± 11 (45) | 642 ± 10 (50) | 635 ± 8 (49) | 639 ± 10 (45)
32 | 664 ± 9 (47) | 655 ± 10 (48) | 673 ± 12 (48) | 665 ± 10 (50) | 661 ± 9 (49) | 664 ± 11 (45)
36 | 688 ± 10 (49) | 681 ± 11 (48) | 698 ± 12 (48) | 687 ± 11 (50) | 683 ± 9 (49) | 688 ± 12 (45)
40 | 704 ± 10 (47) | 695 ± 11 (44) | 724 ± 14 (44) | 705 ± 14 (44) | 700 ± 10 (46) | 710 ± 14 (42)
44 | 732 ± 12 (46) | 724 ± 12 (48) | 746 ± 14 (47) | 731 ± 14 (50) | 723 ± 10 (48) | 732 ± 15 (43)
48 | 752 ± 12 (49) | 745 ± 13 (48) | 763 ± 15 (48) | 749 ± 15 (50) | 744 ± 11 (49) | 755 ± 16 (43)
52 | 772 ± 13 (49) | 763 ± 14 (47) | 781 ± 15 (48) | 757 ± 14 (49) | 756 ± 12 (49) | 770 ± 17 (43)
56 | 789 ± 14 (49) | 778 ± 15 (47) | 800 ± 16 (48) | 773 ± 15 (49) | 778 ± 13 (49) | 792 ± 18 (42)
60 | 811 ± 15 (48) | 799 ± 17 (46) | 813 ± 17 (46) | 798 ± 16 (46) | 793 ± 14 (49) | 810 ± 19 (42)
64 | 831 ± 16 (48) | 815 ± 16 (44) | 832 ± 18 (46) | 816 ± 17 (45) | 815 ± 15 (47) | 826 ± 20 (42)
68 | 855 ± 16 (46) | 834 ± 18 (43) | 846 ± 19 (46) | 837 ± 17 (45) | 836 ± 16 (45) | 848 ± 22 (39)
72 | 874 ± 17 (46) | 851 ± 19 (42) | 861 ± 22 (43) | 837 ± 19 (42) | 858 ± 18 (44) | 866 ± 22 (35)
76 | 884 ± 17 (44) | 870 ± 21 (39) | 896 ± 22 (40) | 874 ± 19 (37) | 869 ± 18 (41) | 878 ± 24 (34)
80 | 888 ± 18 (43) | 883 ± 23 (39) | 913 ± 25 (38) | 892 ± 22 (33) | 875 ± 20 (40) | 893 ± 30 (29)
84 | 896 ± 17 (39) | 873 ± 22 (35) | 920 ± 25 (36) | 895 ± 24 (30) | 879 ± 18 (37) | 915 ± 32 (26)
88 | 906 ± 18 (37) | 885 ± 26 (31) | 932 ± 23 (33) | 908 ± 30 (26) | 874 ± 21 (34) | 918 ± 34 (23)
92 | 903 ± 16 (32) | 879 ± 25 (27) | 911 ± 22 (31) | 935 ± 35 (21) | 887 ± 23 (30) | 955 ± 28 (20)
96 | 903 ± 19 (29) | 874 ± 28 (25) | 901 ± 26 (27) | 941 ± 44 (17) | 884 ± 27 (27) | 925 ± 30 (16)
100 | 928 ± 20 (21) | 876 ± 29 (18) | 893 ± 30 (21) | 953 ± 49 (13) | 878 ± 26 (25) | 932 ± 31 (14)
104 | 908 ± 23 (16) | 845 ± 30 (16) | 908 ± 33 (16) | 941 ± 45 (13) | 863 ± 33 (16) | 894 ± 37 (10)

^a^ BPA doses are μg/kg bw/day. Numbers of litters are shown in parentheses. Outlier identification and exclusion are described in Materials and Methods and Supplemental Appendix XXV. Pairwise comparisons of means were performed using contrasts within a two-way repeated measures, mixed model ANOVA. Model terms were treatment group, weeks, and the interaction. Within-group correlations were modeled using a heterogeneous first-order autoregressive (ARH(1)) correlation structure, which allows for correlated differences in variability across time points. Tests of trends, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Pairwise comparisons of treatment groups to the vehicle control group were conducted with Dunnett’s method to adjust for multiple comparisons. All tests were performed as two-sided tests at the 0.05 significance level. Full results of the analyses are presented in Supplemental Appendix XXV. The only significant effect is indicated with an asterisk (dose trend, week 4, p = 0.043). There were no additional significant treatment effects in the sensitivity analysis that excluded all animals that overlapped with animals treated with 250,000 μg BPA/kg bw/day (see Materials and Methods, Statistical Methods).

### Implantation Sites and Litter Parameters (Supplemental Appendices XVIII and XIX)

Implantation site counts and litter weight data were analyzed using a one-way ANOVA and litter mean pup weights were analyzed using contrasts within an ANOCOVA, with litter size as a covariate, to test for treatment effect. Dunnett’s test was used for comparisons to the vehicle control group to adjust for multiple comparisons. Sex ratios of pups within litters were analyzed for treatment effects using logistic regression. Pup counts (number alive, males, females, number unsexed (i.e., pups that could not be definitively assigned as male or female), and number born dead) were analyzed using Poisson regression. For analyses of sex proportions and female and male counts, unsexed pups were assigned either as male sex or female sex in separate runs with comparable results (Supplemental Appendix XIX).

### Analyses of Vaginal Opening, Vaginal Cytology, and Onset of Aberrant Estrous Cycles (Supplemental Appendices XXVI-XXVIII)

Analyses of age and body weight at occurrence of vaginal opening were performed using contrasts within a one-way ANOVA to test for treatment effect. Comparisons of dosed groups to vehicle control for age and body weight were performed with Dunnett’s method to adjust for multiple comparisons.

Summary statistics were calculated for proportions of days spent in estrus, diestrus, and proestrus for each animal and for estrous cycle length. Cycle length in days was defined from the first day of estrus in one sequence of contiguous days to the first day of estrus in the following sequence of stages. Cycles were considered censored if the last stage of data collection was either diestrus or proestrus.

Analyses were conducted on proportions of animals with abnormal cycles. The endpoints evaluated were any abnormal cycling, extended estrus, extended diestrus, and excessive proestrus. Extended estrus was defined as three or more consecutive days of estrus; extended diestrus was defined as four or more consecutive days of diestrus; and excessive proestrus was defined as two or more consecutive days of proestrus in a cycle. For abnormal cycling defined by animal, the Cochran-Armitage method for binomial proportions was used to evaluate the pairwise differences in proportions. The two-sided p-value for the Fisher’s exact test is reported for comparisons of dosed groups to control, and the one-sided Cochran-Armitage trend test was performed. Holm’s (step-down Bonferroni) method was used to adjust for multiple pairwise comparisons of dosed groups to control.

An accelerated failure time model assuming a lognormal distribution was used for onset of aberrant cycling, which was defined as occurring at first swab date of two consecutive months of aberrant estrous cycle data. An aberrant estrous cycle was defined as three or more consecutive days of estrus or five consecutive days without estrus. The data for this endpoint contained left-, right-, and interval-censored data, which can all be accommodated by the accelerated failure time model used. Left censoring occurred because some animals had begun to show aberrant cycles prior to the start of monitoring, while right censoring occurred because some animals died or reached the end of the study without showing aberrant cycles. The intermittent nature of the data collection, one 5-day period every month, makes it impossible to determine the exact time of onset of aberrant cycles, so the data are interval censored. Multiple comparisons were adjusted using Holm’s (step-down Bonferroni) method for treatment group comparisons to the control group.

### Organ Weight Analyses (Supplemental Appendix XXX)

Statistical analyses were performed separately for the BPA study arms, stop-dose and continuous-dose, and for the EE_2_ continuous-dose arm in one-year interim sacrifice rats. Weights of paired organs were analyzed as combined weight. ANOVA was performed for each sex and organ to determine the effect of treatment on organ weight. ANOCOVA was performed to determine the effect of treatment on organ weight adjusted for body weight at necropsy or brain weight. Separate analyses were performed with each covariate. Comparisons of dosed groups versus vehicle control were performed using Dunnett’s method for adjusted contrasts. Tests of trend, increasing treatment effect with increasing dose, were performed for the BPA and vehicle control groups. Organ weight exclusions based on the observation of gross cysts or consideration of statistical distributions are listed in Supplemental Appendix XXX.

### Clinical Chemistry and Hematology Analyses (Supplemental Appendix XXIX)

A non-parametric ANOVA method based on mid-ranks was used to evaluate the effect of treatment on clinical chemistry and hematology assessments assuming an unstructured covariance.^45^ The average of the left and right ranks was used for ties. Dunnett’s adjustment was used for pairwise multiple comparisons relative to the control. Orthogonal contrasts were used to test for trends over increasing BPA dose concentrations. Any measurements below the limit of detection (LOD) were evaluated at half the LOD level.

### Sperm Parameter Analyses (Supplemental Appendix XXXI)

Analysis of sperm morphology data was performed using a generalized linear model with a Poisson distribution and a log link function. Each treatment was compared to the vehicle control group, and adjustment for multiple comparisons was performed using Dunnett’s method. Percent sperm motility, testes sperm counts, and caudal sperm counts were analyzed using an ANOVA model with Kenward-Roger estimated degrees of freedom.^46^ Each treatment was compared to the control group, and adjustment for multiple comparisons was performed using Dunnett’s method. Tests of trends, increasing treatment effect with increasing dose, were performed for each compound and dosing arm.

### Analyses of Non-Neoplastic and Neoplastic Lesions, Interim and Terminal Sacrifice (Supplemental Appendices XXXIII and XXXIV)

Microscopic findings were recorded in NTP’s automated Toxicology Data Management System Enterprise. For the statistical analyses of groups with 20−26 animals (all interim sacrifice groups and EE_2_ terminal sacrifice groups), any lesion present in at least two animals in any dose group was included in the analyses. In groups with 46−50 animals (all terminal sacrifice vehicle control and BPA groups), any lesion present in at least four animals in any dose group was included in the analyses.

The NTP-preferred approach to assess neoplastic and non-neoplastic lesion prevalence is a survival-adjusted quantal-response procedure (see description of Poly-3 test below) that modifies the Cochran-Armitage linear trend test to take survival differences into account (h[underlined: ttps://ntp.niehs.nih.gov/testing/types/stats/index.html]). For neoplasm and non-neoplasm incidence for interim sacrifice animals, where early removals or deaths were few, the Cochran-Armitage test, without survival adjustment, was used to test for a linear dose trend, with the Fisher’s exact test used to compare dosed groups to the vehicle control. This combination of tests is referred to as CAFE. For neoplasm and non-neoplasm incidence for terminal sacrifice animals, the Poly-3 method of Bailer and Portier,^47^ as modified by Bieler and Williams,^48^ and the NIEHS continuity-correction, discussed in Peddada and Kissling,^49^ was used to analyze age-adjusted incidence for linear dose trend and for pairwise comparisons to the vehicle control. For both the analysis of interim and terminal neoplasm and non-neoplasm incidences, tests were one-sided for treatment comparisons to the vehicle control group with no adjustment for multiple comparisons to the vehicle control, while the trend test was two-sided.

Lesion severities, ordinal scores provided by the Study Pathologist, were available for many of the non-neoplastic lesions. Although these scores are more subjective than the lesion incidences, statistical tests were run to include this additional information with the incidence data. The Jonckheere-Terpstra test^50,51^ was run to test for monotonic dose trends, followed by Shirley’s test^52,53^ to compare to controls. This combination of tests is referred to as JT/SW, and it presumes a monotonic dose response. One aspect of this study was to consider potential non-monotonic effects, which would be detected by the pairwise comparisons. JT/SW is blind to this effect. Therefore, a test not typically used in NTP studies, the non-parametric relative treatment effect (RTE) method^45^ was used to test for non-monotonic dose effects. While the results of the JT/SW and RTE tests are presented in the summary tables and in the statistical appendices (Supplemental Appendices XXXIII and XXXIV), the CAFE and Poly-3 tests are the primary tests to be considered both because of the nature of the severity scores and, in the case of terminal sacrifice, because the JT/SW and RTE tests are not mortality adjusted.

A subset of lesions is discussed and tabulated in the body of this report. Comprehensive tabulations of all statistical results, including the JT/SW and RTE test results, for all lesions diagnosed in the study are found in Supplemental Appendices XXXIII and XXXIV.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. Historical control data, however, are often helpful in interpreting potential treatment-related effects. Although these historical control data are generally most useful for uncommon or rare neoplasms, they can be useful for assessing the range of background lesions in the animal strain used as part of the weight-of-evidence consideration of whether an observed lesion is treatment related. For meaningful comparisons, the conditions for studies used for historical control comparisons generally should be similar. In the case of the present study, two two-year studies conducted with the Sprague-Dawley/CD23/Nctr BR rat using the same diet used in the present study have been conducted.^14,16^ These were multigenerational studies in which animals in the F_1_ and F_3_ generations were evaluated at two years of age. Thus, each study had two sets of control animals of both sexes. These were dietary administration studies, rather than gavage studies, and were conducted outside the five-year period generally used for such comparisons, although drift in neoplasm incidence over time can vary among strain and neoplasm type.^54,55^ Historical incidences of neoplasms (mean percentages and ranges) from these studies are referenced in the Results and Discussion sections.

### Sensitivity Analyses

In the present study, approximately 20% of the animals were housed for a short period early in the study in the same room as animals dosed with 250,000 μg BPA/kg bw/day exclusively for a CLARITY-BPA grantee study. These animals were potentially exposed to low levels of BPA, leading to blood levels of BPA metabolites above the LOD and similar to those resulting from the 2.5 μg BPA/kg bw/day dose^12^ (Supplemental Appendix XVI). Animals co-housed only with the high dose from the two-year study (25,000 μg BPA/kg bw/day) had no detectable BPA metabolites in their blood.^12^ As a conservative approach to determine if this low-level exposure to a subset of animals impacted the interpretation of study results, a sensitivity analysis was conducted for each endpoint. In the sensitivity analysis, all animals that for any portion of their lives were co-housed in the same room as the subset of animals treated with the 250,000 μg BPA/kg bw/day dose were excluded. Any significant effects found in the sensitivity analysis that were not found in the analysis that included all animals are noted in data tables and in the statistical appendices (Supplemental Appendices XVII-XXXI, XXXIII, and XXXIV). Only those animals involved in or resulting from the first mating were co-housed at any point in their lives with the animals dosed with 250,000 μg BPA/kg bw/day. Thus, the sensitivity analyses that were conducted after exclusion of all animals in the first mating removed all animals that potentially had exposure to BPA above that present in the diet. This included the subset of animals that had received a single dose of contaminated vehicle as adults (see above under “Preparation and Analysis of Dose Formulations” and Supplemental Appendix III, note to study file October 13, 2017).

## Quality Assurance

This study was conducted in compliance with the Food and Drug Administration (FDA) Good Laboratory Practice (GLP) for the conduct of nonclinical laboratory studies (United States Code of Federal Regulations Title 21, Part 58). The Quality Assurance Unit at NCTR performed audits and inspections of the protocols, procedures, data, and reports throughout the course of the study. Separate audits covering completeness and accuracy of the pathology data, pathology specimens, and final pathology tables, and a draft of this technical report were conducted. Audit procedures and findings are on file at NCTR. The audit findings were reviewed and assessed by the NCTR staff, and all comments were resolved or otherwise addressed either before or during the preparation of the technical report. Raw data sheets from the study are archived by NCTR’s Record Management Unit. Histopathology samples collected during the study are stored in the archives of Toxicologic Pathology Associates at NCTR. Backup computer data are maintained by the Computer Support Group at the NCTR. All records and samples are stored in accordance with FDA GLP Regulations.