# Background

Bisphenol A (BPA) is a high-production-volume industrial chemical that is used as a monomer in the production of polycarbonate plastics and epoxy resins that have broad applications in consumer products, including storage containers for foods and beverages and in medical devices. BPA has undergone extensive toxicological evaluations in laboratories around the world, but the conclusions derived from the aggregate results of the studies remain under debate. The current safety assessments by the preponderance of international regulatory agencies conclude that BPA at current exposure levels (upper 95^th^ percentile of typical daily aggregate exposure <0.5 μg/kg body weight (bw)/day) does not pose a risk to humans via dietary exposure.^1-4^ In contrast, others have concluded that the overall body of evidence from BPA investigations indicates that BPA is likely to be a human health hazard.^5-7^ France has banned the use of BPA in food contact materials based on the assessment of the French Agency for Food, Environmental Health and Safety.^8^ The Office of Environmental Health Hazard Assessment of the California Environmental Protection Agency has listed BPA as a reproductive toxicant under California’s Proposition 65.^9^

The National Toxicology Program (NTP) previously assessed BPA in two-year dietary administration studies in both sexes of F344 rats at feed concentrations of 1,000 and 2,000 ppm (approximately 50,000 and 100,000 μg BPA/kg bw/day), in male B6C3F_1_ mice at feed concentrations of 1,000 and 5,000 ppm (approximately 150,000 and 750,000 μg BPA/kg bw/day), and in female B6C3F_1_ mice at feed concentrations of 5,000 and 10,000 ppm (approximately 750,000 and 1,500,000 μg BPA/kg bw/day).^10^ The NTP conclusions from these studies were that there was no convincing evidence of carcinogenesis. The earlier NTP studies did not address the current issues of toxicities resulting from developmental exposures at levels closer to human exposure levels. Given the current public controversy, the NTP and the National Institute of Environmental Health Sciences (NIEHS) Division of Extramural Research and Training (DERT) agreed to sponsor a study that would involve exposures to a broad range of BPA doses, include developmental exposure, and, in addition to evaluating endpoints typically used for regulatory decision-making, provide animals or tissues from this study to a group of NIEHS-funded academic scientists to pursue hypothesis-driven studies in various organ systems. The purpose of this research program was to evaluate chronic exposure to BPA over a broad dose range using traditional and non-traditional endpoints. It aimed to determine if the non-traditional endpoints could reveal toxicity not detected by traditional guideline study endpoints and provide mechanistic support for observations made in the guideline study. For most of the hypothesis-driven studies, the academic scientists were provided by the Food and Drug Administration (FDA)’s National Center for Toxicological Research (NCTR) with tissues or serum from animals of various ages. The exceptions were behavioral and erectile dysfunction studies, where staff from the academic laboratories conducted the studies with animals at NCTR with the assistance of NCTR staff. Detailed descriptions of the general plan of this project, termed the Consortium Linking Academic and Regulatory Insights on BPA Toxicity (CLARITY-BPA), have been published.^11,12^ This report focuses only on the description of the conduct of and results from the core chronic study, which focused on standard toxicological endpoints.

## Animal Model

The animal model used in these studies was the Sprague-Dawley rat maintained at NCTR. This colony had its origins in the late 1970s from Charles River Sprague-Dawley founders and has been used in toxicology studies with hormonally active agents for over a decade at NCTR.^13-20^ A comprehensive evaluation of the pharmacokinetics of BPA in this rat strain across life stages, including upon oral exposure by gavage, has been conducted.^21-23^ Dietary ethinyl estradiol (EE_2_) exposure studies in this strain^15,16,18,20^ resulted in peak blood levels of EE_2_ in adult animals below 10 pg/mL (30 pM) at the highest dose tested (50-ppb feed concentration, or approximately 4 and 5-6 μg/kg bw/day in males and females, respectively).^24^ Stimulation of male mammary hyperplasia was observed at 2, 10, and 50 ppb dietary EE_2_ at postnatal day (PND) 140, but not in older animals (two years of age). Effects on vaginal opening, body weight gain, food efficiency, and estrous cyclicity were observed at the higher doses of 10 and 50 ppb, approximately 1 and 6 μg/kg bw/day, respectively. Similar, but not identical, effects were observed with dietary genistein over a dose range of 5 to 500 ppm (approximately 300 to 50,000 μg/kg bw/day).^18^ Taken together with the more recent gavage BPA and EE_2_ studies,^19,25^ these data demonstrate the relative sensitivity of this rat strain to estrogenic compounds.

## Rationale for Dose Selection for BPA and the Reference Estrogen, EE_2_

Prior to the design of this chronic toxicity study and the conception of the CLARITY-BPA project, a subchronic study was conducted at NCTR using the same animal model and dosing regimen used in the current chronic study.^19^ BPA in 0.3% carboxymethylcellulose (CMC) was administered by oral gavage to pregnant female Sprague-Dawley rats from gestation day (GD) 6 through the start of parturition, with seven doses between 2.5 and 2,700 μg BPA/kg bw/day spaced at half-log intervals. Two high doses of BPA (100,000 and 300,000 μg/kg bw/day) were added as doses expected to produce adverse effects based on published guideline studies.^26,27^ Vehicle and naïve (not dosed by gavage) controls were included. Dams were not dosed after their litters were born, but pups were directly dosed by oral gavage from PND 1 until termination (PND 90 ± 5). Pups were directly dosed because of the demonstrated low transmission of BPA to pups via milk.^28^ BPA showed clearly adverse effects in F_1_ females at the highest doses of 100,000 and 300,000 μg BPA/kg bw/day. Statistically significant differences at lower BPA doses were few and sporadic and were judged not to provide evidence of BPA-induced toxicity.^19^ There were no BPA effects observed in the males.

The design of the CLARITY-BPA core study was discussed and finalized at a series of meetings in late 2011 and early 2012. These meetings included NTP, NCTR, NIEHS/DERT, and FDA product center representatives, as well as NIEHS-funded CLARITY-BPA grantees. It was proposed that, because of the literature concerning permanent adverse effects resulting from developmental exposures to hormonally active agents, the study would include groups of animals for which exposure would terminate at weaning. For discussion of dose selection, a summary of data obtained from the NCTR BPA subchronic study^19^ was presented and discussed. It was initially agreed that a vehicle control and six log-spaced doses between 2.5 and 250,000 μg BPA/kg bw/day would provide an adequate dose range from reasonably close to human exposure on the low end to a dose expected to produce clear adverse effects at the high end. Serum measurements of BPA across the postnatal life span of animals in the subchronic study^25^ showed that the high dose of 300,000 μg BPA/kg bw/day gave rise to approximately 50 μM active unconjugated BPA in PND 4 animals and approximately 1 μM in PND 80 animals, which were clearly out of the range of attainable human internal exposure from dietary sources, estimated to be in the low to sub-pM range.^29^ There was general agreement that the current concern was restricted to a lower dose range, below the previously reported no-observed-adverse-effect level in guideline-compliant regulatory toxicity assays, which was 5,000 μg/kg bw/day.^26,27^ The 250,000 μg BPA/kg bw/day dose group would provide little additional information to influence regulatory action. A high dose of 25,000 μg BPA/kg bw/day was viewed as providing an adequate margin of human exposure, greater than 25,000-fold based on the aggregate human exposure estimates of <0.5 μg BPA/kg bw/day mentioned above. The low dose selected, 2.5 μg BPA/kg bw/day, provided a margin of exposure at least 10-fold higher than the maximum allowed background dietary exposure (see below).

Much of the research on BPA, particularly early in the investigations of the potential toxicity of low doses of BPA, focused on its estrogenic activity, although the involvement of mechanisms other than classical estrogen receptors have been increasingly implicated in BPA actions.^30-33^ Both doses of EE_2_ used in the NCTR BPA subchronic study (0.5 and 5 μg EE_2_/kg bw/day) produced strong effects in female reproductive organs and on estrous cyclicity. In males, the low dose of 0.5 μg/kg bw/day had little effect, with an increase in male mammary hyperplasia as the only apparent effect at PND 90.^19^ The 5 μg EE_2_/kg bw/day dose also stimulated male mammary gland hyperplasia at PND 90, and increased hyperplasia in the coagulating gland, increased degeneration in the testicular germinal epithelium, and increased exfoliated germ cells and hypospermia in the epididymis. Based on the observed effects in the NCTR BPA subchronic study, two levels of EE_2_, one of which was lower than the doses used in the subchronic study, were selected for use in the current study to expand information on the sensitivity of the animal model to EE_2_. In the absence of data from this exposure model to guide the selection of the EE_2_ lower dose, a 10-fold lower dose was chosen. The CLARITY-BPA consortium consensus for the two doses of EE_2_ used in the current study was 0.05 and 0.5 μg/kg bw/day. Resource limitations did not allow for the inclusion of stop-dose EE_2_ groups. Likewise, although the NCTR BPA subchronic study had included a naïve control group that was not dosed by gavage, this group could not be included in the chronic study. The responses of the naïve and vehicle control groups in the NCTR BPA subchronic study were similar.^19^

## Internal Dosimetry of BPA and EE_2_

In the previous NCTR BPA subchronic study, blood levels of conjugated (biologically inactive) and unconjugated (biologically active) BPA (dose levels of 2.5, 8, 25, 80, 260, 840, 2,700, 100,000, and 300,000 μg/kg bw/day) and EE_2_ (0.5 and 5.0 μg/kg bw/day) were measured. The previous study used identical conditions to the current chronic study, including the same animal model, feed, housing materials, dosing formulation, and dosing regimen. Blood was collected at approximate maximal concentration time (C_max_, 15–30 minutes after dosing) at PND 4, 21, and 80.^10^ For both BPA and EE_2_, percentages of unconjugated compound were highest on PND 4 and decreased with age, reflective of increasing capacity for metabolism with age.^17^ Although the percentage of unconjugated BPA at doses lower than 100,000 μg/kg bw/day were approximately 4% at PND 4 and 1–2% at PNDs 21 and 80, EE_2_ was 100%, 50%, and 10% unconjugated on PNDs 4, 21, and 80, respectively. For BPA, there was evidence of saturation of metabolism at the higher doses, with ≥10% unconjugated at 100,000 and 300,000 μg/kg bw/day. Based on these data and an earlier single-dose pharmacokinetic study in this rat strain,^21^ peak serum levels of unconjugated BPA across the 2.5–25,000 μg/kg bw/day dose span tested in the present study were anticipated to range from <0.5 nM to approximately 2.5–3 µM at PND 4 and from approximately 0.01 nM (below detectable limits) to approximately 30 nM after weaning. In the case of 0.5 μg EE_2_/kg/day, equivalent to the high EE_2_ dose of in this chronic study, peak measured serum levels were approximately 500 and 10 pM on PND 4 and 21, respectively, and below the limit of detection of 5 pM in adults (PND 80).^25^ Estimates of the potency of BPA relative to EE_2_ from in vitro transcriptional and in vivo uterotrophic assays are in the range of 10^-4^–10^-5^ (see, for example, Conley et al.^34^).