# Appendix A List of Supplemental Appendices

Supplemental appendices are available at https://doi.org/10.22427/NTP-DATA-018-00015-0001-000-6.

Supplemental Appendix | Title and Description
I | Protocol and Amendments* Approved NCTR study protocol (E0219001), which includes description of study sponsor, testing facility and responsible personnel, study objectives, background of the scientific problem being addressed, and a detailed description of the study design. Follow-up amendments to the approved study protocol and rationale for the changes, as well as a copy of the study protocol with all amendment changes incorporated, are also included.
II | Protocol Deviations* Documentation generated by Priority One (Animal Care contractor), Toxicologic Pathology Associates (Pathology services contractor), or the Study Director to report noted deviations from the procedures defined in the approved study protocol or follow-up amendments. It includes description of deviations, the corrective measurements taken to prevent re-occurrence, and the assessment by the Study Director on the impact of the deviation on study integrity. A summary table with all deviations is also included.
III | Notes to Study File* Documentation on various events related to the study conduct and not covered in the study protocol deviations documentation.
IV | Study Startup Memo and Study Definition E0219002 (F_0_ and F_1_ Preweaning)* Documentation generated by the Computer Support Group to describe the programming of the in-life tracking system used to support the study and its validation, animal allocation and breeding schemes, treatment group definitions, rack configurations used for animals of the F_0_ generation and F_1_ animals prior to weaning on postnatal day 21. Definitions of disposition and reasons for removal terms are also included.
V | Study Startup Memo and Study Definition E0219003 (F_1_ Postweaning)* Documentation generated by the Computer Support Group to describe the programming of the in-life tracking system used to support the study and its validation, animal allocation scheme, treatment group definitions, and rack configurations used for F_1_ animals after weaning on postnatal day 21.
VI | Breeder Weight Ranking, Treatment Randomization, and Pairing Schedule* Documentation to define the treatment randomization and weight ranking of the F_0_ breeders, the breeding pair randomization, and to report the breeder pairings conducted in the study.
VII | Chemistry Support Report Report by the Chemistry Support Group on the analyses of the study test articles, dose preparations, BPA levels in study materials, and phyto/mycoestrogens in diet. The standard operating procedures followed to perform these analyses are also included.
VIII | Microbiology Support Report Report by the Surveillance/Diagnostic Program Support Group on the microbiological findings on sentinel animals, animal rooms, and animal husbandry supplies.
IX | Diet Preparation Services Report Report by the Diet Preparation Support Group describing the inventory and storage conditions of the study diet and test articles, dose preparations, and the standard operating procedures followed.
X | Animal Rooms Temperature and Humidity Reports* Report of the temperature and relative humidity recorded in the rooms used to house the animals over the course of the study.
XI | Dosing Pump Volume Delivery Accuracy Determinations* Documentation on the accuracy tests performed of the volumes dispensed by the Hamilton Microlab 500 Series Diluter/Dispenser instruments used in the oral dosing of the study animals over the course of the study.
XII | 5K96 Diet Nutrient and Contaminant Analyses from Diet Manufacturer Certificates of analysis from the diet manufacturer of the nutrient and contaminants on each lot of study diet.
XIII | Summary Statistics for Food Consumption a. Interim Sacrifice b. Terminal Sacrifice Report by the Statistical Support Group on the analysis of feed consumption data collected after weaning from F_1_ animals assigned to the interim (1-year) or terminal (2-year) sacrifice study arms. The analyses reported were limited to means and standard errors.
XIV | Estimate of BPA Background Ingestion from Diet Documentation on the calculations conducted to estimate the BPA background exposure of animals due to ingestion of study diet.
XV | Animals Transferred to Cellulose (Alpha-Dri) Bedding* Documentation on the animals transferred from hardwood bedding to Alpha-Dri cellulose bedding over the course of the study. These transfers were recommended by Veterinary Services due to foot lesions or ventral masses that could be further irritated by the hardwood chips.
XVI | Rationale for Sensitivity Analyses in Statistical Reports* Background on the rationale to conduct a sensitivity statistical analysis that excluded any animal that was co-housed in the same room as animals treated with 250,000 μg BPA/kg body weight/day, and list of animals excluded in the sensitivity analysis.
XVII | Gestational Body Weight Statistical Analysis Report by the Statistical Support Group on the analysis of gestational body weight data collected from F_0_ dams. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XVIII | Implantation Site Statistical Analysis Report by the Statistical Support Group on the analysis of uterine implantation data collected from F_0_ dams. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XIX | Litter Parameters Statistical Analysis Report by the Statistical Support Group on the analysis of litter data collected, including litter counts, sex proportions, and body weights. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XX | Preweaning Animal Survival Analysis Report by the Statistical Support Group on the analysis of survival data collected from F_1_ animals prior to weaning. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXI | Interim Sacrifice Survival Analysis Report by the Statistical Support Group on the analysis of survival data collected after weaning from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXII | Terminal Sacrifice Survival Analysis Report by the Statistical Support Group on the analysis of survival data collected after weaning from F_1_ animals assigned to the terminal (2-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXIII | Preweaning Body Weight Statistical Analysis Report by the Statistical Support Group on the analysis of body weight data collected from F_1_ animals prior to weaning. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXIV | Postweaning Body Weight Statistical Analysis, Interim Sacrifice Animals Report by the Statistical Support Group on the analysis of the body weight data collected after weaning from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXV | Postweaning Body Weight Statistical Analysis, Terminal Sacrifice Animals Report by the Statistical Support Group on the analysis of body weight data collected after weaning from F_1_ animals assigned to the terminal (2-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXVI | Vaginal Opening Time and Body Weight Statistical Analysis Report by the Statistical Support Group on the analysis of vaginal opening and body weight data collected from a subset of F_1_ animals assigned to the terminal (2-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXVII | Estrous Cycle Statistical Analysis Report by the Statistical Support Group on the analysis of vaginal cytology data collected from a subset of F_1_ animals assigned to the terminal (2-year) sacrifice study arm to determine estrous cyclicity. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXVIII | Time to Onset of Aberrant Cycling Statistical Analysis Report by the Statistical Support Group on the analysis of vaginal cytology data collected from a subset of F_1_ animals assigned to the terminal (2-year) sacrifice study arm to determine onset of abnormal estrous cycling. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXIX | Hematology and Clinical Chemistry Statistical Analysis, Interim Sacrifice Animals Report by the Statistical Support Group on the analysis of hematology and clinical chemistry data collected from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXX | Organ Weight Statistical Analysis, Interim Sacrifice Animals Report by the Statistical Support Group on the analysis of organ weight data collected from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXXI | Sperm Parameter Statistical Analysis, Interim Sacrifice Animals Report by the Statistical Support Group on the analysis of sperm parameter data collected from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXXII | Pathology Report, Interim and Terminal Sacrifice Animals Report by Toxicologic Pathology Associates (Pathology services contractor) on the gross and microscopic lesions found in tissues collected from F_1_ animals assigned to the interim (1-year) and terminal (2-year) sacrifice study arms. The incidence rates of neoplasms and non-neoplasms by anatomic site and by individual animal, severity scores for some non-neoplasms, the cause of death, and the mammary gland fibroadenoma/adenoma/ adenocarcinoma counts are also included.
XXXIII | Neoplastic and Non-neoplastic Lesions Statistical Analysis, Interim Sacrifice Animals Report by the Statistical Support Group on the analysis of neoplastic and non-neoplastic lesions data collected from F_1_ animals assigned to the interim (1-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.
XXXIV | Neoplastic and Non-neoplastic Lesions Statistical Analysis, Terminal Sacrifice Animals Report by the Statistical Support Group on the analysis of neoplastic and non-neoplastic lesions data collected from F_1_ animals assigned to the terminal (2-year) sacrifice study arm. The report includes a description of statistical methods used, tables of results of analyses conducted on the full set of study animals, and a summary of the results of the sensitivity analyses.

* Available upon request: cdm@niehs.nih.gov.