# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: http://dx.doi.org/10.22427/NTP-RR-4

Report Series: NTP Research Report Series

Report Series Number: 4

Official citation: Pelch K, Wignall J, Goldstone A, Ross P, Blain R, Shapiro A, Holmgren S, Hsieh J-H, Svoboda D, Auerbach S et al. 2017. NTP research report on biological activity of bisphenol A (BPA) structural analogues and functional alternatives. Research Triangle Park, NC: National Toxicology Program. Research Report 4.