# Protocol Review

The study protocol and design was evaluated by the reviewers listed below.

Johanna R. Rochester, Ph.D.

The Endocrine Disruption Exchange/ICF

Cheryl S. Watson, Ph.D.

The University of Texas Medical Branch at Galveston