# Peer Review

The draft research report on the study of biological activity of bisphenol A (BPA) structural analogues and functional alternatives was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies was appropriate and ensured that this NTP Research Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Nicholas J. Cabaton, Ph.D.
  INRA/Toxalim
- René Viñas, MS, Ph.D.
  Grocery Manufacturers Association
- Anne Marie Vinggaard, Ph.D.
  Technical University of Denmark
- Vickie S. Wilson, Ph.D.
  U.S. Environmental Protection Agency