# References

1 European Food Safety Authority (EFSA). Public consultation on the draft opinion on bisphenol A (BPA) – exposure assessment. Parma, Italy: European Food Safety Authority; 2013. https://www.efsa.europa.eu/en/consultations/call/130724 [Accessed: 8/23/13]
2 Food and Agriculture Organization and World Health Organization (FAO/WHO). 2011. Joint Food and Agriculture Organization of the United Nations and World Health Organization (FAO/WHO) expert meeting to review toxicological and health aspects of bisphenol A: Final report, including report of stakeholder meeting on bisphenol A, 1-5 November 2010. Ottawa, Canada: Food and Agriculture Organization of the United Nations and World Health Organization. https://apps.who.int/iris/bitstream/10665/44624/1/97892141564274_eng.pdf.
3 National Toxicology Program (NTP). 2008. NTP-CERHR monograph on the potential human reproductive and developmental effects of bisphenol A. RTP, NC: National Toxicology Program/CERHR. https://ntp.niehs.nih.gov/ntp/ohat/bisphenol/bisphenol.pdf.
4 Östberg T Noaksson E Bisfenol A in svenska kvitton: analysresultat. Ösavagen, Sweden: Institutet för Tillämoa Grön Kemi; 2010.
5 Ye X Bishop AM Reidy JA Needham LL Calafat AM Parabens as urinary biomarkers of exposure in humans. Environ Health Perspect. 2006;114(12):1843– 1846. 10.1289/ehp.9413 17185273
6 Rochester JR Bisphenol A and human health: a review of the literature. Reprod Toxicol. 2013; 42:132–155. 10.1016/j.reprotox.2013.08.008 23994667
7 vom Saal FS Akingbemi BT Belcher SM Birnbaum LS Crain DA Eriksen M Farabollini F Guillette LJ Jr Hauser R Heindel JJ Chapel Hill bisphenol A expert panel consensus statement: integration of mechanisms, effects in animals and potential to impact human health at current levels of exposure. Reprod Toxicol. 2007; 24(2):131–138. 10.1016/j.reprotox.2007.07.005 17768031
8 Liao C Liu F Alomirah H Loi VD Mohd MA Moon HB Nakata H Kannan K Bisphenol S in urine from the United States and seven Asian countries: occurrence and human exposures. Environ Sci Technol. 2012; 46(12):6860–6866. 10.1021/es301334j 22620267
9 Liao C Kannan K Concentrations and profiles of bisphenol A and other bisphenol analogues in foodstuffs from the United States and their implications for human exposure. J Agric Food Chem. 2013; 61(19):4655–4662. 10.1021/jf400445n 23614805
10 Liao C Liu F Guo Y Moon HB Nakata H Wu Q Kannan K Occurrence of eight bisphenol analogues in indoor dust from the United States and several Asian countries: implications for human exposure. Environ Sci Technol. 2012; 46(16):9138–9145. 10.1021/es302004w 22784190
11 Liao C Liu F Moon HB Yamashita N Yun S Kannan K Bisphenol analogues in sediments from industrialized areas in the United States, Japan, and Korea: spatial and temporal distributions. Environ Sci Technol. 2012; 46(21):11558–11565. 10.1021/es303191g 23020513
12 Liao C Liu F Kannan K Bisphenol s, a new bisphenol analogue, in paper products and currency bills and its association with bisphenol a residues. Environ Sci Technol. 2012; 46(12):6515–6522. 10.1021/es300876n 22591511
13 Becerra V Odermatt J Detection and quantification of traces of bisphenol A and bisphenol S in paper samples using analytical pyrolysis-GC/MS. Analyst (Lond). 2012; 137(9):2250–2259. 10.1039/c2an15961a 22428152
14 Becerra V Odermatt J Interferences in the direct quantification of bisphenol S in paper by means of thermochemolysis. J Chromatogr A. 2013; 1275:70–77. 10.1016/j.chroma.2012.12.034 23305856
15 United States Environmental Protection Agency (US EPA). Bisphenol A alternatives in thermal paper (Final Report January 2014). U.S. Environmental Protection Agency; 2014. https://www.epa.gov/sites/production/files/2014-05/documents/bpa_final.pdf [Accessed: 3/31/14]
16 Zhou F Zhang L Liu A Shen Y Yuan J Yu X Feng X Xu Q Cheng C Measurement of phenolic environmental estrogens in human urine samples by HPLC-MS/MS and primary discussion the possible linkage with uterine leiomyoma. J Chromatogr B Analyt Technol Biomed Life Sci. 2013; 938:80–85. 10.1016/j.jchromb.2013.08.032 24060595
17 Zhou X Kramer JP Calafat AM Ye X Automated on-line column-switching high performance liquid chromatography isotope dilution tandem mass spectrometry method for the quantification of bisphenol A, bisphenol F, bisphenol S, and 11 other phenols in urine. J Chromatogr B Analyt Technol Biomed Life Sci. 2014; 944:152–156. 10.1016/j.jchromb.2013.11.009 24316527
18 Cacho JI Campillo N Viñas P Hernández-Córdoba M Stir bar sorptive extraction coupled to gas chromatography-mass spectrometry for the determination of bisphenols in canned beverages and filling liquids of canned vegetables. J Chromatogr A. 2012; 1247:146–153. 10.1016/j.chroma.2012.05.064 22682950
19 Grumetto L Gennari O Montesano D Ferracane R Ritieni A Albrizio S Barbato F Determination of five bisphenols in commercial milk samples by liquid chromatography coupled to fluorescence detection. J Food Prot. 2013; 76(9):1590–1596. 10.4315/0362-028X.JFP-13-054 23992504
20 Cacho JI Campillo N Viñas P Hernández-Córdoba M Stir bar sorptive extraction with EG-Silicone coating for bisphenols determination in personal care products by GC-MS. J Pharm Biomed Anal. 2013; 78-79:255–260. 10.1016/j.jpba.2013.02.023 23507687
21 Song S Song M Zeng L Wang T Liu R Ruan T Jiang G Occurrence and profiles of bisphenol analogues in municipal sewage sludge in China. Environ Pollut. 2014; 186:14–19. 10.1016/j.envpol.2013.11.023 24355443
22 Cunha SC, Almeida C, Mendes E, Fernandes JO. Simultaneous determination of bisphenol A and bisphenol B in beverages and powdered infant formula by dispersive liquid-liquid micro-extraction and heart-cutting multidimensional gas chromatography-mass spectrometry. Food Addit Contam A. 2011; 28(4):513-526. 10.1080/19440049.2010.542551
23 Cunha SC Cunha C Ferreira AR Fernandes JO Determination of bisphenol A and bisphenol B in canned seafood combining QuEChERS extraction with dispersive liquid-liquid microextraction followed by gas chromatography-mass spectrometry. Anal Bioanal Chem. 2012; 404(8):2453–2463. 10.1007/s00216-012-6389-5 22995997
24 Cunha SC Fernandes JO Assessment of bisphenol A and bisphenol B in canned vegetables and fruits by gas chromatography–mass spectrometry after QuEChERS and dispersive liquid–liquid microextraction. Food Control. 2013; 33(2):549–555. 10.1016/j.foodcont.2013.03.028
25 Grumetto L Montesano D Seccia S Albrizio S Barbato F Determination of bisphenol a and bisphenol B residues in canned peeled tomatoes by reversed-phase liquid chromatography. J Agric Food Chem. 2008; 56(22):10633–10637. 10.1021/jf802297z 18959420
26 Cobellis L Colacurci N Trabucco E Carpentiero C Grumetto L Measurement of bisphenol A and bisphenol B levels in human blood sera from healthy and endometriotic women. Biomed Chromatogr. 2009; 23(11):1186–1190. 10.1002/bmc.1241 19444800
27 Cobellis L Panariello A Campitiello MR Nocerino A Pacilio C Salzillo ME Castaldi MA Boccia O Borrelli A [Relationship between endometriosis and exposure to BPA and BPB]. Giorn It Ost Gin. 2010; 32(1):44–48.
28 Cunha SC Fernandes JO Quantification of free and total bisphenol A and bisphenol B in human urine by dispersive liquid-liquid microextraction (DLLME) and heart-cutting multidimensional gas chromatography-mass spectrometry (MD-GC/MS). Talanta. 2010; 83(1):117–125. 10.1016/j.talanta.2010.08.048 21035651
29 Thayer KA, Taylor KW, Garantziotis S, Schurman S, Kissling GE, Hunt D, Herbert B, Church R, Jankowich R, Churchwell MI, et al. Bisphenol A, Bisphenol S, and 4-Hydroxyphenyl 4-Isoprooxyphenylsulfone (BPSIP) in Urine and Blood of Cashiers. Environ Health Persp. 2015. 10.1289/ehp.1409427
30 Bruze M Persson L Trulsson L Zimerson E Demonstration of contact sensitizers in resins and products based on phenol-formaldehyde. Contact Dermat. 1986; 14(3):146–154. 10.1111/j.1600-0536.1986.tb01194.x 3709159
31 Kruse J Dolgner K Greve H Zaporojtchenko V Faupel F Dispersion of gold nanoclusters in TMBPA-polycarbonate by a combination of thermal embedding and vapour-induced crystallization. J Phys D Appl Phys. 2006; 39(23):5086.10.1088/0022-3727/39/23/028
32 Liao C, Kannan K. A survey of bisphenol A and other bisphenol analogues in foodstuffs from nine cities in China. Food Addit Contam A. 2014; 31(2):319-329. 10.1080/19440049.2013.868611
33 Voordeckers JW Fennell DE Jones K Häggblom MM Anaerobic biotransformation of tetrabromobisphenol A, tetrachlorobisphenol A, and bisphenol A in estuarine sediments. Environ Sci Technol. 2002; 36(4):696–701. 10.1021/es011081h 11878385
34 National Toxicology Program (NTP). Draft summary of endocrine disruption literature for bisphenol A analogs and derivatives supporting nomination for toxicological evaluation by the National Toxicology Program. RTP. NC: National Toxicology Program; 2013.
35 Finnish Institute of Occupational Health (FIOH). 2014. Bisphenol A exposure in Finnish workplaces. Finish Institute of Occupational Health. https://www.ttl.fi/fi/verkkokirjat/Sivut/Bisfenoli.aspx
36 Food and Drug Administration (FDA). Indirect Food Additives: Polymers. Final Rule. 2012. 77 FR 41899. https://www.govinfo.gov/content/pkg/fr-2012-07-17/html/2012-17366.Htm [Accessed: 25 July 2013]
37 Food and Drug Administration (FDA). Indirect Food Additives: Adhesives and Components of Coatings. Final Rule. 2013. 78 FR 41840 https://www.federalregister.gov/documents/2013/07/12/2013-16684/indirect-food-additives-adhesives-and-components-of-coatings [Accessed: 25 July 2013]
38 Rochester JR Bolden AL Bisphenol S and F: a systematic review and comparison of the hormonal activity of bisphenol A substitutes. Environ Health Perspect. 2015; 123(7):643–650. 10.1289/ehp.1408989 25775505
39 National Toxicology Program (NTP). 2014. Literature Review of Bisphenol A (BPA) Analogues. RTP, NC: National Toxicology Program. 10.22427/NTP-DATA-RR-4
40 Moher D Liberati A Tetzlaff J Altman DG PRISMA Group Preferred reporting items for systematic reviews and meta-analyses: the PRISMA statement. J Clin Epidemiol. 2009; 62(10):1006–1012. 10.1016/j.jclinepi.2009.06.005 19631508
41 Rooney AA Boyles AL Wolfe MS Bucher JR Thayer KA Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 2014; 122(7):711–718. 10.1289/ehp.1307972 24755067
42 Higgins JP Green S Cochrane handbook for systematic reviews of interventions. West Sussex, England: John Wiley & Sons; 2011.
43 AHRQ training modules for the systematic reviews methods guide. U.S. Department of Health and Human Services; 2014. [Accessed: 10/11/13]. https://www.effectivehealthcare.ahrq.gov/index.cfm/tools-and-resources/slide-library/.
44 ICF. From systematic review to sssessment development: managing big (and small) datasets with DRAGON. ICF International; 2013. https://www.icf.com/solutions-and-apps/dragon-dose-response
45 ICF. DRAGON: An online tool for systematic review. ICF International; 2016. https://www.icf.com/technology/dragon [Accessed: 12/1/2016]
46 Rohatgi A. WebPlotDigitizer. 2015. https://arohatgi.info/webplotdigitizer [Accessed: 3/30/16]
47 Shapiro AJ. Health Assessment Workplace Collaborative. 2014. https://hawcproject.org [Accessed: 1/6/16]
48 National Toxicology Program (NTP). 2015. OHAT risk of bias tool. RTP, NC: Office of Health Assessment and Translation (OHAT), National Toxicology Program. https://ntp.niehs.nih.gov/go/38673.
49 United States Environmental Protection Agency (US EPA). Distributed structure-searchable toxicity (DSSTox) database. United States Environmental Protection Agency; 2015. https://www.epa.gov/chemical-research/distributed-structure-searchable-toxicity-dsstox-database [Accessed: 11/1/15]
50 Tice RR Austin CP Kavlock RJ Bucher JR Improving the human hazard characterization of chemicals: a Tox21 update. Environ Health Perspect. 2013; 121(7):756–765. 10.1289/ehp.1205784 23603828
51 Kavlock R Chandler K Houck K Hunter S Judson R Kleinstreuer N Knudsen T Martin M Padilla S Reif D Update on EPA’s ToxCast program: providing high throughput decision support tools for chemical risk management. Chem Res Toxicol. 2012; 25(7):1287–1302. 10.1021/tx3000939 22519603
52 United States Environmental Protection Agency (US EPA). Endocrine disruptor screening program for the 21st century: (EDSP21 work plan). Washington, DC: United States Environmental Protection Agency; 2011. https://www.epa.gov/sites/production/files/2015-07/documents/edsp21_work_plan_summary_overview_final.pdf
53 Hsieh JH Sedykh A Huang R Xia M Tice RR A data analysis pipeline accounting for artifacts in Tox21 quantitative high-throughput screening assays. J Biomol Screen. 2015; 20(7):887–897. 10.1177/1087057115581317 25904095
54 Reif DM Sypa M Lock EF Wright FA Wilson A Cathey T Judson RR Rusyn I ToxPi GUI: an interactive visualization tool for transparent integration of data from diverse sources of evidence. Bioinformatics. 2013; 29(3):402–403. 10.1093/bioinformatics/bts686 23202747
55 Zhang SS Liu Y Liu SS Zhu XW [Detecting the cytotoxicities of five bisphenol A analogues to the MCF-7 human breast carcinoma cell line through different endpoints]. Huan Jing Ke Xue. 2012; 33(11):3935–3940. 23323428
56 Muroi T Matsuzawa M Kurata S Relationship between the molecular structures and estrogenic activity of bisphenol A and its chemical analogs. Kanagawa Shigaku. 2003; 38(2-3):77–91.
57 Zhang HC Chen LY Liu SS Yin DQ [Jointed estrogenic activities of bisphenol A and three of its analogs]. Huan Jing Ke Xue. 2009; 30(1):260–265. 19353891
58 Wang L Yi Z-S Li L-C Liu H-Y Mo L-Y Zhang A-Q [CoMSIA study of estrogen compounds binding to estrogen receptor beta based on docking]. Guilin Li Gong Da Xue Xue Bao. 2010; 30(4):625–631.
59 Xiao Q Wang X Wang L Studies on quantitative structure—Genotoxicity of substituted benzenes on the human lymphocyte. Zhongguo Huanjing Kexue. 2004; 25(1):18–22.
60 Yoo I-K, Choe W-S. Screening of peptide sequences with affinity to bisphenol A by biopanning. Korean J Microbiol. 2013; 49(2):211-214. 10.7845/kjm.2013.3039
61 Li Y Hu S-Q Yin D-Q Primary screening and evaluation of endocrine disrupting activities of eleven substituted phenols. Environ Chem-Beijing. 2003; 22(4):385–389.
62 Asano K Ono A Hashimoto S Inoue T Kanno J Screening method of endocrine disrupting chemicals using a surface plasmon resonance sensor. Bunseki Kagaku. 2002; 51(6):389–396.10.2116/bunsekikagaku.51.389
63 Zhang W-M Yang L Li X-F Lin Q Li G-H Wei W-B Screening of active compounds from Gastrodia elata Blume for vascular smooth muscle relaxation. Chin J Exp Tradit Med Formul. 2011; 17:157–160.
64 Hayakawa R, Matsunaga K, Takeuchi Y, Tatsumi H, Masamoto Y. Occupational contact dermatitis from bisphenol F. Skin Res. 1985; 27(3):494-500. 10.11340/skinresearch1959.27.494
65 Bruze M Zimerson E Contact allergy to dihydroxydiphenyl methanes (bisphenol F). Derm Beruf Umwelt. 1985; 33(6):216–220. 2936594
66 Jelen G Cavelier C Protois JP Foussereau J A new allergen responsible for shoe allergy: chloroacetamide. Contact Dermat. 1989; 21(2):110–111. 10.1111/j.1600-0536.1989.tb04709.x 2530048
67 Shmidt E Farmer SA Davis MD Patch-testing with plastics and glues series allergens. Dermatitis. 2010; 21(5):269–274. 20920413
68 Furr JR Lambright CS Wilson VS Foster PM Gray LE Jr A short-term in vivo screen using fetal testosterone production, a key event in the phthalate adverse outcome pathway, to predict disruption of sexual differentiation. Toxicol Sci. 2014; 140(2):403–424. 10.1093/toxsci/kfu081 24798384
69 Higashihara N Shiraishi K Miyata K Oshima Y Minobe Y Yamasaki K Subacute oral toxicity study of bisphenol F based on the draft protocol for the “Enhanced OECD Test Guideline no. 407”. Arch Toxicol. 2007; 81(12):825–832. 10.1007/s00204-007-0223-4 17628788
70 Umano T Tanaka R Yamasaki K Endocrine-mediated effects of 4,4′-(hexafluoroisopropylidene)diphenol in SD rats, based on a subacute oral toxicity study. Arch Toxicol. 2012; 86(1):151–157. 10.1007/s00204-011-0731-0 21713527
71 Feng Y Yin J Jiao Z Shi J Li M Shao B Bisphenol AF may cause testosterone reduction by directly affecting testis function in adult male rats. Toxicol Lett. 2012; 211(2):201–209. 10.1016/j.toxlet.2012.03.802 22504055
72 Yamasaki K Okuda H Comparison of endocrine-mediated effects of two bisphenol A related compounds, 2,2-bis(4-cyanatophyenyl)propane and 4,4′-cyclohexylidenebisphenol, based on subacute oral toxicity studies using rats. Toxicol Lett. 2012; 208(2):162–167. 10.1016/j.toxlet.2011.11.001 22093917
73 Eastman Kodak Letter concerning enclosed information on bisphenol S with attachments. Rochester (NY): Eastman Kodak Company; 1991.
74 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.002. European Chemicals Agency; 2010. https://echa.europa.eu/registration-dossier/-/registered-dossier/5460/7/6/2/?documentUUID=c0770bc7-80bf-4c24-b95d-5e31c8e4458814228 [Accessed: 3/29/16]
75 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.003. European Chemicals Agency; 1997. https://echa.europa.eu/registration-dossier/-/registered-dossier/5460/7/6/2/?documentUUID=a8856985-28ab-4914-bb7e-0faf31efad6e [Accessed: 3/29/16]
76 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.001. European Chemicals Agency; 2003. https://echa.europa.eu/registration-dossier/-/registered-dossier/13018/7/6/2/?documentUUID=cb7e9a3f-f61c-4195-8769-23a42c22313f [Accessed: 3/31/16]
77 Tohmé M Prud’homme SM Boulahtouf A Samarut E Brunet F Bernard L Bourguet W Gibert Y Balaguer P Laudet V Estrogen-related receptor γ is an in vivo receptor of bisphenol A. FASEB J. 2014; 28(7):3124–3133. 10.1096/fj.13-240465 24744145
78 Shi J Jiao Z Zheng S Li M Zhang J Feng Y Yin J Shao B Long-term effects of bisphenol AF (BPAF) on hormonal balance and genes of hypothalamus-pituitary-gonad axis and liver of zebrafish (Danio rerio), and the impact on offspring. Chemosphere. 2015; 128:252–257. 10.1016/j.chemosphere.2015.01.060 25723718
79 Ji K Hong S Kho Y Choi K Effects of bisphenol s exposure on endocrine functions and reproduction of zebrafish. Environ Sci Technol. 2013; 47(15):8793–8800. 10.1021/es400329t 23806087
80 Naderi M Wong MY Gholami F Developmental exposure of zebrafish (Danio rerio) to bisphenol-S impairs subsequent reproduction potential and hormonal balance in adults. Aquat Toxicol. 2014; 148:195–203. 10.1016/j.aquatox.2014.01.009 24508763
81 Yang X, Liu Y, Li J, Chen M, Peng D, Liang Y, Song M, Zhang J, Jiang G. Exposure to Bisphenol AF disrupts sex hormone levels and vitellogenin expression in zebrafish. Environ Toxicol. 2014. 10.1002/tox.22043
82 Song M Liang D Liang Y Chen M Wang F Wang H Jiang G Assessing developmental toxicity and estrogenic activity of halogenated bisphenol A on zebrafish (Danio rerio). Chemosphere. 2014; 112:275–281. 10.1016/j.chemosphere.2014.04.084 25048916
83 Yamasaki K Noda S Imatanaka N Yakabe Y Comparative study of the uterotrophic potency of 14 chemicals in a uterotrophic assay and their receptor-binding affinity. Toxicol Lett. 2004; 146(2):111–120. 10.1016/j.toxlet.2003.07.003 14643963
84 Yamasaki K Takeyoshi M Yakabe Y Sawaki M Imatanaka N Takatsuki M Comparison of reporter gene assay and immature rat uterotrophic assay of twenty-three chemicals. Toxicology. 2002; 170(1-2):21–30. 10.1016/S0300-483X(01)00505-4 11750080
85 Yamasaki K Takeyoshi M Sawaki M Imatanaka N Shinoda K Takatsuki M Immature rat uterotrophic assay of 18 chemicals and Hershberger assay of 30 chemicals. Toxicology. 2003; 183(1-3):93–115. 10.1016/S0300-483X(02)00445-6 12504345
86 Akahori Y Nakai M Yamasaki K Takatsuki M Shimohigashi Y Ohtaki M Relationship between the results of in vitro receptor binding assay to human estrogen receptor α and in vivo uterotrophic assay: comparative study with 65 selected chemicals. Toxicol In Vitro. 2008; 22(1):225–231. 10.1016/j.tiv.2007.08.004 17904329
87 Stroheker T Chagnon MC Pinnert MF Berges R Canivenc-Lavier MC Estrogenic effects of food wrap packaging xenoestrogens and flavonoids in female Wistar rats: a comparative study. Reprod Toxicol. 2003; 17(4):421–432. 10.1016/S0890-6238(03)00044-3 12849853
88 Greco AM Marino G Scapagnini U Scardi V Oestrogenic activity of some simple compounds related to diethylstilboestrol. Arch Int Pharmacodyn Ther. 1967; 168(1):149–158. 6058093
89 Wang S Rijk JC Besselink HT Houtman R Peijnenburg AA Brouwer A Rietjens IM Bovee TF Extending an in vitro panel for estrogenicity testing: the added value of bioassays for measuring antiandrogenic activities and effects on steroidogenesis. Toxicol Sci. 2014; 141(1):78–89. 10.1093/toxsci/kfu103 24928889
90 Bitman J Cecil HC Estrogenic activity of DDT analogs and polychlorinated biphenyls. J Agric Food Chem. 1970; 18(6):1108–1112. 10.1021/jf60172a019 5483049
91 Campbell NR Molecular structure in relation to oestrogenic activity: derivatives of 4:4'dihydroxydiphenylmethane. Proc R Soc Lond. 1941; 672:528–538.
92 Dodds EC Lawson W Molecular structure in relation to oestrogenic activity. Compounds without a phenanthrene nucleus. Proc R Soc Lond B Biol Sci. 1938; 125(839):222–232.10.1098/rspb.1938.0023
93 Dodds E Lawson W Synthetic estrogenic agents without the phenanthrene nucleus. Nature. 1936; 137(3476):996.10.1038/137996a0
94 Hashimoto Y Moriguchi Y Oshima H Kawaguchi M Miyazaki K Nakamura M Measurement of estrogenic activity of chemicals for the development of new dental polymers. Toxicol In Vitro. 2001; 15(4-5):421–425. 10.1016/S0887-2333(01)00046-7 11566573
95 Kuruto-Niwa R Nozawa R Miyakoshi T Shiozawa T Terao Y Estrogenic activity of alkylphenols, bisphenol S, and their chlorinated derivatives using a GFP expression system. Environ Toxicol Pharmacol. 2005; 19(1):121–130. 10.1016/j.etap.2004.05.009 21783468
96 Terasaki M Shiraishi F Fukazawa H Makino M Occurrence and estrogenicity of phenolics in paper-recycling process water: pollutants originating from thermal paper in waste paper. Environ Toxicol Chem. 2007; 26(11):2356–2366. 10.1897/06-642R.1 17941731
97 Goldinger DM Demierre AL Zoller O Rupp H Reinhard H Magnin R Becker TW Bourqui-Pittet M Endocrine activity of alternatives to BPA found in thermal paper in Switzerland. Regul Toxicol Pharmacol. 2015; 71(3):453–462. 10.1016/j.yrtph.2015.01.002 25579646
98 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.003. European Chemicals Agency; 2014. https://echa.europa.eu/registration-dossier/-/registered-dossier/14986/7/6/2/?documentUUID=627d81e2-b6e0-4a92-8089-5e78906a6c59 [Accessed: 3/28/16]
99 European Chemicals Agency (ECHA). Exp supporting repeated dose toxicity: oral. 001. European Chemicals Agency; 1999. https://echa.europa.eu/it/registration-dossier/-/registered-dossier/14986/7/6/2#sApplicantSummaryAndConclusion
100 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.002. European Chemicals Agency; 2002. https://echa.europa.eu/registration-dossier/-/registered-dossier/12390/7/6/2/?documentUUID=34800bf1-4b5a-4cf5-9efa-dc08a1cfb31b [Accessed: 3/28/16]
101 European Chemicals Agency (ECHA). Exp Key Repeated dose toxicity: oral.003. European Chemicals Agency; 2000. https://echa.europa.eu/registration-dossier/-/registered-dossier/12390/7/6/2/?documentUUID=a6f44f03-4202-425b-80da-57af98c5607e [Accessed: 3/28/16]
102 Fang H Tong W Branham WS Moland CL Dial SL Hong H Xie Q Perkins R Owens W Sheehan DM Study of 202 natural, synthetic, and environmental chemicals for binding to the androgen receptor. Chem Res Toxicol. 2003; 16(10):1338–1358. 10.1021/tx030011g 14565775
103 Hong H Branham WS Ng HW Moland CL Dial SL Fang H Perkins R Sheehan D Tong W Human sex hormone-binding globulin binding affinities of 125 structurally diverse chemicals and comparison with their binding to androgen receptor, estrogen receptor, and α-fetoprotein. Toxicol Sci. 2015; 143(2):333–348. 10.1093/toxsci/kfu231 25349334
104 Kitamura S Suzuki T Sanoh S Kohta R Jinno N Sugihara K Yoshihara S Fujimoto N Watanabe H Ohta S Comparative study of the endocrine-disrupting activity of bisphenol A and 19 related compounds. Toxicol Sci. 2005; 84(2):249–259. 10.1093/toxsci/kfi074 15635150
105 Goto Y Kitamura S Kashiwagi K Oofusa K Tooi O Yoshizato K Sato J Ohta S Kashiwagi A Suppression of amphibian metamorphosis by bisphenol a and related chemical substances. J Health Sci. 2006; 52(2):160–168.10.1248/jhs.52.160
106 Goto K Akiike T Konno K Shiba T Patz M Takahashi M Inoue Y Matsubara M Thermally stable polyarylenes with low dielectric constant: direction towards the lowest limit of dielectrics. J Photopolym Sci Technol. 2002; 15(2):223–229.10.2494/photopolymer.15.223
107 Kitamura S Kato T Iida M Jinno N Suzuki T Ohta S Fujimoto N Hanada H Kashiwagi K Kashiwagi A Anti-thyroid hormonal activity of tetrabromobisphenol A, a flame retardant, and related compounds: affinity to the mammalian thyroid hormone receptor, and effect on tadpole metamorphosis. Life Sci. 2005; 76(14):1589–1601. 10.1016/j.lfs.2004.08.030 15680168
108 Butt CM Stapleton HM Inhibition of thyroid hormone sulfotransferase activity by brominated flame retardants and halogenated phenolics. Chem Res Toxicol. 2013; 26(11):1692–1702. 10.1021/tx400342k 24089703
109 Butt CM Wang D Stapleton HM Halogenated phenolic contaminants inhibit the in vitro activity of the thyroid-regulating deiodinases in human liver. Toxicol Sci. 2011; 124(2):339–347. 10.1093/toxsci/kfr117 21565810
110 Shiizaki K Asai S Ebata S Kawanishi M Yagi T Establishment of yeast reporter assay systems to detect ligands of thyroid hormone receptors α and β. Toxicol In Vitro. 2010; 24(2):638–644. 10.1016/j.tiv.2009.10.001 19853653
111 Kim H-J Park H-Y Kim J-A Kang I-H Kim T-S Han S-Y Kang T-S Park K-L Kim H-S Assessment of in vitro assay system for thyroid hormone disruptors using rat pituitary GH 3 cells. Toxicol Res. 2006; 22(4):307–313.
112 Okada H Tokunaga T Liu X Takayanagi S Matsushima A Shimohigashi Y Direct evidence revealing structural elements essential for the high binding ability of bisphenol A to human estrogen-related receptor-gamma. Environ Health Perspect. 2008; 116(1):32–38. 10.1289/ehp.10587 18197296
113 Delfosse V Grimaldi M Pons JL Boulahtouf A le Maire A Cavailles V Labesse G Bourguet W Balaguer P Structural and mechanistic insights into bisphenols action provide guidelines for risk assessment and discovery of bisphenol A substitutes. Proc Natl Acad Sci USA. 2012; 109(37):14930–14935. 10.1073/pnas.1203574109 22927406
114 Dring AM Anderson LE Qamar S Stoner MA Rational quantitative structure-activity relationship (RQSAR) screen for PXR and CAR isoform-specific nuclear receptor ligands. Chem Biol Interact. 2010; 188(3):512–525. 10.1016/j.cbi.2010.09.018 20869355
115 Sui Y Ai N Park SH Rios-Pilier J Perkins JT Welsh WJ Zhou C Bisphenol A and its analogues activate human pregnane X receptor. Environ Health Perspect. 2012; 120(3):399–405. 10.1289/ehp.1104426 22214767
116 Imai J Yamazoe Y Yoshinari K Novel cell-based reporter assay system using epitope-tagged protein for the identification of agonistic ligands of constitutive androstane receptor (CAR). Drug Metab Pharmacokinet. 2013; 28(4):290–298. 10.2133/dmpk.DMPK-12-RG-112 23268926
117 Peyre L Rouimi P de Sousa G Héliès-Toussaint C Carré B Barcellini S Chagnon MC Rahmani R Comparative study of bisphenol A and its analogue bisphenol S on human hepatic cells: a focus on their potential involvement in nonalcoholic fatty liver disease. Food Chem Toxicol. 2014; 70:9–18. 10.1016/j.fct.2014.04.011 24793377
118 Roelofs MJ van den Berg M Bovee TF Piersma AH van Duursen MB Structural bisphenol analogues differentially target steroidogenesis in murine MA-10 Leydig cells as well as the glucocorticoid receptor. Toxicology. 2015; 329:10–20. 10.1016/j.tox.2015.01.003 25576683
119 Kolšek K Gobec M Mlinarič Raščan I Sollner Dolenc M Molecular docking revealed potential disruptors of glucocorticoid receptor-dependent reporter gene expression. Toxicol Lett. 2014; 226(2):132–139. 10.1016/j.toxlet.2014.01.047 24518828
120 Kamata R Shiraishi F Nishikawa J Yonemoto J Shiraishi H Screening and detection of the in vitro agonistic activity of xenobiotics on the retinoic acid receptor. Toxicol In Vitro. 2008; 22(4):1050–1061. 10.1016/j.tiv.2008.01.002 18289828
121 Nishigori M Nose T Shimohigashi Y Highly potent binding and inverse agonist activity of bisphenol A derivatives for retinoid-related orphan nuclear receptor RORγ. Toxicol Lett. 2012; 212(2):205–211. 10.1016/j.toxlet.2012.05.020 22659100
122 Monsanto Co. Initial submission: Acute oral toxicity of several diphenyl sulfones in rats and rabbits with cover letter dated 08/05/92. St. Louis, MS: Monsanto Company; 1992. OTS0555048. internal-pdf://4186365337/OTS0555048.pdf
123 Dupont. Initial submission: acute oral toxicity of 4,4'-(hexafluoroisopropylidene)diphenol in male rats with cover letter dated 10/15/92. EPA/OTS. 1992; 920010335:#88-920010335.
124 Army Chemical Center Table V Toxicity Tests. Chemical Biological Coordination Center, Summary Biological Tests. National Research Council; 1954. p. 138–149.
125 Pan F, Xu T, Yang L, Jiang X, Zhang L. Probing the binding of an endocrine disrupting compound-Bisphenol F to human serum albumin: insights into the interactions of harmful chemicals with functional biomacromolecules. Spectroc Acta Pt A-Molec Biomolec Spectr. 2014; 132:795-802. 10.1016/j.saa.2014.05.093 10.1016/j.saa.2014.05.093
126 Wang X Yang J Wang Y Li Y Wang F Zhang L Studies on electrochemical oxidation of estrogenic disrupting compound bisphenol AF and its interaction with human serum albumin. J Hazard Mater. 2014; 276:105–111. 10.1016/j.jhazmat.2014.05.028 24866560
127 Hendriks HS Meijer M Muilwijk M van den Berg M Westerink RH A comparison of the in vitro cyto- and neurotoxicity of brominated and halogen-free flame retardants: prioritization in search for safe(r) alternatives. Arch Toxicol. 2014; 88(4):857–869. 10.1007/s00204-013-1187-1 24395120
128 Lee S Kim YK Shin TY Kim SH Neurotoxic effects of bisphenol AF on calcium-induced ROS and MAPKs. Neurotox Res. 2013; 23(3):249–259. 10.1007/s12640-012-9353-4 22996013
129 Héliès-Toussaint C Peyre L Costanzo C Chagnon MC Rahmani R Is bisphenol S a safe substitute for bisphenol A in terms of metabolic function? An in vitro study. Toxicol Appl Pharmacol. 2014; 280(2):224–235. 10.1016/j.taap.2014.07.025 25111128
130 Masuno H Iwanami J Kidani T Sakayama K Honda K Bisphenol a accelerates terminal differentiation of 3T3-L1 cells into adipocytes through the phosphatidylinositol 3-kinase pathway. Toxicol Sci. 2005; 84(2):319–327. 10.1093/toxsci/kfi088 15659569
131 Hayashi J Sekine T Deguchi S Lin Q Horie S Tsuchiya S Yano S Watanabe K Ikegami F Phenolic compounds from Gastrodia rhizome and relaxant effects of related compounds on isolated smooth muscle preparation. Phytochemistry. 2002; 59(5):513–519. 10.1016/S0031-9422(02)00008-0 11853746
132 Lee JY Jang YW Kang HS Moon H Sim SS Kim CJ Anti-inflammatory action of phenolic compounds from Gastrodia elata root. Arch Pharm Res. 2006; 29(10):849–858. 10.1007/BF02973905 17121179
133 Pyo MK, Jin JL, Koo YK, Yun-Choi HS. Phenolic and furan type compounds isolated from Gastrodia elata and their anti-platelet effects. Arch Pharmacal Res. 2004; 27(4):381-385. 10.1007/BF02980077 10.1007/BF02980077
134 Gao X Ma J Chen Y Wang HS Rapid responses and mechanism of action for low-dose bisphenol S on ex vivo rat hearts and isolated myocytes: evidence of female-specific proarrhythmic effects. Environ Health Perspect. 2015; 123(6):571–578. 10.1289/ehp.1408679 25723814
135 Kubo T Maezawa N Osada M Katsumura S Funae Y Imaoka S Bisphenol A, an environmental endocrine-disrupting chemical, inhibits hypoxic response via degradation of hypoxia-inducible factor 1α (HIF-1α): structural requirement of bisphenol A for degradation of HIF-1α. Biochem Biophys Res Commun. 2004; 318(4):1006–1011. 10.1016/j.bbrc.2004.04.125 15147973
136 Hopp L Megee SO Lloyd JB Bisphenols that stimulate cells to release alkali metal cations: a structure-activity study. J Med Chem. 1998; 41(22):4421–4423. 10.1021/jm980315d 9784117
137 Zhang H-C Hu X-L Yin D-Q Lin Z-F Development of molecular docking-based binding energy to predict the joint effect of BPA and its analogs. Hum Exp Toxicol. 2011; 30(4):318–327. 10.1177/0960327110372400 20511291
138 Kolle SN Kamp HG Huener HA Knickel J Verlohner A Woitkowiak C Landsiedel R van Ravenzwaay B In house validation of recombinant yeast estrogen and androgen receptor agonist and antagonist screening assays. Toxicol In Vitro. 2010; 24(7):2030–2040. 10.1016/j.tiv.2010.08.008 20732407
139 Coleman KP Toscano WA Wiese TE QSAR models of the in vitro estrogen activity of bisphenol A analogs. QSAR Comb Sci. 2003; 22(1):78–88.10.1002/qsar.200390008
140 Kataria A Levine D Wertenteil S Vento S Xue J Rajendiran K Kannan K Thurman JM Morrison D Brody R Exposure to bisphenols and phthalates and association with oxidant stress, insulin resistance, and endothelial dysfunction in children. Pediatr Res. 2017; 81(6):857–864. 10.1038/pr.2017.16 28099427
141 Catanese MC Vandenberg LN Bisphenol S BPS) alters maternal behavior and brain in mice exposed during pregnancy/lactation and their daughters. Endocrinology. 2017; 158(3):516–530. 10.1210/en.2016-1723 28005399
142 Wang RY Abbott RD Zieba A Borowsky FE Kaplan DL Development of a three-dimensional adipose tissue model for studying embryonic exposures to obesogenic chemicals. Ann Biomed Eng. 2017; 45(7):1807–1818. 10.1007/s10439-016-1752-x 27815650
143 Chen Y Shu L Qiu Z Lee DY Settle SJ Que Hee S Telesca D Yang X Allard P Exposure to the BPA-substitute bisphenol S causes unique alterations of germline function. PLoS Genet. 2016; 12(7):e1006223. 10.1371/journal.pgen.1006223 27472198
144 Thayer KA Pelch KE Birnbaum LS Bucher JR Bisphenols: more unnecessary surprises. Endocr Disruptors (Austin). 2016; 4(1):e1131032.10.1080/23273747.2015.1131032
145 Hashimoto Y Nakamura M Estrogenic activity of dental materials and bisphenol-A related chemicals in vitro. Dent Mater J. 2000; 19(3):245–262. 10.4012/dmj.19.245 11218845
146 Blair RM Fang H Branham WS Hass BS Dial SL Moland CL Tong W Shi L Perkins R Sheehan DM The estrogen receptor relative binding affinities of 188 natural and xenochemicals: structural diversity of ligands. Toxicol Sci. 2000; 54(1):138–153. 10.1093/toxsci/54.1.138 10746941
147 Kitamura S Sanoh S Kohta R Suzuki T Sugihara K Fujimoto N Ohta S Metabolic activation of proestrogenic diphenyl and related compounds by rat liver microsomes. J Health Sci. 2003; 49(4):298–310.10.1248/jhs.49.298
148 Perez P Pulgar R Olea-Serrano F Villalobos M Rivas A Metzler M Pedraza V Olea N The estrogenicity of bisphenol A-related diphenylalkanes with various substituents at the central carbon and the hydroxy groups. Environ Health Perspect. 1998; 106(3):167–174. 10.1289/ehp.98106167 9449681
149 Stroheker T Picard K Lhuguenot JC Canivenc-Lavier MC Chagnon MC Steroid activities comparison of natural and food wrap compounds in human breast cancer cell lines. Food Chem Toxicol. 2004; 42(6):887–897. 10.1016/j.fct.2004.01.012 15110097
150 Molina-Molina JM Amaya E Grimaldi M Sáenz JM Real M Fernández MF Balaguer P Olea N In vitro study on the agonistic and antagonistic activities of bisphenol-S and other bisphenol-A congeners and derivatives via nuclear receptors. Toxicol Appl Pharmacol. 2013; 272(1):127–136. 10.1016/j.taap.2013.05.015 23714657
151 Matsushima A Liu X Okada H Shimohigashi M Shimohigashi Y Bisphenol AF is a full agonist for the estrogen receptor ERalpha but a highly specific antagonist for ERbeta. Environ Health Perspect. 2010; 118(9):1267–1272. 10.1289/ehp.0901819 20427257
152 Yamasaki K Takeyoshi M Yakabe Y Sawaki M Takatsuki M Comparison of the reporter gene assay for ER-alpha antagonists with the immature rat uterotrophic assay of 10 chemicals. Toxicol Lett. 2003; 142(1-2):119–131. 10.1016/S0378-4274(03)00019-5 12765246
153 Rotroff DM Dix DJ Houck KA Kavlock RJ Knudsen TB Martin MT Reif DM Richard AM Sipes NS Abassi YA Real-time growth kinetics measuring hormone mimicry for ToxCast chemicals in T-47D human ductal carcinoma cells. Chem Res Toxicol. 2013; 26(7):1097–1107. 10.1021/tx400117y 23682706
154 Viñas R Watson CS Mixtures of xenoestrogens disrupt estradiol-induced non-genomic signaling and downstream functions in pituitary cells. Environ Health. 2013; 12(1):26. 10.1186/1476-069x-12-26 23530988
155 Li Y Burns KA Arao Y Luh CJ Korach KS Differential estrogenic actions of endocrine-disrupting chemicals bisphenol A, bisphenol AF, and zearalenone through estrogen receptor α and β in vitro. Environ Health Perspect. 2012; 120(7):1029–1035. 10.1289/ehp.1104689 22494775
156 Teng C Goodwin B Shockley K Xia M Huang R Norris J Merrick BA Jetten AM Austin CP Tice RR Bisphenol A affects androgen receptor function via multiple mechanisms. Chem Biol Interact. 2013; 203(3):556–564. 10.1016/j.cbi.2013.03.013 23562765
157 Ma M Crump D Farmahin R Kennedy SW Comparing the effects of tetrabromobisphenol-A, bisphenol A, and their potential replacement alternatives, TBBPA-bis(2,3-dibromopropyl ether) and bisphenol S, on cell viability and messenger ribonucleic acid expression in chicken embryonic hepatocytes. Environ Toxicol Chem. 2015; 34(2):391–401. 10.1002/etc.2814 25470364
158 Stossi F Bolt MJ Ashcroft FJ Lamerdin JE Melnick JS Powell RT Dandekar RD Mancini MG Walker CL Westwick JK Defining estrogenic mechanisms of bisphenol A analogs through high throughput microscopy-based contextual assays. Chem Biol. 2014; 21(6):743–753. 10.1016/j.chembiol.2014.03.013 24856822
159 Li M Guo J Gao W Yu J Han X Zhang J Shao B Bisphenol AF-induced endogenous transcription is mediated by ERα and ERK1/2 activation in human breast cancer cells. PLoS One. 2014; 9(4):e94725. 10.1371/journal.pone.0094725 24727858
160 Rivas A Lacroix M Olea-Serrano F Laíos I Leclercq G Olea N Estrogenic effect of a series of bisphenol analogues on gene and protein expression in MCF-7 breast cancer cells. J Steroid Biochem Mol Biol. 2002; 82(1):45–53. 10.1016/S0960-0760(02)00146-2 12429138
161 Letcher RJ Sanderson JT Bokkers A Giesy JP van den Berg M Effects of bisphenol A-related diphenylalkanes on vitellogenin production in male carp (Cyprinus carpio) hepatocytes and aromatase (CYP19) activity in human H295R adrenocortical carcinoma cells. Toxicol Appl Pharmacol. 2005; 209(2):95–104. 10.1016/j.taap.2005.03.013 15907334
162 Rosenmai AK Dybdahl M Pedersen M Alice van Vugt-Lussenburg BM Wedebye EB Taxvig C Vinggaard AM Are structural analogues to bisphenol a safe alternatives? Toxicol Sci. 2014; 139(1):35–47. 10.1093/toxsci/kfu030 24563381
163 Ashcroft FJ Newberg JY Jones ED Mikic I Mancini MA High content imaging-based assay to classify estrogen receptor-α ligands based on defined mechanistic outcomes. Gene. 2011; 477(1-2):42–52. 10.1016/j.gene.2011.01.009 21256200