# Summary

Our results add to a growing literature indicating that risk characterizations of BPA need to expand and should begin to consider BPA structural and functional analogues.^144^ This is especially important given that the evidence presented in the current review highlights that many of the BPA analogues are active at concentrations similar to or lower than BPA. Given that many of the BPA analogues are already known to be in use (because they are found in consumer products, house dust, or in biomonitoring specimens), it is important that we increase our knowledge about their potential biological activities. We hope that this systematic review of the literature can serve as a starting point for considering the class of BPA analogues more broadly. It is our hope that future analyses can integrate information from data-rich chemicals such as BPA, BPAF, and BPS to inform scientists about the predicted biological activity of the data poor analogues and thereby avoid situations of regrettable substitution.