# Discussion

In this review we sought to identify, synthesize and summarize the existing evidence based on associated health outcome or biological response for 24 BPA structural or functional analogues. The systematic literature search identified 166 relevant studies as well as data from the publicly available databases for the high throughput screening platforms Tox21 and ToxCast and the ECHA database. From the published literature and database searches we identified one or more studies for 17 of the BPA analogues and no studies for seven of the chemicals. The majority of the available data were in vitro (n = 130 studies), but there were also a significant amount of animal (n = 39 studies) and a few human studies (n = 4). The in vitro work focused largely on the ability of the BPA analogues to act as endocrine disrupting chemicals by binding to, activating or antagonizing various steroid receptors. Of the BPA analogues with one or more study available, there is growing evidence suggesting that most are of high concern. Eight of the 16 chemicals reviewed here and in the DfE received either a high or very high hazard ID in one or more category of human health effect or ecotoxicity (4,4-BPF, BPC, BPS, BPS-MAE, BPS-MPE, D8, Pergafast 201, and TGSA), indicating that these chemicals are of high concern.^15^ However, these conclusions were not always based on empirical, publicly available data. The current review adds additional information and makes greater use of available in vitro data by presenting the biological and chemical similarities of the BPA analogues. When considered together, these data highlight that BPAF, BPAP, BPB, BPE, BPP, BPZ, and TMBPA are also of concern given their ability to affect endocrine related endpoints at concentrations below 1 µM. For the remaining BPA analogues, there is an overall lack of empirical evidence from which to draw conclusions. In some cases, the hazard classifications seem to range from low to moderate (UU, D-90) based on confidential studies submitted to US EPA.^15^ For others (BPPH, 2,4-BPS, DD-70, MBHA, BTUM) there are estimates of high ecotoxicity hazard but empirical evidence is lacking.^15^ Importantly, a lack of evidence does not indicate a lack of effect, rather it indicates that more research is needed to fully characterize the biological activity of the data poor BPA analogues.

## Data Gaps and Research Needs

For some BPA analogues (4,4-BPF, BPAF, BPAP, BPB, BPC, BPE, BPP, BPPH, BPS, BPZ, Pergafast 201, TMBPA) there is sufficient evidence to suggest the potential for endocrine disruption. Despite this, we noted several limitations to the evidence base:

- Some chemicals are very data poor. For seven chemicals (BPS-MPE, BTUM, D-90, DD-70, MBHA, TGSA, UU) there were no studies either in the published literature or publicly available databases. Only 10 of the 24 chemicals were investigated in three or more studies.
- While not the focus of this review, it is apparent that there is a need for more exposure assessment. This information would help prioritize which data poor chemicals should be assessed in additional toxicological testing. As it is, the lack of exposure information makes it difficult to prioritize the data poor chemicals for subsequent testing, even when there is concern for potential hazard.
- For three chemicals (BPS-MAE, BDP, and Pergafast 201), the majority of available data was found in the ECHA database. While most of the studies included in the ECHA database are conducted according to guideline study procedures, the reports in the ECHA database are generally lacking in presentation of study details, including methods and effect sizes.
- Risk of bias was assessed for the animal studies identified from the published literature (Figure A-22) and from the ECHA database (Figure A-23). Overall there was a general lack of reporting of key study features including randomization to study groups, allocation concealment, and blinding research personnel throughout the study and at outcome assessment. Future studies should include appropriate considerations in study design, conduct, and reporting in order to minimize bias for the exposure and outcomes considered. At a minimum, studies should include randomization of treatment and blinding of outcome assessors.
- It is important to fully characterize the nature of the dose response of each chemical on the various biological endpoints. The majority of in vitro and in vivo studies utilized more than one dose of the chemicals. The exception, however, was the assessment of gene expression which was most often performed with only a single treatment level. For a few chemicals, the only evidence for a given effect is based on a test of a single dose (e.g., MCF7 cell proliferation after treatment with BPP or BPZ). We strongly encourage researchers to perform a full dose response for all main effects tested in research studies. In this regard, since many of the endpoints examined pertain to disruption of the endocrine system, it is important that researchers be aware of the possibility for non-monotonic response curves and include low, environmentally relevant doses.
- Along similar lines, it was not always clear from some of the in vitro studies exactly what doses were tested. In some instances, only an AC_50_ was presented with no indication of the range of doses tested [e.g., Zhang et al.^137^] In other instances, results were presented qualitatively (+ or – activity) [e.g., Kolle et al.^138^] or relative to a positive control [e.g., Coleman et al.^139^], which makes comparison of results across studies difficult. Characterization with and without metabolic activation was primarily only evident in studies of genotoxicity. While some in vitro studies utilized cell lines that display limited metabolic competency, others did not. Given how metabolism can dramatically alter the activity of these and similar chemicals, future research would benefit from further exploring this question.

## Limitations of the Review

This review used a systematic review methodology to search for and extract the available data for 24 BPA analogues as of March 2015. As stated in the objectives, the aim of this review was to extract and compile all of the available evidence for this set of chemicals. Given the number of chemicals investigated, the diversity of the various biological effects that were reported, and the lack of an available tool for assessing risk of bias of in vitro studies, providing evidence synthesis conclusions was not an aim of this review. Rather, this review has highlighted the extent and nature or dearth of information available for these 24 BPA analogues. While this review was being conducted, BPA structural and functional analogues have continued to receive much needed research attention. Therefore, a further limitation of this review is the difficulty in incorporating the rapidly growing literature in this field. As such, we are aware of several more recent studies that have not been included in this data synthesis [for example Kataria et al.^140^; Catanese and Vandenberg^141^; Wang et al.^142^; Chen et al.^143^].