# Results

## Literature Search Results

The literature searches yielded 5,124 unique studies and an additional 8 studies were identified while reviewing included studies. Of these, 4,783 were excluded during title and abstract screening. Three hundred forty nine studies were reviewed at the full text level, and 166 were identified as relevant to the PECO statement (Figure 1). Nine of the 166 studies (5%) were non-English.^55-63^

Figure 1

Study Flow Diagram

Study flow diagram. Describes the number of studies processed at each step of the evaluation. ^a^Records were broadly characterized by evidence stream (human, animal, in vitro), type of health outcome, and chemical. No results are extracted or summarized.

There was very little to no toxicity data available for many of the BPA analogues. Sixteen of the 24 BPA analogues had been reported on in at least 1 publication, but only ten had been evaluated in more than three studies. Most studies reported on in vitro data (n = 130), whereas fewer (n = 40) reported on in vivo data and only 4 studies reported on human epidemiological data (Figure 1, Table 3). There were no studies recovered from the literature search for eight of the 24 BPA analogues (BPS-MAE, BPS-MPE, BTUM, D-90, DD-70, MBHA, TGSA, UU). These eight BPA analogues were listed in the 2014 US EPA DfE Report where their potential hazards were summarized based largely on values from estimation software, professional judgment, analogy to experimental data for a structurally similar compound, or, where available, submitted confidential studies^15^ (Supplemental Table 11, posted online). One of these chemicals (BPS-MAE) and BDP, BPS, and Pergafast 201 were included in the ECHA database (See Appendix A. Supplemental Materials).

Table 3 Inventory of Published Literature by Chemical and Evidence Stream

Chemical | Human | Animal | In Vitro
4,4-BPF | 3 | 15 | 61
BPS | 1 | 9 | 52
BPAF | 0 | 10 | 41
BPB | 0 | 9 | 35
BPC | 0 | 5 | 22
BPE | 0 | 3 | 23
BPZ | 0 | 3 | 15
TMBPA | 0 | 1 | 14
BPAP | 0 | 2 | 9
BPP | 0 | 0 | 6
2,2-BPF | 0 | 2 | 1
BDP | 0 | 1 | 2
2,4-BPS | 0 | 1 | 1
BPPH | 0 | 0 | 2
D-8 | 0 | 0 | 2
Pergafast 201 | 0 | 0 | 1

## Survey of Evidence

### Human Evidence

Four human studies reported information on exposure to BPA analogues and contact dermatitis.^64-67^ No other health outcomes were assessed in the human studies. In the four human studies patients or workers with suspected allergic contact dermatitis were patch tested with one or more of the BPA analogues or additional chemicals that they may have come in contact with including plastics, epoxy resins, glues, and hardeners. Dermal patch testing with BPF (both the 2,2- and 4,4-isomers) caused some reactions in patients or workers.^64,65,67^ In contrast, dermal patch testing with BPS did not elicit an effect.^66^

### Animal Evidence

Forty experimental animal studies reporting on 13 BPA analogues were identified from the published literature and are summarized in Table 4 following the definitions provided in.^15^ The most commonly studied BPA analogues were 4,4-BPF (n = 15 studies), BPAF (n = 10 studies), BPB (n = 9 studies) and BPS (n = 9 studies). Eleven studies assessed uterotrophic responses (4,4-BPF, BPS, BPZ, BPB, 2,2-BPF, BPAF, BPC, BPAP), five studies assessed subchronic exposure (BPAF, 4,4-BPF, BPZ, BPS), eleven studies assessed sensitization), and none assessed chronic toxicity. Doses in rodent studies ranged from 2 to 32,000 mg/kg-day. Only one rodent developmental study, for BPAF, was identified from the published literature.^68^ Otherwise all developmental or reproductive studies from the published literature were in fish models testing concentrations of 0.1 to 1,500 µg/L. Additional animal studies including developmental, reproductive and aquatic toxicology endpoints were identified in the ECHA database for BPS, BDP, BPS-MAE, and Pergafast 201 (Table 4).

Table 4 Summary of Animal Evidence

Number of Studies | 4,4-BPF | BPS | BPAF | BPB | BPC | BPE | BPZ | TMBPA | BPAP | 2,2-BPF | BDP | 2,4-BPS | BPS-MAE | Pergafast
Number of Studies | 15 | 9 [31] | 10 | 9 | 5 | 3 | 3 | 1 | 2 | 2 | 1 [126] | 1 | [21] | [14]
Endpoint Classification (Number of Studies by Endpoint)
Acute Toxicity | 1^R^,1^Rb^ | 1^R^, 1^Rb^, 1^GP^ [5^R^, 2^M^, 2^GP^] | 1^R^ | – | 1^R^ | – | – | – | – | – | [21^R^, 2^M^] | 1^R^, 1^Rb^ | [4^R^] | [3^R^]
Carcinogenicity | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Reproductive | – | 2^ZF^ [1^R^] | 2^ZF^ | – | – | – | – | – | – | – | [2^R^] | – | [1^R^] | [1^R^]
Developmental | 1^ZF^ | 2^ZF^ [1^R^] | 1^R^, 3^ZF^ | 1^ZF^ | – | 1^ZF^ | – | – | 1^ZF^ | – | [9^R^] | – | [2^R^] | –
Neurological | – | 1^ZF^ | – | – | – | – | – | – | – | – | | – | – | –
Repeated Dose | 1^R^ | 1^R^ [3^R^] | 2^R^, 1^ZF^ | – | – | – | 1^R^ | – | – | – | [16^R^] | – | [1^R^] | [3^R^]
Skin Sensitization | 1^GP^ | 1^GP^ [1^M^, 2^GP^] | – | – | – | – | – | – | – | 1^GP^ | [14^GP^] | – | [2^GP^] | [1^GP^]
Eye Irritation | 1^Rb^ | 1^Rb^ [4^Rb^] | – | – | 1^Rb^ | – | – | – | – | – | [13^Rb^, 1^P^] | – | [2^Rb^] | [1^Rb^]
Dermal Irritation | 1^GP^, 1^Rb^ | 1^GP^ [3^Rb^, 1^GP^] | – | – | 1^Rb^ | – | – | – | – | 1^GP^ | [13^Rb^] | – | [2^Rb^] | –
Endocrine Activity | 8^R^ | 1^R^, 1^ZF^ | 3^R^ | 7^R^ | 1^R^ | – | 2^R^ | 1^Fr^ | 1^R^ | 1^R^ | – | – | – | –
Aquatic Toxicity (Acute) | 1^D^ | 2^D^ [2^F^, 2^D^] | – | 1^D^ | 1^D^ | 1^F^, 1^D^ | – | – | – | – | 1^D^ [12^F^, 14^D^] | – | [2^F^, 2^D^] | [1^ZF^, 1^D^]
Aquatic Toxicity (Chronic) | – | [1^D^] | – | – | – | – | – | – | – | – | [1^ZF^, 1^F^, 8^D^] | – | [1^F^, 1^D^] | [1^F^, 1^D^]
Other Studies | 1^M^, 1^GP^ | 1^F^ | – | – | 2^P^ | – | – | – | – | – | – | – | – | –
Doses Tested
Range (mg/kg) in Mammalian Studies | 2–1,000 | 10–32,000 | 4–11,000 | 2–600 | 25–63 | – | 6–300 | – | not listed | 2–200 | 15–5,000 | 1,400–10,000 | 100–2,000 | 12.5–2,000
Range (µg/L) in Aquatic Studies | 200–14,016 | 0.1–500,000 | 5–23,536 | 242–16,692 | – | 214–14,998 | – | 2.84–284 | 290–20,325 | – | 21–100,000 | – | 66–14,000 | 890–86,000

Superscript indicates species: ^R^Rat, ^M^Mouse, ^GP^Guinea Pig, ^Rb^Rabbit, ^P^Poultry, ^Fr^Frog, ^ZF^Zebra Fish, ^F^Other Fish, ^D^Daphnia.

Numbers in [ ] are from ECHA database and are not included in any of the summary or overall counts. – indicates no studies were found.

### In Vitro Evidence

One hundred thirty in vitro studies reporting on 16 BPA analogues were identified in the published literature. These studies are summarized in Table 5. Although many of the studies evaluated multiple BPA analogues or other chemicals, approximately half (70/130) reported on the effects of only a single BPA analogue, thus limiting ability to make direct comparisons across studies on the BPA analogues. Eighty-six of the 130 studies evaluated the ability of the BPA analogues to interact with nuclear receptors; for example, interaction with the estrogen receptor was reported in 68 studies and interaction with the androgen receptor was reported in 18 studies). In vitro studies of genetic toxicity were also summarized in the ECHA database for BPS, BDP, BPS-MAE, and Pergafast 201 (Table 5).

Table 5 Summary of In Vitro Evidence

| 4,4-BPF | BPS | BPAF | BPB | BPC | BPE | BPZ | TMBPA | BPAP | BPP | 2,4-BPS | 2,2-BPF | BDP | BPPH | D-8 | Pergafast 201 | BPS-MAE
Number of Studies in Published Literature | 61 | 52 | 41 | 35 | 22 | 23 | 15 | 14 | 8 | 6 | 1 | 1 | 2 | 2 | 2 | 1 | 0
Endpoint Classification (Total Number for Each Endpoint)
Estrogen Receptor (68) | 32 | 26 | 29 | 25 | 13 | 13 | 11 | 8 | 5 | 3 | – | 1 | – | 1 | 2 | [1] | –
Androgen Receptor (18) | 13 | 11 | 5 | 6 | 3 | 4 | 2 | 1 | – | – | – | – | – | – | 1 | 1 | –
Thyroid Receptor (6) | 1 | 1 | 3 | 1 | 3 | 1 | – | 4 | – | – | – | – | – | – | – | – | –
Cytotoxicity (11) | 2 | 7 | 1 | 1 | 1 | 1 | – | – | – | – | – | – | 1 | – | 1 | 1 | –
Miscellaneous/Not Otherwise Classified (25) | 13 | 11 [1] | 1 | 3 | 1 | 3 | – | 3 | 1 | – | – | – | 1 | – | 1 | 1 | –
Adipocytes (3) | 2 | 2 | – | 2 | – | 2 | – | – | – | – | – | – | – | – | – | – | –
Pregnane X Receptor (3) | 3 | 3 | 2 | 1 | – | 1 | 1 | 1 | – | – | – | – | – | – | – | – | –
Constitutive Androstane Receptor (2) | 2 | 2 | 1 | – | – | – | 1 | 1 | – | – | – | – | – | – | – | – | –
Estrogen Related Receptor γ (3) | 2 | 1 | 3 | 2 | – | 2 | – | – | 1 | – | – | – | – | – | – | – | –
Retinoic Acid Receptor γ (2) | 2 | 2 | – | 2 | – | 2 | 1 | – | – | – | – | – | – | – | – | – | –
Retinoid-related Orphan Receptor γ (1) | 1 | 1 | – | – | 1 | 1 | 1 | – | 1 | 1 | – | – | – | 1 | – | – | –
Glucocorticoid Receptor (3) | 2 | 2 | 1 | – | 1 | – | 1 | – | – | 1 | – | – | – | – | – | – | –
Aryl Hydrocarbon Receptor (1) | 1 | 1 | – | 1 | – | 1 | – | – | – | – | – | – | – | – | – | – | –
Albumin or SHBG Binding (5) | 1 | 2 | 2 | 1 | – | – | – | – | – | – | – | – | – | – | – | – | –
Genotoxicity (14) | 8 | 6 [10] | 5 | – | 6 | 1 | 1 | 1 | 1 | 1 | 1 | – | [36] | – | – | [3] | [4]

Numbers in [ ] are from ECHA database and are not included in any of the summary or overall counts.

– indicates no studies were found.

## Health Outcomes and Mechanistic Findings

### Repeated Dose Effects

Subchronic effects of repeated exposure (13–28 days) to BPAF, 4,4-BPF, BPZ or BPS were evaluated in five rodent studies in the published literature^69-73^ (Figure A-1, Figure A-2) and 23 additional studies in the ECHA database. These studies evaluated changes in body and organ weight as well as other signs of toxicity, such as clinical chemistry. Overall, the most sensitive endpoints include body, kidney, brain, and liver weight (Table 6). In addition to the publicly available literature, there were 28- and 90-day repeated dose studies available in the ECHA database for BPS, BPS-MAE, BDP and Pergafast 201 (Table 6). BDP did not appear to cause any treatment related effects, including on body weight,^74,75^ and there were no study details available for the one study reporting subchronic exposure of rats to BPS-MAE.^76^

Table 6 Summary of Most Sensitive Endpoints in Subchronic Studies

Study | Animal Group | Endpoint | Doses Tested (mg/kg/-day) | NOEL (mg/kg-day) | LOEL (mg/kg-day) | Direction of Change (% Change Relative to Control at LOEL)
Published Literature
4,4-BPF
Higashihara et al.^69^ | Female Crj:CD (Sprague-Dawley) rat | kidney weight | 20, 100, 500 | 20 | 100 | ↑ (8.1%)
Higashihara et al.^69^ | Female Crj:CD (Sprague-Dawley) rat | body weight | 20, 100, 500 | – | 20 | ↓ (11.6%)
Higashihara et al.^69^ | Female Crj:CD (Sprague-Dawley) rat | brain weight | 20, 100, 500 | – | 20 | ↑ (14.1%)
BPAF
Feng et al.^71^ | Male Sprague-Dawley rat | body weight | 2, 10, 50, 200 | 10 | 50 | ↓ (12.3%)
Umano et al.^70^ | Female Sprague-Dawley rat | body weight | 10, 30, 100 | 10 | 30 | ↓ (7.3%)
BPZ
Yamasaki and Okuda^72^ | Male CRL:CD (Sprague-Dawley) rat | heart weight | 30, 100, 300 | 30 | 100 | ↓ (10.9%)
Yamasaki and Okuda^72^ | Male CRL:CD (Sprague-Dawley) rat | serum T4 | 30, 100, 300 | – | 30 | ↑ (14.7%)
ECHA Database
BPS | Male Wistar rat | kidney weight | 100, 300, 1000 | – | 100 | ↑ (10%)
BPS-MAE | Female Crj:CD (Sprague Dawley) IGS rat | clinical signs | 40, 200, 1000 | 200 | – | Details not provided.
BPS-MAE | Male Crj:CD (Sprague Dawley) IGS rat | kidney weight | 40, 200, 1000 | 40 | 200 | ↑ (Details not provided.)
BDP | Male and female Sprague-Dawley rat | – | – | 1000 | – | Details not provided.
Pergafast 201 | Female Wistar rat | liver weight | 12.5, 25, 50, 150 | – | 12.5 | ↑ (14.7%)

– indicates no studies were found.

### Reproductive and Developmental Effects

Only one rodent developmental study was identified from the published literature. In this study, rats were dosed with BPAF via gavage at 200 to 500 mg/kg-day from gestation day 14 to 18 and testosterone production was evaluated in the male offspring at gestation day 18.^68^ Developmental exposure to BPAF did not alter fetal testosterone production in this assay. In addition, there were reproductive and developmental rodent studies identified in the ECHA database for BPS, Pergafast 201, BDP, and BPS-MAE, which are summarized in Supplemental Table 1, posted online.

Pergafast 201 decreased F1 body weight at the same dose that caused maternal kidney and liver toxicity (200 mg/kg-day). BPS reduced the number of F1 offspring at the same dose that disrupted maternal estrus cyclicity and implantation (300 mg/kg-day). There were no effects reported for BDP and no information available for BPS-MAE.

Reproductive and developmental effects of exposure to six BPA analogues (4,4-BPF, BPS, BPAF, BPB, BPE, BPAP) were tested in zebrafish models (Table 4).^77-82^ Developmental exposure to all of these BPA analogues except 4,4-BPF (which was only tested in a single study) caused some degree of morphological malformation ranging from pericardial edema to otic vesicle deformities, for example. Steroidogeneisis and hatching endpoints were disrupted in adult zebrafish exposed to BPS or BPAF.^79,81^

### Estrogenic and Anti-estrogenic Activity

Seven studies evaluated the effects of BPAF, BPB, 2,2-BPF, 4,4-BPF, BPS, and BPZ on the uterotrophic response and 68 studies assessed estrogenic effects in vitro, mostly for 4,4-BPF (32), BPS (26), BPAF (29), BPB (25), BPC (13), BPE (13), TMBPA (8), and BPAP (6) (Table 5). Like BPA, the BPA analogues were shown to have varying levels of estrogenic activity in the test systems evaluated, but the majority had activity within the same order of magnitude as BPA. However, all chemicals tested were less potent than positive control reference agonists such as E_2_.

In vivo estrogenic endpoints evaluated included (a) the uterotrophic response (Figure 2, Figure A-3, Figure A-4),^83-89^ (b) the uterine glycogen deposition response,^90^ (c) assessment of vaginal smears for cornified cells,^87,91-93^ and (d) measurement of vitellogenin^78,80-82^ or other E_2_-responsive genes in fish.^79^ The uterotrophic assay is a standard assay in which juvenile or ovariectomized rodents are administered test substance for three to five days after which time the effects on uterine growth are observed. The BPA analogues tested in this assay (BPAF, BPB, 2,2-BPF, 4,4-BPF, BPS, BPZ) were all uterotrophic (Figure 2, Figure A-3, Figure A-4). Because the chemicals were not tested over the same dose range it is difficult to assess which chemical is the most potent in this assay. In general, however, 2,2-BPF and BPS appeared to be weaker than the other tested analogues. Another well-characterized assay for determining estrogenicity is the induction of vitellogenin (VTG) gene or protein expression in juvenile or male fish. BPS^80^ and BPAF^78,81,82^ both induced plasma or liver VTG expression (Figure A-5). In the one study that evaluated both BPA and BPAF, BPAF was more potent (more estrogenic) than BPA at inducing VTG.^82^

Figure 2

Estrogenic Activity

(A) Summary of uterotrophic responses (dry, absolute uterine weight) following three days of exposure in weanling rats. Live link with all available uterotrophic data available in Figure A-3; (B) Summary of uterotrophic responses (dry, absolute uterine weight) by dose and % change from control for studies with subcutaneous exposure. Live link available for all routes of exposure and data reporting subtypes (dry or wet weight, relative or absolute) available in Figure A-4; (C) Scatterplot showing the relationship between reported AC_50_ values (µM) for BPA and BPAF, 4,4-BPF or BPS. Agonist assays are shown with closed diamonds and antagonist assays are shown with open circles. The color of the symbol indicates the type of assay (androgen-blue; estrogen-red; cell toxicity-black, estrogen related receptor (ERR)-purple, glucocorticoid receptor-green; steroidogeneisis of other hormones-orange). When the BPA analogue has an AC_50_ more potent than BPA the points fall above the black line and when the BPA analogue has an AC_50_ less potent than BPA the points fall below the black line.

In vitro estrogenic endpoints were evaluated for fourteen BPA analogues in 68 studies (Table 5). In vitro estrogenic endpoints evaluated included (a) receptor binding, (b) modulation of cellular proliferation, (c) modulation of reporter genes transfected into immortalized cell lines, (d) modulation of endogenous estrogen-responsive genes and proteins (e.g. progesterone receptor) or steroidogenesis, (e) the ability to recruit co-regulatory elements, (f) induction of non-genomic signaling pathways, and (g) interaction of ER with ERE. Because of the wealth of in vitro estrogenic endpoints, the results of each of these types of assays is discussed in detail in Appendix A. Supplemental Materials.

The largest number of chemicals were tested in the MCF7 cell proliferation and the reporter gene assays (Table 7). Ten of the BPA analogues demonstrated estrogen receptor agonism in one or more of the assays at concentrations ≤1 µM (BPE, BPP, BPAF, BPS, 4,4-BPF, BPC, BPB, BPZ, BPAP, TMBPA). BPAF was consistently one of the most potent BPA analogues in the estrogen agonist and antagonist assays (Figure 2C). Conversely BPS and TMBPA, tended to be some of the least potent BPA analogues (Figure 2C, Table 7). BPE was interesting in that it was one of the most potent BPA analogues in stimulating MCF7 cell proliferation^56^ but one of the weakest at binding ER.^94^ D8 was not active in any of the estrogen activity assays it was tested in (ER binding, reporter gene, and steroidogenesis assays)^95-97^ but did antagonize E_2_ activity at 50 µM.^95^ In Tox21 BPAF was the most potent ER agonist of the BPA analogues, and was more potent than BPA. BPZ, BPC, TMBPA, 4,4-BPF, BPB, BPE, BPS displayed ER agonism similar to BPA (AC_50_ between 0.2 and 2 µM). PHBB was weaker (AC_50_ ~20 µM). 2,2-BPF, TCBPA, TBBPA only stimulated the partial receptor at ~50 µM. ER antagonism at ~50 µM was observed for TGSA, TCBPA, BPZ, BPC, TMBPA, BPAF, BPE, and BPB.

Table 7 Summary of In Vitro Estrogen Endpoints

Lowest Effect Level Reported (µM)
| ER Binding | MCF7 Cell Proliferation | Reporter Gene Assay | Tox21 ER Reporter Assay | Endogenous Gene and Protein Expression^a^ | Steroidogenesis | ER Binding to ERE
BPE | 100 | 0.00001 | 0.01 | – | 10 | 3.14 | –
BPP | – | 0.00001 | 2.51 | – | – | – | –
BPAF | 0.0003 | 0.001 | 0.001 | – | 0.01 | – | 0.01
BPS | 1 | 0.01 | 0.0001 | – | 10 | ND | 1
4,4-BPF | 0.01 | 0.01 | 0.01 | – | 1 | 3.14 | 0.01
BPC | 0.01 | 0.01 | 0.04 | – | 0.1 | – | 1
BPB | 0.023 | 0.01 | 0.1 | – | 0.1 | 6.25 | 0.01
BPZ | – | 10 | 0.0043 | – | 10 | – | 0.01
BPAP | – | 10 | 5 | – | 10 | – | 0.01
BPPH | – | 10 | – | – | – | – | –
TMBPA | – | – | 0.73 | – | 1 | – | 0.01
D-8 | ND | – | ND | – | – | ND | –
Pergafast 201 | – | – | – | – | – | ND | –

^a^ Most of these tested at only a single dose. ND, not detected.

### Androgenic and Anti-androgenic Activity

In vivo endpoints to assess androgen-regulated outcomes included (a) the Hershberger assay,^85^ (b) disruption of testis function in rats exposed as adults^71^ or developmentally,^68^ and (c) male reproductive organ weights after subchronic exposure.^69-71,98-100^ The lack of effects following developmental and subchronic exposures to BPAF, 4,4-BPF, BPZ, BPS, BPS-MAE, BDP, or Pergafast 201 have already been discussed above.^68-72,74,75,98-101^ In the Hershberger assay adult male Brl Han:WIST Jcl rats were exposed for 10 days to 50, 200 or 600 mg/kg-day BPAF, BPB or 4,4-BPF via oral gavage.^85^ There were few effects reported from the Hershberger assay except that exposure to BPB (200 and 600 mg/kg-day) and BPAF (200 mg/kg-day) decreased the relative bulbo cavernous/levator 2ani muscle weight and BPAF (600 mg/kg-day) increased relative glans penis weight (Figure A-13).

Both androgen agonism (Figure A-14) and antagonism (Figure A-15) were assessed in vitro. Androgen endpoints in vitro included (a) receptor binding, (b) reporter gene activity, (c) cellular proliferation, and (d) steroidogenic production of testosterone, androstenedione, or dehydroepiandrosterone. Androgen receptor (AR) binding was only explored for two analogues, BPB and BPS; BPB was found to bind AR with similar potency to BPA^102,103^ whereas BPS only bound AR weakly.^102^ Eight analogues (BPAF, BPB, BPC, BPE, 4,4-BPF, BPS, BPZ, TMBPA) were tested for AR agonist activity (Figure A-14). There was very limited evidence of weak agonism for two analogues (4,4-BPF, and BPS), but this was not replicated in other studies of the same chemicals. All eight analogues were, however, anti-androgenic in the range of 0.01 to 100 µM (Figure A-15). TMBPA and BPAF were the most potent anti-androgens, with TMBPA ten times more potent that the positive control anti-androgen flutamide.^104^ Of the anti-androgenic analogues, BPS appeared to be the weakest, acting as an anti-androgen in some assays but not others. Two additional BPA analogues, D-8 and Pergafast 201, were also tested for AR activity in a single study in which neither analogue altered androgen steroidogenesis^97^ (Figure A-11). In Tox21, none of the analogues were AR agonists. Like BPA, TBBPA, BPAF, BPB, BPZ, BPE, 4,4-BPF, 2,2-BPF, BPC, TGSA, TMBPA were AR antagonists in the Tox21 assays between 3 and 100 µM. BPS, TCBPA, PHBB, were inactive in Tox21 AR antagonist assays.

### Thyroid and Anti-thyroid Activity

In vivo studies of thyroid disruption were identified for 4,4-BPF, BPAF, BPS, TMBPA, and BPZ and included evaluation of thyroid hormone levels in rats^69,70,72^ or fish,^80,81^ and disruption of frog metamorphosis^105^ (Figure A-16). Subchronic (28 day) studies were performed in young adult rats in which increased plasma T4 was observed in males exposed to 4,4-BPF (500 mg/kg-day),^69^ BPAF (100 mg/kg-day),^70^ or BPZ (30 mg/kg-day)^72^ and in females exposed to 4,4-BPF (20 mg/kg-day) and BPAF (100 mg/kg-day). In male rats treated with 500 mg/kg-day 4,4-BPF the T4 increase was accompanied by a decrease in plasma T3 and an increase in relative thyroid weight.^69^ In adult zebrafish treatment for 75 days with BPS or 28 days with BPAF had seemingly opposite effects: exposure to BPS reduced plasma T3 and T4 in males (10 and 100 µg/L) and females (100 µg/L), whereas exposure to BPAF increased whole body homogenate levels of free T3 in females at 1000 µg/L but had no effect in males.^80,81^ In developing frogs TMBPA treatment (28.4 and 284 µg/L) for 9 days suppressed tail regression and spontaneous metamorphosis.^106^

In vitro studies of thyroid hormone receptor activity were identified for 4,4-BPF, BPS, BPAF, BPB, BPC, BPE, and TMBPA^104,107-111^. Endpoints used to assess thyroid hormone activity in vitro included (a) TR binding, (b) TR reporter gene activity in yeast, (c) growth hormone (GH) production in GH3 pituitary cells, (d) cellular proliferation of GH3 cells, and (e) inhibition of deiodinase or sulfotransferase activity in liver microsomes as a measure of receptor antagonism (Figure A-17, Figure A-18). Receptor binding was only assessed for TMBPA and BPC, both of which bound TR within the range of 1-100 µM.^107^ TMBPA induced TRα and β mediated reporter gene activity between the doses of 1 and 10 µM^110^ and GH production in GH3 cells,^104^ but did not induce GH3 cell proliferation.^111^ The opposite effects were noted for BPC, which stimulated GH3 cell proliferation,^111^ but did not induce GH production.^104^ There was no evidence that BPAF, BPB, BPE, 4,4-BPF, or BPS were thyroid hormone agonists as none of these chemicals stimulated GH production in GH3 cells.^104^ BPAF, however, disrupted thyroid hormone homeostasis by inhibiting deiodinase and sulfotransferase activity in liver microsomes.^108,109^ In the Tox21 assays there is no evidence that the BPA analogues were TR agonists or antagonists with the exception of TCBPA, which appeared to be a TR antagonist but this was confounded by concurrent cytotoxicity.

### Other Receptor Activity

The ability of BPA analogues to interact with additional nuclear receptors (PXR, CAR, ERRγ, RARγ, RORγ, GR, and AhR) was also explored in the in vitro studies we identified (Figure A-19). There were three or fewer in vitro studies identified for each of these nuclear receptors. Of these, only ERRγ was also evaluated in vivo, where three of five tested BPA analogues disrupted otolith development in zebrafish.^77^ In vitro 4,4-BPF, BPAF, BPB, and BPE bound ERRγ, induced the expression of a reporter gene, and antagonized the activity of the ERRγ inverse-agonist 4-hydroxytamoxifen.^112,113^ Several of the analogues were found to be agonists for PXR and one or more CAR isoform (4,4-BPF, BPAF, BPB, BPE, BPZ, TMBPA),^114,115^ which was consistent with the results from Tox21 that indicated these and BPC to be agonists and BPZ and BPAF to be CAR antagonists. However, some of these findings were not repeated with endogenously expressed receptors.^116,117^ TMBPA, BPAF, BPC BPB, were found to be GR antagonists in Tox21. Though there was relatively little information on GR activity in the published literature it appeared that 4,4-BPF competitively bound GR but BPP and BPS did not.^118,119^ 4,4-BPF, BPB, BPE, and BPZ did not bind RARγ, nor did they or BPAF, BPAP, BPC, and BPS bind RORγ.^120,121^ In contrast, in the Tox21 analysis, BPAF, BPC, BPB, TGSA were identified as RORγ antagonists.

### Acute Toxicity and DNA Damage

Acute oral and dermal toxicity studies reported the lethality in 50% of the exposed animals (LD_50_) following a single exposure. The studies identified from the database search all appeared to be company documents submitted to US EPA and contained very few study details.^73,122-124^ Of these studies, BPC had the lowest LD_50_ of 25 mg/kg in orally exposed mice. The oral LD_50_ for BPAF, 2,4-BPS, and BPS ranged from 3,600 to >7,000 mg/kg. Several studies of acute oral and dermal toxicity for BPS, Pergafast 201, BDP and BPS-MAE were also identified in the ECHA database where the LD_50_ was in the rage of 1,600 to >5,000 mg/kg.

In vitro analyses of DNA damage and toxicity were identified in the published literature as well as in the ECHA database and included (a) Ames test, (b) CHO/HGPRT mutation assay, (c) chromosomal aberration assays, (d) Comet assay, (e) micronucleus assay, (f) cellular proliferation, (g) cell transformation assay, and (h) expression of p53 or γH2AX (Figure A-20). The tests use different cell types, different methods with or without metabolic activation, and not all reported if concurrent cytotoxicity was an issue. As noted in the figure, a large number of the studies found some increase in genotoxicity compared to vehicle treatment conditions. There were also some decreases in measures of genotoxicity that could not always be explained by increases in cytotoxicity. 4,4-BPF was the most studied (Table 5) with increases in genotoxicity noted in the Ames assay with and without metabolic activation and in cell transformation studies. Similar results were also observed with BPAF, but more consistent results were observed for increased chromosomal aberration. Genotoxicity was consistently increased by BPC as observed in the cell transformation, chromosomal aberration, micronuclei assays, or the Ames assay with or without metabolic activation. The other analogues tested for genotoxicity (BPAP, BPB, BPE, BPP, BPS, BPZ, and TMBPA) either had conflicting results or there were not enough of the same tests to form conclusions (Figure A-20), but there was a suggestion of increased genotoxicity for each of these. In Tox21, BPAF and BPB induced p53 between 50 and 60 µM. In most cases the mitochondrial toxicity assay was the most sensitive assay for cell stress in Tox21. For the most part the AC_50_ for mitochondrial toxicity was ≥10 µM, except for TCBPA and BPAF, in which the AC_50_ was <5 µM. There were no indications of DNA damage or cell stress after BPS exposure in the Tox21 assays.

### Other Endpoints

A handful of additional endpoints have been explored for the BPA analogues. Binding to alpha fetoprotein or sex hormone binding globulin has been evaluated for BPB, 4,4-PBF, and BPAF.^103,125,126^ In vitro neurotoxicity was assessed for BDP and BPAF.^127,128^ A few studies evaluated the lipid metabolism and adipogenic activity of BPS, BPB, 4,4-BPF, and BPE.^117,129,130^ Along with various other phenolic compounds, 4,4-BPF has been extracted from the Chinese medical herb Gastrodia elata Blume and has been evaluated as a smooth muscle relaxant^63,131^ an anti-inflammatory,^132^ and a platelet anti-aggregating agent.^133^ Other miscellaneous effects explored include the effects of BPS on rat hearts and isolated myocytes,^134^ inhibition of the hypoxic response of human hepatoma cells,^135^ and stimulation of cells to release alkali metal cations.^136^

## Structural and Biological Similarity Analysis

The analyses of BPA analogues in chemical structure and HTS space is unique because not only do they allow for more analogues to be directly compared to one another than in any of the published reports, but they can also provide a broader perspective of how similar the chemicals are when considered in the context of a larger chemical set such as the entire Tox21 library (>8,000 chemicals).

### Structural Similarity Analysis

The structural similarity to BPA or E_2_ was assessed for the 25 BPA analogues that were tested in Tox21 (Figure 3). Two BPA analogues, D-90 and UU, were not considered in this analysis because they are polymers. Using chemical structural features to evaluate the relationship between E_2_ and the BPA analogues shows a clear separation between E_2_ and the BPA analogues with BPZ being the most structurally similar to E_2_ (i.e., had the highest Tanimoto Coefficient). The BPA analogues are more structurally similar to BPA, with BPB, 4,4-BPF and BPE being very similar to BPA and TGSA and PHBB being most dissimilar. A complete list of Tanimoto similarity metrics between BPA and Tox21 library can be found in Supplemental Table 13 and Supplemental Table 14 (column E), posted online.

Figure 3

Structural Similarity of BPA Analogues to BPA and E_2_

Structural similarity of BPA analogues to (A) BPA or (B) E_2_. The horizontal axis is the Tanimoto coefficient (reverse scale; decreasing similarity left to right), a measure of similarity based on the presence or absence of structure features (Leadscope Enterprise v3.4) relative to the reference chemical. A larger coefficient indicates greater structural similarity. Dark circles indicate BPA analogues present in the Tox21 collection (note: BPPH, BPAP and BPS-MPE were only run in a limited number of Tox21 assays), triangles are BPA analogues absent from the collection (2,4-BPS, BPS-MAE, BPP, BPPH, DD-70, D-8, BTUM, MBHA, Pergafast 201, BDP), squares are BPA analogues present in the Tox21 collection, but not considered in elsewhere in this review (TBBPA, TCBPA, PHBB), and small circles are 8,278 non-BPA analogue chemicals from the Tox21 collection. Points are jittered in the vertical direction for clarity.

### Biological Similarity Analysis Based on HTS Data

Ten BPA analogues were tested either in ToxCast Phase II or the E1K library. These chemicals were tested in a range of 316 to 882 different medium or high throughput assays. Analysis of these chemicals in ToxCast, which covers a wider biological space than Tox21, included assays on cell cycle disruption, DNA binding, growth factors, cell adhesion molecules, cytokines, and proteases that were not assessed in Tox21. The BPA analogues were listed as active in anywhere from 4% to 30% of tested ToxCast assays, most typically in assays for nuclear receptors, DNA binding, GPCR, cell cycle, and cytokines (Figure A-21). Subsequent assessments of biological similarity consider only the Tox21 data because more chemicals were tested in this platform. Figure 4 shows the half-maximal concentration (AC_50_) for each BPA analogue in the Tox21 assays. The ER agonism assay was the most sensitive assay for 8 of the 13 BPA analogues tested in Tox21. The BPA analogues were similar to BPA in that they tended to be 100 to 10,000 fold weaker than E_2_ in stimulating ER activity. Based on evaluation of the dendogram in Figure 4, BPB had the most similar activity to BPA across the Tox21 assays, followed by BPC and BPAF. TGSA,which was not an ER agonist, had the most dissimilar activity compared to BPA, and was the only BPA analogue to activate the aryl hydrocarbon receptor (AhR). These findings are highlighted by the similarity of the ToxPI profiles for compounds within groups and the difference in ToxPI profiles between the groups (Figure 4).

Figure 4

Biological Similarity Analyses in Tox21

Biological similarity of BPA analogues evaluated in Tox21 HTS library. Plot and ToxPI depiction of selected assays based on half maximal concentrations (AC_50_). The 24 assays in which one or more BPA analogue was active are each represented by a different symbol in the plot. Chemicals are sorted on the x-axis based on their activity similarity. The dendogram beneath the scatterplot displays the Euclidean distance based on respective activities and a hierarchical clustering with average linkage. Raw data are available in Supplemental Table 8, posted online. In the ToxPI depiction of biological similarity the height of the pie slice for each assay category indicates how active that chemical is for that type of assay (i.e., –log(AC_50_)) relative to the most potent chemical-assay pair within the library (i.e., dioxin and AhR agonism). The dendogram was generated based on biological similarity across the assays shown. Abbreviations are as follows: Nuclear factor erythroid 2-related factor 2 (Nrf2), estrogen receptor (ER), androgen receptor (AR), farnesoid X receptor (Fxr), Aryl hydrocarbon receptor (AhR), peroxisome proliferator-activated receptor (PPAR), thyroid receptor (TR), glucocorticoid receptor (GR), constitutive androstane receptor (CAR), retinoid-related orphan receptor (ROR), retinol signaling pathway (RSP).

The biological activity of the 13 BPA analogues was compared to that of 14 pharmacological E_2_ analogues. In thirteen assays, including two AR antagonist assays, at least half of both the BPA analogue and E_2_ analogue sets had decreasing activity (indicating antagonism or cytotoxicity). In three assays, including two ER agonist assays, at least half of both analogue sets had increasing (agonist) activity. For 10 of the Tox21 assay channels, including PPAR antagonist and aromatase inhibition assays, the BPA analogues set tended to have decreasing activity, while the E_2_ analogue set was not consistently active. BPA analogues activated Nrf2 signaling whereas the pharmacological E_2_ analogues did not. A complete listing of results of the analysis can be found in Appendix A. Supplemental Materials, and Supplemental Table 10), posted online.

Another biological similarity analysis determined the relative similarity of 13 Tox21 BPA analogues (including TCBPA, TBBPA, and PHBB) in Tox21 to BPA and E_2_ in the context of the entire Tox21 library (Figure 5). This was done by determining the Pearson correlation coefficient between E_2_ or BPA and the entire Tox21 library. E_2_ appeared to be most similar to BPB and TMBPA. The least similar analogues to E_2_ were BPPH and BPAP, neither of which were significantly associated with E_2_. Overall, the BPA analogues exhibit much greater biological similarity to BPA than the average chemical in the Tox21 library. Like the above analysis, BPA appeared to be most similar to BPB, BPC, and BPE. The least similar analogues to BPA were BPS, BPAP and BPPH. All analogues, even those least similar to BPA, exhibited highly significant association with BPA in this analysis. Supplemental Table 13 and Supplemental Table 14, posted online, provide a complete listing of BPA and E_2_ correlation values, respectively, for the entire Tox21 library along with confidence intervals and an association statistic. Note: the values in the supplementary table are listed by substance (i.e., not averaged by CASRN) hence the same CASRN may have multiple correlation values.

Figure 5

Biological Similarity of BPA Analogues to E_2_ and BPA in Context of the Entire Tox21 Library

Biological similarity of BPA analogues to BPA and E_2_ in context of the entire Tox21 Library. The horizontal axis is the Pearson Correlation Coefficient (reverse scale; decreasing similarity left to right), computed from Tox21 HTS Assay profiles for BPA analogues each compared to BPA or E_2_. A larger coefficient (i.e., close to 1) indicates greater biological similarity to BPA. Dark circles are BPA analogues, squares are BPA analogues in the Tox21 library that are not considered elsewhere in this review (TBBPA, TCBPA PHBB), triangles are reference chemicals, and small circles are 6,053 non-BPA analogues from the Tox21 collection. Points are jittered in the vertical direction for clarity. Some chemicals are present in the chemical library more than once. For these chemicals, the Pearson Correlation Coefficients were averaged to acquire a single correlation value per CASRN identifier pair. No BPA analogues were negatively correlated. BPPH, BPAP and BPS-MPE were included in the Tox21 library, however they were only screened in a limited number of assays and are therefore not included in the analysis.

### Integrated Chemical and Biological Similarity

In vitro assay results such as those from Tox21 and chemical structure can provide complementary information on the biological effects of chemicals. We present in Figure 6 a plot that integrates the biological (from Figure 5) and chemical structure similarity (from Figure 3) of the BPA analogues relative to E_2_ and BPA. This was done in the context of the chemicals from the Tox21 library, hence several of the analogues were not included, due to lack of or limited HTS data (2,4-BPS, BPPH, BPS-MAE, BPP, DD-70, BPS-MPE, D8, BPAP, BTUM, MBHA, Pergafast 201, and BDP) or lack of both HTS and structure information (D-90, UU). Chemicals shown at the upper right of the graph have the highest degree of combined similarity to BPA or E_2_ (Figure 6). In the case of E_2_, the BPA analogues tend to cluster in the middle to lower left of the graph, albeit still showing some distinction from the overall set of Tox21 compounds. BPAP is not shown on the E_2_ plots because its biological correlation with E_2_ was less than 0.25. With BPA, the chemicals in the upper right of the graph include BPB, BPE, BPF, BPAF, and BPC. An overall assessment of the analysis suggests most of the BPA analogues exhibit a relatively high degree of combined similarity to BPA as they are all shifted to the upper right relative compared to the average chemical in the Tox21 library, suggesting that most of the BPA analogues are likely to share biological effects with BPA. This finding is less robust with E_2_, although the association with E_2_ is still significant (Supplemental Table 14, posted online), therefore suggesting a marginal degree of similarity may exist between E_2_ and the BPA analogues.

Figure 6

Integrated Structural and Biological Similarity of the BPA Analogues to E_2_ and BPA

Integrated structural and biological similarity of the BPA analogues to BPA or E_2_. Pearson correlation coefficients to BPA or E_2_ of chemicals represented by multiple samples in the chemical library were averaged to acquire a single correlation value per CASRN identifier pair. BPA analogues that were not included in the Tox21 library could not be included in the graph because biological similarity could not be determined. Dark circles are BPA analogues, squares are BPA analogues in the Tox21 library that are not considered elsewhere in this review (TBBPA, TCBPA PHBB), triangles are reference chemicals, and small circles are 6,053 non-BPA analogues from the Tox21 collection. BPPH, BPAP and BPS-MPE were included in the Tox21 library, however they were only screened in a limited number of assays and are therefore not included in the analysis.