# Methods

## Systematic Review Methods

Methods for the systematic review are briefly summarized below and are available in more detail in the evaluation protocol.^39^ Systematic review processes were conducted in accordance with the Preferred Reporting Items for Systematic Reviews and Meta-Analyses (PRISMA) Statement criteria^40^ and following the OHAT framework for conducting a systematic review.^41^

## Formulate the Study Question

A literature search strategy was initially developed for 27 BPA structural and/or functional analogues and refined during problem formulation (described in the evaluation protocol) to focus on the 24 BPA analogues listed in Table 1 (with additional details provided in Supplemental Table 1, posted online. In brief, analogues were prioritized for inclusion in the systematic review based on (1) detection in the environment (e.g., dust, water, sewage), foodstuff, or human biological samples; (2) identification by the US EPA Design for the Environment (DfE) program as being a potential alternative to BPA in thermal paper (henceforth referred to as the “US EPA DfE report”)^15^; (3) use as a halogenated flame retardant; and (4) considered of emerging interest, i.e. relatively data-poor and not the focus of many previous or on-going hazard or risk evaluations.

To address our overall objective we developed a PECO (Populations, Exposures, Comparators, Outcomes) statement (Table 2) to aid in developing an answerable question, the search terms, and the inclusion/exclusion criteria for our systematic review.^42,43^ The overall objective and PECO statement were based on a series of problem formulation steps that included assembling an NIEHS/NTP evaluation design team with expertise in BPA and BPA alternatives, toxicology, epidemiology, systematic review, information science, and analysis of high throughput screening data; and consultation with scientists at state governments and other Federal agencies. More details about problem formulation activities can be found in the evaluation protocol.^39^

Table 2 PECO (Populations, Exposures, Comparators Outcomes) Statement

PECO Element | Evidence
Populations | Human, animal (whole organism), or ex vivo/in vitro models utilizing organs, tissues, cell lines, or cellular components (e.g., cell-free receptor binding assays).
Exposures | Exposure to at least one of the 24 BPA analogues listed in Table 1.
Comparators | Humans, animals, organs, tissues, cell lines, or cellular components exposed to a lower level of a BPA analogue than the more highly exposed subjects or treatment groups, or vehicle-only treatment.
Outcomes | Any health outcome or type of biological response.

## Search For and Select Studies for Inclusion

### Literature Search Strategy

Prior to the literature search, the SciFinder database was searched using each chemical’s chemical abstracts service registration number (CASRN) to retrieve synonym names as well as old or additional CASRNs. Six databases were initially searched on March 28, 2014: Embase, PubMed, SciFinder, Scopus, Toxline and Web of Science. The search strategy was customized for each database because of differences in syntax. In addition, a broader search of the literature using the phrase “bisphenol A (analogue or analog)” was done, in order to retrieve studies that had not specified analogues in the title or abstract. The search was not limited by language or publication date. A literature search update was performed on March 23, 2015. The search update did not include searches for PHBB, TBBPA, or TCBPA because these compounds were not prioritized after problem formulation as they have been the focus of prior literature-based evaluations. The specific language used for each database and numbers of studies retrieved are available in the evaluation protocol.

### Searching Other Resources

Additional relevant publications were searched for by reviewing studies from the database search that did not contain original data (e.g., reviews), the US EPA DfE report,^15^ an NTP background document on BPA alternatives,^34^ and the European Chemicals Agency (ECHA) database that contains registration dossiers submitted for REACH chemicals (https://echa.europa.eu/information-on-chemicals/registered-substances). Though the ECHA database was searched, relevant data could not always be analyzed to the same degree as other included studies because the information is not peer reviewed and the database often only contains summaries of study findings. For example, the study’s No Observed Effect Level (NOEL) may be listed, but the study summary does not present underlying data such as mean or standard deviation. When available, relevant findings from studies in ECHA are presented separately from those available in the published literature. Additionally, the numbers of studies available in ECHA for each chemical and study type are listed in the results tables in order to indicate the availability of the data.

## Study Selection Criteria

Studies were screened for inclusion using a structured form in DistillerSR (Evidence Partners; https://www.evidencepartners.com/). In order to be eligible for inclusion, studies needed to comply with the criteria specified by the PECO statement (Table 2). Studies that did not meet the PECO criteria were excluded. In addition, the following exclusion criteria were applied: studies that did not contain original data, such as reviews, editorials, or commentaries, or that were conference abstracts.

Two members of the evaluation design team (K.E.P. and K.A.T. or P.R.) independently conducted title and abstract screening of the search results to determine whether a reference met the inclusion criteria; studies not excluded based on the title and abstract were screened through a full-text review. Full-text copies of potentially relevant studies were reviewed by one author (K.P.) and exclusions confirmed by a second author (K.A.T. or P.R.). Discrepant screening results were resolved by discussion. Native-language speakers at NIH facilitated the assessment of eligibility status of non-English studies.

Although beyond the scope of the current review, we also tracked studies reporting information on human exposure (detection in human blood, urine, or tissues) (Supplemental Table 2, posted online); wildlife (Supplemental Table 3, posted online); absorption, distribution, metabolism, and excretion (ADME) (Supplemental Table 4, posted online); and studies assessing the health effects of PHBB, TCBA, and TBBPA, which were not included past problem formulation as they have been the focus of prior literature-based evaluations (Supplemental Table 5, Supplemental Table 6, and Supplemental Table 7, respectively, posted online).

### Extract Data from Studies

Data were extracted from studies that met the inclusion criteria using DRAGON software.^44,45^ For each study, data extraction was done by one of the contract staff and reviewed for completeness and accuracy by a senior contractor (J.W.) and by K.E.P. The following data were collected for each study: authors, journal, reference information, year of publication, chemical, purity, dose or concentration tested, species/strain, cell line/tissue type, assay, endpoint, and AC_50_ (when reported). Dose and concentration level specific effects were summarized based on statistical significance as reported in the research studies. For in vivo studies, measures of effect at each dose or concentration level were extracted (e.g., mean, median, and measures of precision or variance). Findings from in vivo studies for continuous endpoints were converted to percent of control response using numbers presented in tabular form or by use of the WebPlot Digitizer^46^ from graphical depictions of data. For in vitro studies, the effects were summarized as increase, decrease, or no change from a vehicle control at each dose tested. One limitation is that in the in vitro studies authors often express results as a percentage of the positive or negative control response which may miss subtle induction or inhibition effects only apparent when looking at raw data. Disagreement was resolved by discussion between reviewers. Data extraction results are stored and visualized using Health Assessment Workspace Collaborative (HAWC)^47^ and are available for download in Excel format (https://hawcproject.org/assessment/46/).

### Assess Internal Validity (“Risk of Bias”) of Individual Human and Animal Studies

Internal validity, often referred to as “risk of bias” in systematic review, was assessed for individual human and animal studies using the OHAT risk of bias tool.^41,48^ In brief, risk of bias questions addressed randomization, allocation concealment, similarity of conditions across groups, blinding during the study, characterization of the treatment, adequacy of the outcome assessment, concerns for missing data, and other potential threats to internal validity such as failure to control for litter effects in developmental studies. Each risk of bias question was answered on a 4-point scale: “definitely low risk of bias,” “probably low risk of bias,” “probably high risk of bias,” and “definitely high risk of bias.” Risk of bias was independently assessed by one senior contract staff (R.B.), reviewed by another (P.R), with a final review conducted by K.E.P. Any discrepancies were resolved by consensus, arbitration by an additional member of the review team, or consultation with technical advisors as needed. Risk of bias was not assessed for in vitro studies because a tool analogous to that used for human and animal studies has not yet been finalized for the NTP method.

## Structural and Biological Similarity Analysis

### Structural Similarity Analysis

Chemical structures (SMILES strings) were retrieved from the US EPA annotation of the Tox21 10K library^49^ (Supplemental Table 1, posted online). Structures were not available for two BPA analogues that are polymers (D90 and UU). For chemicals that were not contained in the Tox21 library a SMILES string was identified in the EPA Chemical Dashboard (https://comptox.epa.gov/dashboard) by searching with CASRN. Smiles strings were loaded into the Leadscope Model Applier software (Version 3.1; Columbus, OH) and the presence or absence of a total of 8,026 structural features representing medicinal chemistry building blocks were annotated to the chemicals. Tanimoto coefficients (chemical structure similarity metric) for the structural features were then calculated for all pairs of chemicals. Pairs of chemicals with Tanimoto coefficients close to 1 are quite similar and those close to 0 have limited similarity.

### HTS Data

Analyses of HTS data from Tox21^50^ and ToxCast^51^ focused on evaluating structural and biological similarity among the BPA analogues and relative to BPA or E_2_. Fifteen BPA analogues (TGSA, BPC, 4,4-BPF, TBBPA, PHBB, BPS, TCBPA, 2,2-BPF, BPE, TMBPA, BPAF, BPZ, BPB, BPPH, BPS-MPE) were included in the Tox21 library, 4 (TGSA, TBBPA, BPAF, BPB) were included in the ToxCast Phase I/II libraries, and 6 were included in the ToxCast E1K library (PHBB, BPS, TCBPA, 2,2-BPF, BPB, BPAF) (Supplemental Table 1, posted online), which is an additional set of 800 compounds that are part of the Endocrine Disruption Screening Program (EDSP21) and that have only been tested in the endocrine-related subset of ToxCast assays.^52^ Although not included in the systematic review, the “data rich” chemicals TBBPA, TCBPA, and PHBB were included in the HTS similarity profiling.

### Biological Similarity Analysis Based on HTS Data

The biological similarity was assessed either in the scope of BPA analogues themselves (analysis #1), in the scope of pharmaceutical estrogens (analysis #2) or in the scope of the whole Tox21 library (analysis #3). In the first analysis, the activity values (AC_50_; concentration eliciting a half-maximal response) of chemicals in Tox21 assays were retrieved from https://ntp.niehs.nih.gov/sandbox/tox21-activity-browser/.^53^ Activities that were potentially confounded by interferences such as compound auto-fluorescence and compound cytotoxicity were flagged as inconclusive.^53^ The similarity of chemicals was viewed as a dendrogram based on the results of hierarchical clustering with average linkage using AC_50_ values (-log10(M), 1M is set for inactives or inconclusives). At the time of analysis, 24 assays targeting nuclear receptor signaling pathways and stress response pathways were used (Supplemental Table 8, posted online). Most Tox21 assays detect the target of transcriptional factor activity using reporter gene transcription technology (https://ncats.nih.gov/tox21/projects/nrassays). BPA and E_2_ were included for comparison. The ToxPI tool^54^ was used to compare the potency (AC_50_) between BPA analogues, BPA, and E_2_, relative to the most potent chemicals in the library (Supplemental Table 8, posted online

In the second analysis, the activity values (wAUC, weighted area under the curve)^53^ from 55 assays (cell viability assays included) including 441 outputs were used. The activity of the BPA analogues was first compared to that of a set of Tox21 chemicals similar to E_2_, then more broadly to the entire Tox21 chemical library. The E_2_ set was defined as all of the Tox21 chemicals with Tanimoto similarity to beta-estradiol of greater than 0.5 (see Appendix A. Supplemental Materials).

In a third analysis, similarity to BPA or E_2_ was determined for the BPA analogues in Tox21 in addition to all other chemicals run as part of Tox21. Log transformed +1 wAUC values from a total of 441 assay metrics across 55 assays were used to determine the Pearson correlation coefficient between E_2_ or BPA and chemicals in the Tox21 library. Assays for which there were no data for one or both of the chemicals were omitted from the calculation. A bootstrap resampling method was used to calculate the 95% confidence intervals. For each pair of chemicals, a bootstrap sample was generated by resampling with replacement from the pairs of wAUC values for those chemicals, and the correlation coefficient for these resampled values was generated. This procedure was performed 1,000 times. If the resampled data could not be used to compute a correlation coefficient (e.g., if all data points had wAUC values of 0 (i.e., inactive) for both assays), the value of the correlation coefficient was treated as 0. The 95% confidence limit was calculated as the range from the 2.5th to 97.5th percentiles of the bootstrapped values. P values for the correlation coefficients were also calculated. The p value of the observed correlation was calculated as the fraction of the bootstrapped correlation with absolute values greater than the observed correlation value, under the null hypothesis of no correlation. Chemicals with less than high quality (“A” rating for purity, defined as >90% and molecular weight identity confirmed) were removed from the analysis to avoid spurious results. For visualization purposes correlation values represent an average by CASRN when the chemical was present more than once in the library (i.e., the chemical had multiple Tox21 IDs).

### Integrated Chemical and Biological Similarity

Chemical structural similarity data from above was merged with biological similarity data from the biological similarity analysis #3 to yield a plot illustrating a trend of increasing biological similarity with chemical similarity for the BPA analogues in the context of the entire Tox21 library.