# Introduction

## Background

Bisphenol A (BPA) is a high production volume chemical used in the manufacture of polycarbonate plastics, epoxy resins, as a dye developer in thermal paper, and as a polymerization inhibitor in the formation of some polyvinyl chloride plastics.^1-3^ Polycarbonates are in consumer products such as plastic dinnerware, microwave ovenware, eyeglass lenses, toys, pacifiers, impact-resistant safety equipment, compact discs and automobile parts. Epoxy resins are used in protective linings of canned food and beverage containers, drinking water storage tanks, wine vat linings, some paints, floorings, and some dental composites.^1-3^ The types of thermal paper products where BPA might be used as a developer include cash register receipts and certain medical technical paper.^1,4^ Consequently, human exposure is widespread. BPA has been detected in the urine of 92% of participants surveyed in the United States National Health and Nutrition Examination Survey (NHANES) in 2003 to 2004.^5^ BPA has been reported to cause a wide range of adverse health outcomes in experimental animal studies; similar findings in humans have also been linked to BPA exposure in observational epidemiology studies.^2,3,6,7^

Recent studies report widespread exposure to a variety of chemicals with structural or functional similarity to BPA, often referred to as BPA analogues or derivatives (and henceforth referred to as BPA analogues) (Table 1). BPA analogues have been detected in foodstuffs,^9,18^ house dust,^10^ river and lake sediment,^11^ personal care products,^32^ and thermal paper.^12,14^ Importantly, BPA analogues have also been detected in human biological specimens.^8,16,17,26-28^ Several chlorinated and brominated derivatives of BPA are used as flame retardants.^1-3,33^ Other chemicals (e.g. MBHA) have also been identified as theoretical alternatives to BPA in thermal paper, although the extent to which they are actually being used is not known.^15^

Table 1 BPA Analogues Included in Systematic Review

Structure | Abbreviation (CASRN) | Detection | Structure | Abbreviation (CASRN) | Detection
| BPS (80-09-1) | blood,^8^ food,^9^ dust,^10^ sediment,^11^ receipts,^12-15^ urine^16,17^ | | 2,4-BPS (5397-34-2) | receipts ^15^
| 4,4-BPF (620-92-8) | food,^9,18,19^ dust,^10^ sediment,^11^ receipts,^15^ urine,^16,17^ PCP,^20^ municipal sewage sludge^21^ | | BPS-MAE (97042-18-7) | receipts ^15^
| BPAP (1571-75-1) | food,^9^ dust,^10^ sediment,^11^ receipts^15^ | | TGSA (41481-66-7) | receipts ^15^
| BPAF (1478-61-1) | food,^9^ dust,^10^ sediment,^11^ municipal sewage sludge^21^ | | BPS-MPE (63134-33-8) | receipts ^15^
| BPB (77-40-7) | food,^9,19,22-25^ dust,^10^ sediment,^11^ blood,^26,27^ urine^28^ | | BPC (79-97-0) | receipts ^15^
| BPP (2167-51-3) | food,^9^ dust^10^ | | BPPH (24038-68-4) | receipts ^15^
| BPZ (843-55-0) | food,^9,18^ sediment,^11^ PCP^20^ | | DD-70 (93589-69-6) | receipts ^15^
| D-8 (95235-30-6) | blood,^29^ receipts^29^ | | D-90 (191680-83-8) | receipts ^15^
| 2,2-BPF (2467-02-9) | resins^30^ | | BTUM (151882-81-4) | receipts ^15^
| BPE (2081-08-5) | municipal sewage sludge^21^ | | MBHA (5129-00-0) | receipts ^15^
| TMBPA (5613-46-7) | polycarbonate resin^31^ | | Pergafast 201 (232938-43-1) | receipts ^15^
| BDP (5945-33-5) | flame retardant | | UU (321860-75-7) | receipts ^15^

Italics indicate that this chemical has been suggested for use as described, but its use or detection has not been confirmed. Full chemical names can be found in Supplemental Table 1, posted online. Abbreviations: PCP (personal care products).

In contrast to BPA, most BPA analogues are poorly understood with respect to potential toxicity.^15,34^ Use of these compounds may increase as companies move towards using alternatives to BPA in consumer products.^35-37^ The health effects of two BPA analogues, bisphenol S and bisphenol F (BPS and BPF) have been recently reviewed using systematic review methodology,^38^ and the United States Environmental Protection Agency’s (US EPA) Design for the Environment program completed an alternative assessment in January 2014 in which the potential human health and environmental impacts of chemical alternatives to BPA in thermal paper were summarized.^15^ However, the literature for some analogues is growing rapidly.

## Objectives

The objective of this review is to answer the question: “What is the biological activity of BPA analogues of emerging public health concern?” Our specific aims were to

- identify all of the publicly available human, animal, and in vitro literature concerning health outcomes or biological responses of BPA analogues with the highest potential for human exposure (Table 1);
- extract data from the relevant studies;
- assess the risk of bias of individual animal and human studies;
- synthesize and summarize the existing evidence based on associated health outcome or biological response;
- evaluate the structural and biological similarity of the analogues to each other, to BPA, and to the potent estrogen estradiol (E_2_) within the National Toxicology Program’s (NTP) Tox21 and US EPA’s ToxCast high throughput screening (HTS) platforms; and
- identify data gaps and research needs that could aid in assessment or development of BPA alternatives.