# Acknowledgments

This research was supported by the National Institute of Environmental Health Sciences/Division of the National Toxicology Program.