# Appendix A Supplemental Materials

All supplemental tables listed below are available at https://doi.org/10.22427/NTP-DATA-4.

Supplemental Table 1. Inclusion of 27 BPA Analogues in Various Databases

Supplemental Table 2. Biomonitoring Studies

Supplemental Table 3. Wildlife Observational Studies

Supplemental Table 4. ADME Type Studies

Supplemental Table 5. PHBB Inventory

Supplemental Table 6. TCBPA Inventory

Supplemental Table 7. TBBPA Inventory

Supplemental Table 8. Tox21 Activity Data

Supplemental Table 9. Pharmacological Estradiol Analogues

Supplemental Table 10. Comparison of HTS Assays Between BPA Analogues and E_2_ Analogues

Supplemental Table 11. Hazard Summary Profile from the US EPA DfE Report

Supplemental Table 12. Summary of Reproductive and Developmental Toxicity Studies in ECHA

Supplemental Table 13. Integrated Biological and Structural Similarity to BPA

Supplemental Table 14. Integrated Biological and Structural Similarity to E_2_

Supplemental Table 15. References

## A.1 Comparison of Pharmaceutical Estrogen Profiles and BPA Analogues

The activity of the BPA analogues was compared to that of a set of Tox21 chemicals similar to E_2_. The E_2_ set was defined as all of the Tox21 chemicals with Tanimoto similarity to beta-estradiol of greater than 0.5. The chemicals in this set are given in Supplemental Table 9, posted online. The two chemical sets were compared using the direction adjusted, weighted area under curve (wAUC) values for the Tox21 assays. Assay values used were all triplicated assay endpoints, except for the two channels of data used for deriving the ratio in assays where the ratio of two channels was reported.

For each chemical and assay, the median of all replicate wAUC values for that chemical in that assay was obtained. Some chemicals were tested more than once (i.e., have more than one set of triplicate wAUCS), and those values were pooled before calculating the median. For each chemical set and each assay, the assay was assigned an activity sign of 1, indicating consistent increasing wAUC, if more than half of the chemicals (not counting chemicals not tested in that assay) had median wAUC greater than 0 for that assay, a sign of 1 if more than half had median wAUC less than 0, and a sign of 0 otherwise.

Results are shown in Supplemental Table 10, posted online . For sixteen of the assays, both the BPA analogues and the E_2_ analogues had the same non-zero sign (sign 1 for three assays, sign −1 for 13 assays), designated Group 1 Assays. (This discussion omits assays with sign 0 for both chemical sets). For 10 of the assays designated Group 2 Assays, the BPA analogues set had a sign of −1 while the E_2_ analogue set had a sign of 0. Five other assays designated Group 3 Assays had different signs for the two chemical sets.

## A.2 Hazard Summaries Based on Analogy and Estimation from the US EPA DfE Report

For eight analogues (BPS-MAE, BPS-MPE, BTUM, D-90, DD-70, MBHA, TGSA, UU), no published studies were identified by the literature search or in the US EPA DfE report.^15^ In the US EPA DfE report, hazard summaries of these chemicals were subsequently derived based on analogy, estimation, or evaluation of data in the ECHA database or submitted confidential studies (Supplemental Table 11, posted online. All of these analogues were found or estimated to have a low hazard for acute toxicity, and were estimated as a moderate hazard for carcinogenicity. MBHA achieved a high hazard label for developmental effects based on analogy to BPA and DD-70 achieved a high hazard label for eye irritation based on analogy to a confidential chemical. In contrast to the generally low hazard for human health effects of these analogues, most of them were found or estimated to be moderate, high, or very high hazards for acute or chronic exposure to aquatic organisms. The exceptions were UU and D-90, which were both estimated to be low aquatic toxicity hazards.

## A.3 Estrogenic and Anti-estrogenic Endpoints

Binding to the estrogen receptor was assessed for ten BPA analogues (4,4-BPF, BPAF, BPB, BPC, BPE, BPS, BPZ, BPAP, TMBPA, D-8) using a number of different assays (Figure A-6). In some assays, binding to the ER was performed in a cell-free context.^94,96,139,145-148^ In others, intact cell systems were utilized to evaluate binding to endogenous ER^149^ or exogenously expressed ER in mammalian cells^113,150^ or bacterial cells.^83,86,151,152^ Among the strongest binders to ER were BPAF, BPB, BPZ, and BPAP, binding between 0.01 and 1 µM, which was four to ten-fold more potent than that reported for BPA. Binding of BPC, 4,4-BPF, BPE, and TMBPA to ER was similar to that of BPA (ranged from >0.01 to <100 µM), and BPS was the weakest with binding six to 10-fold less potent than BPA (>3 µM). D-8 did not bind to ER in the presence or absence of the metabolic activator S9 fraction.^96^ Several BPA analogues bound ERβ more potently than ERα, including BPAF and BPS.^150,151^

Induction of cellular proliferation of human breast cancer cell lines (e.g., MCF7 and T47D) is a well-known characteristic of estrogenic chemicals, and was assessed for 11 BPA analogues (4,4-BPF, BPAF, BPAP, BPB, BPC, BPE, BPP, BPPH, BPS, BPZ, TMBPA). In MCF7 cells, the BPA analogues tested were similar to or slightly weaker than BPA in their ability to induce cellular proliferation (Figure A-7), with the exception of BPAF, which was generally reported as equal to or more potent than BPA.^94,113,139,148,153^ BPS was also interesting in that it was reported as weaker than BPA in inducing MCF7 cell proliferation,^94,145,150^ but was much more potent than BPA in inducing proliferation of the rat pituitary cancer cell line GH3/B6/F10.^154^ The pattern of potency was similar for ER binding and cellular proliferation for the chemicals that were tested in both assays with the exception of BPE, which was one of the most potent at inducing cellular proliferation^56^ but one of the weakest at binding ER.^94^

Modulation of reporter genes was assessed in eukaryotic cells transfected with various reporter constructs and with either ERα or ERβ in cells that do not endogenously express the receptor (Figure A-8). The yeast estrogen screen (YES), in which both the ER and reporter are transformed into yeast cells, was also used. With the exception of D8, all of the BPA analogues tested in these assays were partial to full agonists capable of eliciting induction of the reporter gene similarly to E_2_. The majority of the reported EC_50_ values were in the order of 0.1-10 µM for 4,4-BPF, BPB, BPC, BPE, BPP, and TMBPA. BPAF and BPZ were more potent, with EC_50_ values near 0.01-1 µM and BPAP and BPS were less potent with EC_50_ values in the order of 1-10 µM. The potency of the effect was dependent on cell type and receptor (ERα or ERβ). Antagonism was evaluated for 4,4-BPF, BPB, BPC, BPE, BPS, BPAF, and TMBPA. Only BPAF and TMBPA were found to antagonize the activity of E_2_, but the reports of BPAF antagonism were conflicting and suggest cell type specific effects.^104^ For example, potent antagonism of BPAF on ERβ and weak antagonism on ERα was observed in HeLa cells, but not in HepG2, Ishikawa, or MCF-7 cells.^104,113,155,156^

In Tox21, BPAF was the most potent ER agonist of the BPA analogues, and was more potent than BPA. BPZ, BPC, TMBPA, 4,4-BPF, BPB, BPE, BPS displayed ER agonism similar to BPA (AC_50_ between 0.2 and 2 µM). PHBB was weaker (AC_50_ ~20 µM). 2,2-BPF, TCBPA, TBBPA only stimulated the partial receptor at ~50 µM. ER antagonism at ~50 µM was observed for TGSA, TCBPA, BPZ, BPC, TMBPA, BPAF, BPE, and BPB.

Modulation of endogenous gene (Figure A-9) and protein (Figure A-10) expression was assessed in eukaryotic cells transfected with ERα or ERβ or in cells that endogenously express ER. For the most part, only single doses were evaluated in the gene expression studies. All of the tested BPA analogues (4,4-BPAF, BPAF, BPAP, BPB, BPC, BPE, BPS, BPZ, and TMBPA) induced the expression of endogenous estrogen-responsive genes (e.g., prolactin (PRL), growth regulation by estrogen in breast cancer 1 (GREB1), and progesterone receptor (PR)). Though difficult to discern due to the lack of dose response data, BPS appeared the least potent, only inducing gene expression at 300 µM^157^ whereas the other analogues induced expression at 1 or 10 µM (Figure A-9). In general, when ERβ was present there was no induction of endogenous estrogen-responsive genes.^158^ In the case of BPAF, however, gene expression was decreased relative to control when cells were transfected with ERβ and increased with ERα^159^. In addition, 4,4-BPAF, BPAF, BPAP, BPB, BPC, BPS, BPZ, and TMBPA were able to antagonize E_2_ induced expression of PRL in HeLA cells transfected with ERα or ERβ and GREB1 in MCF7 cells.^158^

The same chemicals were evaluated for modulation of ERα, PR, PRL, trefoil factor 1(pS2), or VTG protein expression (Figure A-10). All of the chemicals tested (4,4-BPF, BPAF, BPB, BPC, BPE) increased expression of PR and pS2 in the dose range of 1-10 µM.^148,160^ Whereas BPAF, BPP, BPC, and TMBPA antagonized E_2_ induced expression of VTG, only BPAF and BPC acted as agonists to induce VTG expression in the absence of E_2_.^161^ Stossi et al.^158^ reported that 4,4-BPF, BPAF, BPAP, BPB, BPC, BPS, and TMBPA could down regulate ERα levels in MCF7 cells.^158^

The production of endogenous estrogens (17β-E_2_ and estrone) was assessed for 4,4-BPF, BPB, BPE, BPS, D8 and Pergafast 201 in the human adrenocortical carcinoma cell line, H295R^97,162^ (Figure A-11). 4,4-BPF, BPB and BPE induced the production of 17β-E_2_ and estrone with potencies similar to BPA, whereas BPS was not active in the H295R steroidogenesis assay.^97,162^ For D8 and Pergafast 201, only the production of 17β-E_2_ was evaluated^97^ and both chemicals were inactive.

There were additional estrogen receptor related endpoints that were assessed (Figure A-12). Ashcroft et al.^163^ and Stossi et al.^158^ evaluated whether or not the BPA analogues could induce ER binding to the estrogen response element (ERE) of DNA using high content imaging. All of the BPA analogues tested (4,4-BPF, BPAF, BPAP, BPB, BPC, BPS, BPZ, TMBPA) demonstrated clear selectivity for ERβ compared to ERα^158^ with BPS and 4,4-BPF not able to induce ERα/ERE binding between 0.001 and 10 µM. In the same study, BPAP and BPAF were able to induce ERα or ERβ homodimerization but BPS showed only weak activity.^158^ In similar studies Ashcroft et al.^163^ demonstrated that BPB could induce ERα nuclear localization and polymerase II recruitment. Non-genomic effects were only explored for BPS, which was able to activate the extracellular signal-regulated kinase ERK and caspase 8 but not JNK or caspase 9.^154^

Figure A-1

Crossview of Subchronic Studies (https://hawcproject.org/summary/visual/176/)

Figure A-2

Body Weight in Subchronic Studies (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-2/)

Figure A-3

Crossview of Uterotrophic Response (https://hawcproject.org/summary/visual/168/)

Figure A-4

Data Pivot of Uterotrophic Response (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-4/)

Figure A-5

Vitellogenin Response (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-5/)

Figure A-6

Estrogen Receptor Binding Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-6/)

Figure A-7

Estrogen Receptor Cell Proliferation Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-7/)

Figure A-8

Estrogen Receptor Reporter Gene Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-8/)

Figure A-9

Estrogen Receptor Modulation of Endogenous Gene Expression (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-9/)

Figure A-10

Estrogen Receptor Modulation of Protein Expression (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-10/)

Figure A-11

Steroidogenesis Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-11/)

Figure A-12

Estrogen Receptor Other Endpoints (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-12/)

Figure A-13

Data Pivot of Hershberger Assay (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-13/)

Figure A-14

Androgen Receptor Agonism Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-14/)

Figure A-15

Androgen Receptor Antagonism Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-15/)

Figure A-16

Thyroid Hormone Disruption (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-16/)

Figure A-17

Thyroid Receptor Agonism Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-17/)

Figure A-18

Thyroid Receptor Antagonism Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-18/)

Figure A-19

Other Nuclear Receptor Activities (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-19/)

Figure A-20

In vitro Genotoxicity Assays (https://hawcproject.org/summary/data-pivot/assessment/46/Supplemental-Figure-20/)

Figure A-21

Assessment of Active and Inactive Assay of BPA Analogues in ToxCast

Figure A-22

Risk of Bias of Animal Evidence from Published Literature (https://hawcproject.org/summary/visual/142/)

Figure A-23

Risk of Bias of Animal Evidence from ECHA Data (https://hawcproject.org/summary/visual/144/)