# Executive Summary

The National Toxicology Program (NTP), National Institute of Environmental Health Sciences (NIEHS), Food and Drug Administration (FDA), and a group of NIEHS grant-supported researchers developed a consortium-based research program to link investigational studies with a modified guideline-compliant toxicology study using a rat model. Bisphenol A (BPA), a chemical with widespread low-level human exposure, was selected as the test chemical because of “the diverse and often difficult-to-interpret evidence” on its health effects (Schug et al. 2013). The resulting research program was called the Consortium Linking Academic and Regulatory Insights on Bisphenol A (BPA) Toxicity (CLARITY-BPA) (Schug et al. 2013). Sprague Dawley rats from the FDA’s National Center for Toxicological Research (NCTR) colony were housed, bred, and orally dosed with BPA in a 2-year perinatal dosing study (called the core study) that was performed at NCTR. Siblings of the rat offspring generated in the core study were provided to the grantees at 14 university laboratories for investigational studies that assessed other endpoints, many of which are not typically evaluated in guideline toxicological studies.

In brief, the core study assessed exposures to a wide range of BPA doses (2.5–25,000 μg/kg body weight [bw]/day) beginning in utero on gestation day (GD) 6 and continuing through postnatal day (PND) 21 (stop-dose arm) or for 2 years (continuous-dose arm). Similar continuous exposure to two levels of ethinyl estradiol (variously referred to as EE or EE2; administered at 0.05 and 0.5 μg/kg bw/day) served as a reference estrogen control, and continuous- or stop-dose exposures to the gavage vehicle served as negative controls. Dosing was done daily by oral gavage and included direct dosing of the pups from birth through weaning to ensure exposure during the perinatal period and to overcome the reported poor lactational transfer of BPA. Assessments in the core study included in-life body weight and clinical observations, estrous cyclicity, sperm parameters, organ weights, and clinical pathology at 1 year and complete necropsy and histopathology at 1 and 2 years. Assessments in the grantee studies focused on earlier timepoints than did the guideline core study and included functional, morphological, and molecular endpoints in the animals as early as PND 1 through age 1 year. The study design of the CLARITY-BPA program was structured to reduce many potential sources of bias. These study design features included such things as randomized allocation of animals to the study, use of a single pup per sex per litter for a given endpoint to control for litter effects, monitoring the purity of BPA and accuracy of dosing, quantification of the background dietary intake of BPA, and blinding of the treatment group of the biological samples, among others. To provide context, the BPA dose range included doses above and below the current United States Environmental Protection Agency reference dose of 50 µg/kg bw/day (U.S. EPA 1988).

This report presents a collation of the reported findings and the peer-reviewed conclusions from the CLARITY-BPA core guideline study (NTP 2018) and the peer-reviewed publications of the investigational research arm, which are listed in Table 1. The findings from the core study presented in the following chapters include all measurements found significant (p < 0.05) by the statistical tests applied, which in the case of histopathology data did not include adjustment for multiple comparisons. The report is organized into 10 chapters by organ or organ system, including brain and behavior, cardiac, immune, mammary gland, ovary, penile function, prostate gland and urethra, testis and epididymis, metabolism and thyroid hormone, and uterus. This report provides a succinct summary of the experimental procedures, findings, and authors’ interpretations reported in each of the peer-reviewed publications. The reader may refer to the raw data in the NTP’s Chemical Effects in Biological Systems (CEBS) database and study details in the original peer-reviewed publications for complete details. In addition, Camacho et al. (2019) presented a summary of the core study data but included a more expansive discussion of the FDA’s conclusions. An integrated analysis of findings from eight CLARITY-BPA grantee studies has also been published (Heindel et al. 2020); however, this paper is not summarized in this report.

Table 1 CLARITY-BPA Program Studies by Outcome Measured and Timing of Assessment

| PND 1 | PND 15 | PND 21 | PND 25–28 | PND 90 | PND 97–125 | 16 ± 2 wk or 20−22 wk | 6 mo | 1 yr | 2 yr
Brain and Behavior | Patisaul (Arambula et al. 2016; Arambula et al. 2018) | – | – | Patisaul (Arambula et al. 2017; Rebuli et al. 2015; Witchey et al. 2019) | – | Patisaul (Rebuli et al. 2015) and Rosenfeld (Cheong et al. 2018; Johnson et al. 2016) | – | – | Core (NTP 2018)^1^ | Core (NTP 2018)
Cardiac | – | – | Belcher (Gear et al. 2017) | – | Belcher (Gear et al. 2017) | – | – | Belcher (Gear et al. 2017)^2^ | Core (NTP 2018) | Core (NTP 2018)
Immune | – | – | Kaminski (Li et al. 2018a) | – | Kaminski (Li et al. 2018a; 2018b) | – | – | Kaminski (Li et al. 2018a; 2018b)^2^ | Kaminski (Li et al. 2018a; 2018b), Core (NTP 2018) | Core (NTP 2018)
Mammary Gland | – | – | Soto (Montévil et al. 2020) Soto (Unpublished) | – | Soto (Montévil et al. 2020) | – | – | Soto (Montévil et al. 2020)^2^ | Core (NTP 2018) | Core (NTP 2018)
Ovary | Flaws (Patel et al. 2017) | _ | Flaws (Patel et al. 2017) | – | Flaws (Patel et al. 2017) | – | Core (NTP 2018) | Flaws (Patel et al. 2017)^2^ | Flaws (Patel et al. 2017), Core (NTP 2018) | Core (NTP 2018)
Penile Function | – | – | – | – | – | – | – | Gonzalez-Cadavid (Unpublished) | – | –
Prostate Gland and Urethra | vom Saal (Uchtmann et al. 2020) | – | – | – | – | – | – | Prins (Prins et al. 2018)^2^ | Prins (Prins et al. 2018) Prins (Unpublished), vom Saal (Unpublished), Core (NTP 2018) | Core (NTP 2018)
Testis and Epididymis | – | – | – | – | Boekelheide (Dere et al. 2018) | – | – | – | Core (NTP 2018) | Core (NTP 2018)
Metabolism and Thyroid | – | Zoeller (Bansal and Zoeller 2019) | – | – | Ben-Jonathan (Unpublished) | – | – | Ben-Jonathan (Unpublished)^2^ | Greenberg (Unpublished), Core (NTP 2018) | Core (NTP 2018)
Uterus | – | – | Ho (Leung et al. 2020) | – | Ho (Leung et al. 2020) | – | – | Ho (Unpublished)^2^ | Ho (Leung et al. 2020), Core (NTP 2018) | Core (NTP 2018)

Unpublished raw data are available in the National Toxicology Program’s Chemical Effects in Biological Systems or by contacting the author.

mo = month; PND = postnatal day; wk = week; yr = year.

^1^ Camacho et al. (2019) presented a summary of the core study data but included a more expansive discussion of the FDA’s conclusions.

^2^ An integrated analysis of findings from eight grantee studies has also been published (Heindel et al. 2020). The manuscript included data from 6-month-old animals for cardiac, immune, mammary gland, metabolism, ovary, prostate, and uterus; this analysis is not summarized is the CLARITY-BPA Compendium Report.

Several grantee studies remain unpublished, and these studies are noted in Table 1. The designs of these studies are briefly described in the following chapters, but their findings are not included. All data from the core study and the majority of data from the grantee studies, including unpublished studies, are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://cebs.niehs.nih.gov/cebs/program/CLARITY-BPA . The data for the remaining two studies of brain and behavior that evaluated tissues from the CLARITY-BPA program, but were not funded by the program, are available upon request from Dr. Heather Patisaul (Arambula et al. 2018; Witchey et al. 2019).

## Summary of Authors’ Conclusions from CLARITY-BPA Peer-reviewed Publications to Date

The following section of the Executive Summary briefly states the conclusions of each author from their own publication(s) for each organ or organ system. The NCTR authors’ overall conclusions from the core study are provided because the authors did not present conclusions for each organ or organ system separately. Findings from the core study and each individual investigational study are provided in the body of this report in the respective organ or organ system chapter.

### Chapters 1 through 10, All Outcomes, Core Study

Given the peer-reviewed findings of the core study, the authors concluded that, “There were few significant effects of BPA treatment in the in-life data collected. […] For clinical pathology endpoints and organ weights, some statistically significant effects of continuous- or stop-dose BPA treatments were observed. These effects were of questionable relevance to BPA toxicity given that they were seen only in single-dose groups, in several cases differed from the vehicle control by less than 10%, and, in the case of organ weights, were not significant when adjusted for body weight” (NTP 2018). In the histopathological evaluations, “statistical differences between BPA treatment groups, particularly below 25,000 μg/kg bw/day, and the vehicle control group detected by the low-stringency statistical tests applied to histopathology lesions, were not dose responsive, sometimes occurring in only one low or intermediate dose group and did not demonstrate a clear pattern of consistent responses within or across organs within the stop- and continuous-dose arms and sacrifice times. In contrast, the high EE2 dose elicited several estrogenic effects in females in a clearly interpretable and biologically plausible manner. Several observations at 25,000 μg BPA/kg bw/day may be treatment related, including effects … in the female reproductive tract (ovary, uterus, and vagina) and in the male pituitary” (NTP 2018). The authors determined, “Based on a weight of evidence approach, we conclude that the core study data do not suggest a plausible hazard of BPA exposure in the lower end of the dose range tested” (Camacho et al. 2019).

### Chapter 1, Brain and Behavior, Grantee Studies

The Patisaul laboratory reported from its studies that exposure to BPA did not affect anxiety or exploratory behavior in juveniles or adults but did result in changes in the expression of genes (including estrogen receptors, androgen receptors, and other genes involved in sexual differentiation) and neuroendocrine function in the hypothalamus, hippocampus, and amygdala as early as PND 1. Structural changes in the hypothalamus and amygdala, as well as loss of sex differences in hypothalamic oxytocin receptor levels, were reported on PND 28. Changes were observed across the entire exposure range. The authors concluded that “these data demonstrate prenatal BPA exposure, even at doses below the current no-observed-adverse-effect level, can alter gene expression in the developing brain” (Arambula et al. 2016).

In its studies, the Rosenfeld laboratory also found a loss of sexual dimorphism in expression levels and promoter DNA methylation of selected genes in the hippocampus and hypothalamus and observed some evidence of disruption of spatial navigational learning and memory at the 2,500 μg BPA/kg bw/day exposure level in females. The authors concluded that “findings suggest BPA exposure induced non-EE-like gene expression and epigenetic changes in adult rat hippocampi, a region involved in spatial navigation” (Cheong et al. 2018).

### Chapter 2, Cardiac, Grantee Study

The Belcher laboratory reported from its studies that in BPA- or EE2-exposed females, “cardiomyopathy incidence and severity was significantly increased compared to control females at PND 21 with myocardial degeneration observed in both males and females at PND 21 and PND 90” (Gear et al. 2017).

### Chapter 3, Immune, Grantee Studies

The Kaminski laboratory evaluated leukocyte composition or function at PND 21, PND 90, 6 months, and 1 year of age. In total, of the 1,160 measurements in BPA-treated rats, 45 measurements were statistically different from vehicle controls. Changes were associated with the percentage of macrophage or dendritic cell populations in the spleen primarily in 6-month-old or 1-year-old males. In addition, changes in T cell activation in 6-month-old males and lymphoproliferative response in 1-year-old males were observed at doses from 2.5 to 25,000 μg BPA/kg bw/day. With the exception of the aforementioned changes, the authors noted that those associated with BPA treatment were mostly sporadic, moderate in magnitude, not dose-dependent, and showed no persistent trend over the 1-year time period examined. Given these findings, the authors concluded that the “BPA-mediated changes observed in the study are unlikely to alter immune competence in adult rats” (Li et al. 2018b).

### Chapter 4, Mammary Gland, Grantee Study

The Soto laboratory reported that, using both semiquantitative and newly developed quantitative methods of analyzing mammary gland development, BPA exposure showed nonmonotonic effects. The new quantitative methods and software were specifically designed to assess and quantify multiple endpoints (including 91 structural mammary gland endpoints) at PND 21, PND 90, and 6 months of age. Using permutation tests and additional statistical tools examining a variety of dose-response relationships, they reported that three-dimensional (3D) morphometric measurements of mammary gland whole mounts showed nonmonotonic effects of BPA with a breaking point between the 25 and 250 μg/kg bw/day doses. Most of the set of 91 endpoints showed the same breaking point, and the statistical analysis showed that this was not a random occurrence. Further, for many of the developmental and histoarchitectural endpoints examined, BPA and EE2 had different effects. The authors’ concluded that “At all time points, lower doses resulted in larger effects [than higher doses of BPA], consistent with the core study, which revealed a significant increase of mammary adenocarcinoma incidence in the stop-dose animals at the lowest BPA dose tested” (Montévil et al. 2020).

### Chapter 5, Ovary, Grantee Study

The Flaws laboratory concluded from its studies that exposure to lower doses of BPA (2.5 and 250 μg/kg bw/day) decreased the numbers of primordial, primary, preantral, and total healthy follicles at PND 21. At the highest doses tested, BPA exposures reduced circulating estradiol levels in continuous-dose females at 1 year. The authors concluded that “BPA exposures at some doses and time points affect ovarian follicle numbers and sex steroid levels in the rat, but these effects are different than those observed with ethinyl estradiol exposure and some previous studies on BPA” (Patel et al. 2017).

### Chapter 6, Penile Function, Grantee Study

Findings from the Gonzalez-Cadavid laboratory have not been published in a peer-reviewed publication. The study data are available in the CEBS database ([underlined: https://cebs.niehs.nih.gov/cebs/program/CLARITY-BPA]).

### Chapter 7, Prostate Gland and Urethra, Grantee Studies

The Prins laboratory reported that “…although developmental and chronic BPA exposures are not carcinogenic to the prostate, they enhance carcinogenic susceptibility [of the lateral prostate and dorsolateral prostatic ducts] to later-life estrogen exposures, with the greatest effects observed at the lowest BPA dose examined” (Prins et al. 2018). Furthermore, chronic low-dose BPA exposures altered adult dorsolateral prostate stem cell homeostasis with increases in stem cell numbers (2.5 μg BPA/kg bw/day) and progenitor cell proliferation (25 and 250 μg BPA/kg bw/day) and a shift in lineage commitment toward basal progenitor cells (25 and 250 μg BPA/kg bw/day), “which may underpin the increased carcinogenic risk with aging” (Prins et al. 2018).

The vom Saal and Ricke laboratories reported that their morphometric analysis of 3D reconstructions of the rat urogenital sinus (UGS; prostate and urethra) on PND 1 “revealed several significant or trending changes […], including changes in colliculus angle and an increase in colliculus size, a decrease in urethral lumen length and width due to low, but not high doses of BPA, similar to EE2. These changes all indicate that the urethra is smaller, associated with changes in colliculus shape, when exposed to low doses of BPA and EE2” (Uchtmann et al. 2020). The authors concluded that “…these data suggest that BPA at lower doses (physiologically relevant [2.5, 25, and 250 μg/kg bw/day]), but not the highest dose, mediates its effects on the fetal UGS via estrogenic pathways” and “…provide further evidence that BPA mediates nonmonotonic developmental effects on the fetal urogenital sinus” (Uchtmann et al. 2020).

### Chapter 8, Testis and Epididymis, Grantee Study

The Boekelheide laboratory reported in its studies that perinatal exposure to 250,000 μg BPA/kg bw/day lowered testis and epididymal weights, but that “prolonged exposure starting in utero to BPA over a wide range of levels [2.5–25,000 μg BPA/kg bw/day] has little, if any, impact on the testes and sperm molecular profiles of 90 day old rats as assessed by the histopathologic, morphometric, and molecular endpoints evaluated” (Dere et al. 2018).

### Chapter 9, Metabolism and Thyroid, Grantee Studies

Findings from the Ben-Jonathan and Greenberg laboratories have not been published in a peer-reviewed publication. The study data are available in the CEBS database ([underlined: https://cebs.niehs.nih.gov/cebs/program/CLARITY-BPA]).

The Zoeller laboratory reported in its studies that “neither BPA nor EE affected serum thyroid hormones or thyroid hormone‒sensitive end points in the developing brain at PND 15. In contrast, propylthiouracil (PTU) reduced serum T4 to the expected degree (80% reduction) and elevated serum TSH [thyroid stimulating hormone]. Few effects of PTU were observed in the male brain and none in the female brain. As a result, it is difficult to interpret the negative effects of BPA on the thyroid in this rat strain because the thyroid system appears to respond differently from that of other rat strains” (Bansal and Zoeller 2019).

### Chapter 10, Uterus, Grantee Study

The Ho laboratory reported minimal, non-statistically significant effects when effects of BPA exposures were evaluated on individual uterine endpoints in isolation. When the combined effects of all testing outcomes were analyzed in a semi-blind fashion using statistical models, however, the authors concluded that “life-long exposure to low doses of BPA (25 or 250 μg/kg/day), but not higher doses, altered the estrous cycle and uterine pathology.” Furthermore, over 400 genes were differentially expressed in each BPA-exposed group relative to control, and expression patterns of genes from the 25 and 250 μg/kg bw/day dose groups were most closely related to each other. The 25 and 250 μg/kg bw/day dose groups also had greater gene expression similarity to the high-dose EE2 group than to the other BPA groups or the low-dose EE2 group, which were all more likely to be similar to the control group. A subset of BPA-responsive genes from the 25 and 250 μg BPA/kg bw/day dose groups was also linked to estrogen responsiveness and “exhibited a non-monotonic dose-response pattern” (Leung et al. 2020).