# Publication Details

Publisher: CLARITY-BPA Research Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: https://doi.org/10.22427/NTP-RR-18

Report Series: NTP Research Report Series

Report Series Number: 18

Official citation: CLARITY-BPA Research Program. 2021. NTP research report on the consortium linking academic and regulatory insights on bisphenol A toxicity (CLARITY-BPA): a compendium of published findings. Research Triangle Park, NC: National Toxicology Program. Research Report 18.