# Peer Review

The draft NTP Research Report on the Consortium Linking Academic and Regulatory Insights on Bisphenol A Toxicity (CLARITY-BPA): A Compendium of Published Findings (formerly titled the Draft NTP Research Report # 23: CLARITY-BPA Final Report) was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the report fully and clearly presents a summary of the methods, reported findings, and conclusions of the publications of the CLARITY-BPA study.

## Peer Reviewers

- Anna Castoldi, Ph.D.
  Senior Scientific Officer
  European Food Safety Authority (EFSA)
  Food Ingredients and Packaging (FIP) Unit
  Parma, Italy
- Marissa Sobolewski (Terry), Ph.D.
  Assistant Professor
  University of Rochester School of Medicine and Dentistry
  University of Rochester Medical Center, Department of Environmental Medicine
  Rochester, NY, USA