# Collaborators

- National Institute of Environmental Health Sciences (NIEHS), Research Triangle Park, North Carolina, USA
  Designed core study, designed and drafted final report
  Retha R. Newbold, M.S. (Retired, and Kelly Government Services)
  John R. Bucher, Ph.D. (Retired)
- Designed core study, evaluated and reported core study findings, reviewed final report
  Nigel J. Walker, Ph.D.
- Designed and drafted final report
  Brandiese E.J. Beverly, Ph.D.
  Kembra L. Howdeshell, Ph.D.
  Andrew A. Rooney, Ph.D.
- U.S. Food and Drug Administration, National Center for Toxicological Research, Jefferson, Arkansas, USA
  Designed and conducted core study, evaluated and reported findings, reviewed final report
  Luísa Camacho, Ph.D.
  K. Barry Delclos, Ph.D.
- Brown University, Providence, Rhode Island, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Kim Boekelheide, M.D., Ph.D.
- Michigan State University, East Lansing, Michigan, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Norbert E. Kaminski, Ph.D.
- North Carolina State University, Raleigh, North Carolina, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Heather B. Patisaul, Ph.D.
- Conducted investigational study, evaluated and reported findings, reviewed final report
  Scott M. Belcher, Ph.D.
- Tufts University, Medford, Massachusetts, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Ana M. Soto, M.D.
- University of Arkansas, Little Rock, Arkansas USA (formerly at the University of Cincinnati, Cincinnati, Ohio, USA)
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Shuk-Mei Ho, Ph.D.
- University of Illinois at Chicago, Chicago, Illinois, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Gail S. Prins, Ph.D.
- University of Illinois at Urbana-Champaign, Urbana, Illinois, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Jodi A. Flaws, Ph.D.
- University of Massachusetts Amherst, Amherst, Massachusetts, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  R. Thomas Zoeller, Ph.D.
- University of Missouri, Columbia, Missouri, USA
  Designed core study, conducted investigational study, evaluated and reported findings, reviewed final report
  Cheryl S. Rosenfeld, D.V.M., Ph.D.
  Frederick S. vom Saal, Ph.D.
- ICF, Fairfax, Virginia, USA
  Provided ICF project management and conducted critical review of final report
  Alexandra E. Goldstone, M.P.H.
- Designed tables, performed quality control reviews, formatted and conducted critical review of final report
  Pamela A. Hartman, M.E.M.
- Extracted data and performed quality control reviews of final report
  Sophie A. Hearn, B.S.
- Designed tables and extracted data for final report
  Courtney R. Lemeris, B.A.