# References

Arambula SE, Belcher SM, Planchart A, Turner SD, Patisaul HB. 2016. Impact of low dose oral exposure to bisphenol A (BPA) on the neonatal rat hypothalamic and hippocampal transcriptome: A CLARITY-BPA consortium study. Endocrinology. 157(10):3856–3872. 10.1210/en.2016-1339 27571134
Arambula SE, Fuchs J, Cao J, Patisaul HB. 2017. Effects of perinatal bisphenol A exposure on the volume of sexually-dimorphic nuclei of juvenile rats: A CLARITY-BPA consortium study. Neurotoxicology. 63:33–42. 10.1016/j.neuro.2017.09.002 28890130
Arambula SE, Jima D, Patisaul HB. 2018. Prenatal bisphenol A (BPA) exposure alters the transcriptome of the neonate rat amygdala in a sex-specific manner: A CLARITY-BPA consortium study. Neurotoxicology. 65:207–220. 10.1016/j.neuro.2017.10.005 29097150
Bansal R, Zoeller RT. 2019. CLARITY-BPA: Bisphenol A or propylthiouracil on thyroid function and effects in the developing male and female rat brain. Endocrinology. 160(8):1771–1785. 10.1210/en.2019-00121 31135896
Beausoleil C, Emond C, Cravedi J-P, Antignac J-P, Applanat M, Appenzeller BR, Beaudouin R, Belzunces LP, Canivenc-Lavier M-C, Chevalier N. 2018. Regulatory identification of BPA as an endocrine disruptor: Context and methodology. Mol Cell Endocrinol. 475:4–9. 10.1016/j.mce.2018.02.001 29426018
Bosland MC, Ford H, Horton L. 1995. Induction at high incidence of ductal prostate adenocarcinomas in NBL/Cr and Sprague-Dawley Hsd:SD rats treated with a combination of testosterone and estradiol-17 beta or diethylstilbestrol. Carcinogenesis. 16(6):1311–1317. 10.1093/carcin/16.6.1311 7788848
Camacho L, Lewis SM, Vanlandingham MM, Olson GR, Davis KJ, Patton RE, Twaddle NC, Doerge DR, Churchwell MI, Bryant MS, et al. 2019. A two-year toxicology study of bisphenol A (BPA) in Sprague-Dawley rats: CLARITY-BPA core study results. Food Chem Toxicol. 132:110728. 10.1016/j.fct.2019.110728 31365888
Cheong A, Johnson SA, Howald EC, Ellersieck MR, Camacho L, Lewis SM, Vanlandingham MM, Ying J, Ho SM, Rosenfeld CS. 2018. Gene expression and DNA methylation changes in the hypothalamus and hippocampus of adult rats developmentally exposed to bisphenol A or ethinyl estradiol: A CLARITY-BPA consortium study. Epigenetics. 13(7):704–720. 10.1080/15592294.2018.1497388 30001178
Churchwell MI, Camacho L, Vanlandingham MM, Twaddle NC, Sepehr E, Delclos KB, Fisher JW, Doerge DR. 2014. Comparison of life-stage-dependent internal dosimetry for bisphenol A, ethinyl estradiol, a reference estrogen, and endogenous estradiol to test an estrogenic mode of action in Sprague Dawley rats. Toxicol Sci. 139(1):4–20. 10.1093/toxsci/kfu021 24496641
Davis B, Fenton S. 2013. Chapter 61, Mammary gland. In: Haschek W, Rousseaux C, Wallig M, editors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. 3rd ed. Academic Press; p. 2665–2694. 10.1016/B978-0-12-415759-0.00061-3
Delclos KB, Camacho L, Lewis SM, Vanlandingham MM, Latendresse JR, Olson GR, Davis KJ, Patton RE, Gamboa da Costa G, Woodling KA, et al. 2014. Toxicity evaluation of bisphenol A administered by gavage to Sprague Dawley rats from gestation day 6 through postnatal day 90. Toxicol Sci. 139(1):174–197. 10.1093/toxsci/kfu022 24496637
Delfosse V, Grimaldi M, le Maire A, Bourguet W, Balaguer P. 2014. Nuclear receptor profiling of bisphenol-A and its halogenated analogues. Vitam Horm. 94:229–251. 10.1016/B978-0-12-800095-3.00009-2 24388193
Dere E, Anderson LM, Huse SM, Spade DJ, McDonnell-Clark E, Madnick SJ, Hall SJ, Camacho L, Lewis SM, Vanlandingham MM, et al. 2018. Effects of continuous bisphenol A exposure from early gestation on 90-day old rat testes function and sperm molecular profiles: A CLARITY-BPA consortium study. Toxicol Appl Pharmacol. 347:1–9. 10.1016/j.taap.2018.03.021 29596923
ECHA.2017a. Member state committee support document for identification of 4,4'-isopropylidenediphenol (Bisphenol A, BPA) as a substance of very high concern because of its endocrine disrupting properties (Article 57(F)) causing probable serious effects to the environment which give rise to an equivalent level of concern to those of CMR1 AND PBT/vPvB2 properties. European Chemicals Agency (ECHA). Available at: https://echa.europa.eu/documents/10162/13638/svhc_msc_support_document_bisphenol_a_en.pdf. [Accessed 18 February 2021]
ECHA.2017b. Member state committee support document for identification of 4,4'-isopropylidenediphenol (Bisphenol A, BPA) as a substance of very high concern because of its endocrine disrupting properties which cause probable serious effects to human health which give rise to an equivalent level of concern to those of CMR1 AND PBT/VPVB2 SUBSTANCES. European Chemicals Agency (ECHA). Available at: https://echa.europa.eu/documents/10162/908badc9-e65d-3bae-933a-3512a9262e59 [Accessed 19 February 2021]
ECHA.2017c. Substance evaluation conclusion as required by REACH Article 48 and evaluation report for 4,4'-Isopropylidenediphenol (EC No 201-245-8, CAS No 80-05-7). European Chemicals Agency (ECHA). Available at: https://echa.europa.eu/documents/10162/2e8ac666-fae6-2e54-f0eb-ef4a5da819ed. [Accessed 18 February 2021]
EFSA.2015. Scientific Opinion on the risks to public health related to the presence of bisphenol A (BPA) in foodstuffs. European Food Safety Authority (EFSA) Panel on Food Contact Materials, Enzymes, Flavourings Processing Aids (CEF). 1831-4732. https://efsa.onlinelibrary.wiley.com/doi/abs/10.2903/j.efsa.2015.3978.
Gear R, Kendziorski JA, Belcher SM. 2017. Effects of bisphenol A on incidence and severity of cardiac lesions in the NCTR-Sprague-Dawley rat: A CLARITY-BPA study. Toxicol Lett. 275:123–135. 10.1016/j.toxlet.2017.05.011 28499613
Glenister TW. 1962. The development of the utricle and of the so-called ‘middle’ or ‘median’ lobe of the human prostate. J Anat. 96(Pt 4):443–455. 13948442
Heindel JJ, Belcher S, Flaws JA, Prins GS, Ho S-M, Mao J, Patisaul HB, Ricke W, Rosenfeld CS, Soto AM, et al.2020. Data integration, analysis, and interpretation of eight academic CLARITY-BPA studies. Reprod Toxicol. 10.1016/j.reprotox.2020.05.014
Heindel JJ, Newbold RR, Bucher JR, Camacho L, Delclos KB, Lewis SM, Vanlandingham M, Churchwell MI, Twaddle NC, McLellen M, et al. 2015. NIEHS/FDA CLARITY-BPA research program update. Reprod Toxicol. 58:33–44. 10.1016/j.reprotox.2015.07.075 26232693
Hunt PA, Koehler KE, Susiarjo M, Hodges CA, Ilagan A, Voigt RC, Thomas S, Thomas BF, Hassold TJ. 2003. Bisphenol a exposure causes meiotic aneuploidy in the female mouse. Curr Biol. 13(7):546–553. 10.1016/S0960-9822(03)00189-1 12676084
Johnson SA, Javurek AB, Painter MS, Ellersieck MR, Welsh TH.Jr., Camacho L, Lewis SM, Vanlandingham MM, Ferguson SA, Rosenfeld CS. 2016. Effects of developmental exposure to bisphenol A on spatial navigational learning and memory in rats: A CLARITY-BPA study. Horm Behav. 80:139-148. 10.1016/j.yhbeh.2015.09.005
Klenke U, Constantin S, Wray S. 2016. BPA directly decreases GnRH neuronal activity via noncanonical pathway. Endocrinology. 157(5):1980–1990. 10.1210/en.2015-1924 26934298
Leung Y-K, Biesiada J, Govindarajah V, Ying J, Kendler A, Medvedovic M, Ho S-M. 2020. Low-dose Bisphenol A in a rat model of endometrial cancer: A CLARITY-BPA study. Environ Health Perspect. 128(12):127005–127005. 10.1289/EHP6875 33296240
Li J, Bach A, Crawford RB, Phadnis-Moghe AS, Chen W, D’Ingillo S, Kovalova N, Suarez-Martinez JE, Zhou J, Kaplan BLF, et al. 2018 a. CLARITY-BPA: Effects of chronic Bisphenol A exposure on the immune system: Part 1 - Quantification of the relative number and proportion of leukocyte populations in the spleen and thymus. Toxicology. 396-397:46–53. 10.1016/j.tox.2018.01.004 29428349
Li J, Bach A, Crawford RB, Phadnis-Moghe AS, Chen W, D’Ingillo S, Kovalova N, Suarez-Martinez JE, Zhou J, Kaplan BLF, et al. 2018 b. CLARITY-BPA: Effects of chronic Bisphenol A exposure on the immune system: Part 2 - Characterization of lymphoproliferative and immune effector responses by splenic leukocytes. Toxicology. 396-397:54–67. 10.1016/j.tox.2018.02.004 29427786
MacKay H, Abizaid A. 2018. A plurality of molecular targets: The receptor ecosystem for Bisphenol-A (BPA). Horm Behav. 101:59–67. 10.1016/j.yhbeh.2017.11.001 29104009
McCormick DL, Rao KV, Dooley L, Steele VE, Lubet RA, Kelloff GJ, Bosland MC. 1998. Influence of N-methyl-N-nitrosourea, testosterone, and N-(4-hydroxyphenyl)-all-trans-retinamide on prostate cancer induction in Wistar-Unilever rats. Cancer Res. 58(15):3282–3288. 9699656
McLachlan JA, Newbold RR, Bullock B. 1975. Reproductive tract lesions in male mice exposed prenatally to diethylstilbestrol. Science. 190(4218):991–992. 10.1126/science.242076 242076
Montévil M, Acevedo N, Schaeberle CM, Bharadwaj M, Fenton SE, Soto AM. 2020. A combined morphometric and statistical approach to assess nonmonotonicity in the developing mammary gland of rats in the CLARITY-BPA study. Environ Health Perspect. 128(5):057001. 10.1289/EHP6301 32438830
NTP.2018. NTP research report on the CLARITY-BPA core study: A perinatal and chronic extended-dose-range study of bisphenol A in rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health. NTP RR 9.10.22427/NTP-RR-9.
Patel S, Brehm E, Gao L, Rattan S, Ziv-Gal A, Flaws JA. 2017. Bisphenol A exposure, ovarian follicle numbers, and female sex steroid hormone levels: Results from a CLARITY-BPA study. Endocrinology. 158(6):1727–1738. 10.1210/en.2016-1887 28324068
Prins GS, Hu WY, Xie L, Shi GB, Hu DP, Birch L, Bosland MC. 2018. Evaluation of Bisphenol A (BPA) exposures on prostate stem cell homeostasis and prostate cancer risk in the NCTR-Sprague-Dawley rat: An NIEHS/FDA CLARITY-BPA consortium study. Environ Health Perspect. 126(11):117001. 10.1289/EHP3953 30387366
Rebuli ME, Camacho L, Adonay ME, Reif DM, Aylor DL, Patisaul HB. 2015. Impact of low-dose oral exposure to bisphenol A (BPA) on juvenile and adult rat exploratory and anxiety behavior: A CLARITY-BPA consortium study. Toxicol Sci. 148(2):341–354. 10.1093/toxsci/kfv163 26209558
Rochester JR. 2013. Bisphenol A and human health: A review of the literature. Reprod Toxicol. 42:132–155. 10.1016/j.reprotox.2013.08.008 23994667
Schug TT, Heindel JJ, Camacho L, Delclos KB, Howard P, Johnson AF, Aungst J, Keefe D, Newbold R, Walker NJ, et al. 2013. A new approach to synergize academic and guideline-compliant research: The CLARITY-BPA research program. Reprod Toxicol. 40:35–40. 10.1016/j.reprotox.2013.05.010 23747832
Sheng Z, Wang C, Ren F, Liu Y, Zhu B. 2019. Molecular mechanism of endocrine-disruptive effects induced by Bisphenol A: The role of transmembrane G-protein estrogen receptor 1 and integrin alphavbeta3. J Environ Sci (China). 75:1–13. 10.1016/j.jes.2018.05.002 30473274
Simerly RB. 2002. Wired for reproduction: Organization and development of sexually dimorphic circuits in the mammalian forebrain. Annu Rev Neurosci. 25:507–536. 10.1146/annurev.neuro.25.112701.142745 12052919
Uchtmann KS, Taylor JA, Timms BG, Stahlhut RW, Ricke EA, Ellersieck MR, vom Saal FS, Ricke WA. 2020. Fetal bisphenol A and ethinylestradiol exposure alters male rat urogenital tract morphology at birth: Confirmation of prior low-dose findings in CLARITY-BPA. Reprod Toxicol. 91:131–141. 10.1016/j.reprotox.2019.11.007 31756437
U.S. EPA.1988. Integrated Risk Information System (IRIS) Toxicological Review of Bisphenol A; Chemical Assessment Summary of Bisphenol A; CASRN 80-05-7. Washington, DC: U.S. Environmental Protection Agency, National Center for Environmental Assessment. https://iris.epa.gov/static/pdfs/0356_summary.pdf. [1 September 2021]
U.S. FDA.2011. Updated review of the ‘low-dose’ literature (data) on bisphenol A (CAS RN 80-05-7) and response to charge questions regarding the risk assessment on bisphenol A. Bisphenol A (BPA) Joint Emerging Science Working Group. Washington, D.C.: U.S. Department of Health and Human Services. https://www.fda.gov/downloads/Food/IngredientsPackagingLabeling/FoodAdditivesIngredients/UCM424074.pdf. [8 April 2019]
U.S. FDA.2012. 2012 Updated review of literature and data on bisphenol A (CAS RN 80-05-7). Bisphenol A (BPA) Joint Emerging Science Working Group. Washington, D.C. https://www.fda.gov/downloads/Food/IngredientsPackagingLabeling/FoodAdditivesIngredients/UCM424073.pdf. [8 April 2019]
U.S. FDA.2014a. 2014 Updated review of literature and data on bisphenol A (CAS RN 80-05-7). Bisphenol A (BPA) Joint Emerging Science Working Group. Washington, D.C. https://www.fda.gov/downloads/Food/IngredientsPackagingLabeling/FoodAdditivesIngredients/UCM424071.pdf. [8 April 2019]
U.S. FDA.2014b. 2014 Final report for the review of literature and data on BPA. FDA Bisphenol A Joint Emerging Science Working Group. Washington, D.C. https://www.fda.gov/downloads/Food/IngredientsPackagingLabeling/FoodAdditivesIngredients/UCM424011.pdf. [8 April 2019]
Vandenberg LN. 2014. Non-monotonic dose responses in studies of endocrine disrupting chemicals: Bisphenol A as a case study. Dose Response. 12(2):259–276. 10.2203/dose-response.13-020.Vandenberg 24910584
vom Saal FS, Vandenberg LN.2020. Update on the health effects of bisphenol A: Overwhelming evidence of harm. Endocrinology. 10.1210/endocr/bqaa171
Wang L, Moenter SM. 2020. Differential Roles of Hypothalamic AVPV and Arcuate Kisspeptin Neurons in Estradiol Feedback Regulation of Female Reproduction. Neuroendocrinology. 110(3-4):172–184. 10.1159/000503006 31466075
WHO.2011. Toxicological and health aspects of bisphenol A. Report of joint FAO/WHO expert meeting 2-5 November 2010. World Health Organization. https://apps.who.int/iris/bitstream/handle/10665/44624/97892141564274_eng.pdf?sequence=1.
Witchey SK, Fuchs J, Patisaul HB. 2019. Perinatal bisphenol A (BPA) exposure alters brain oxytocin receptor (OTR) expression in a sex-and region-specific manner: A CLARITY-BPA consortium follow-up study. Neurotoxicology. 74:139–148. 10.1016/j.neuro.2019.06.007 31251963
Zoeller RT, Bansal R, Parris C. 2005. Bisphenol-A, an environmental contaminant that acts as a thyroid hormone receptor antagonist in vitro, increases serum thyroxine, and alters RC3/neurogranin expression in the developing rat brain. Endocrinology. 146(2):607–612. 10.1210/en.2004-1018 15498886