# Concluding Remarks

In summary, all data from the core study and the majority of data from the grantee studies, including unpublished studies, are available in the NTP CEBS database ([underlined: https://cebs.niehs.nih.gov/cebs/program/CLARITY-BPA]). In addition, readers can reference the peer-reviewed publications for more details on the methods, findings, and interpretation of the respective CLARITY-BPA authors. While the current report does not include an overall integration of the findings or integration of the conclusions of these CLARITY-BPA program publications, the data are presented for other researchers to consider this effort.