# Methods

The initial draft of the final report, including study summaries, was prepared at NIEHS by a team of investigators in the Office of Health Assessment and Translation, Division of NTP. To support the summaries of the Consortium Linking Academic and Regulatory Insights on Bisphenol A Toxicity (CLARITY-BPA) program, manual data extraction from the core study and investigational research studies was conducted, and extracted data were presented in tables by the contract staff for NIEHS. Data extraction was performed by one member of the evaluation team and checked by a second member for completeness and accuracy. If needed, discrepancies in data extraction were resolved by discussion or consultation with additional members of the evaluation team. Data extraction from studies was limited to information used to support the summaries in each chapter. In general, each chapter presents two tables—one table with endpoints measured and timing of assessment for included studies and a second table with endpoint-specific results for statistically significant data. For study data presented in figures, members of the evaluation team contacted authors of studies to obtain data from figures that were considered important for evaluating key study findings. Following completion (including quality assurance/quality control) of all tables for individual chapters, global consistency checks were performed to ensure an accurate and consistent presentation of study results across chapters. The draft organ-specific chapters were shared for comment and revisions with staff at the FDA National Center for Toxicological Research (NCTR) and the grantee responsible for each organ/system. Drafts of the Executive Summary were shared with all CLARITY-BPA participants for review and comment.

Detailed materials and methods for the core study and the investigational studies are contained in the specific study reports and publications cited in each chapter. Because the core study was the source of animals for all of the investigational studies, a brief abstract of the study methods is given here. Further experimental details can be found in NTP Research Report on the CLARITY-BPA Core Study: A Perinatal and Chronic Extended-Dose-Range Study of Bisphenol A in Rats (NTP 2018) and in Heindel et al. (2015).

Rats (Sprague Dawley/CD23/NctrBR [NCTR-SD]) were obtained as weanlings from the NCTR breeding colony and placed under study conditions (soy- and alfalfa-free diet 5K96 [Lab Diet, St. Louis, MO] in polysulfone cages with hardwood chip bedding, glass water bottles, and food-grade silicone stoppers). Study materials were monitored for background BPA levels; the only material with detectable levels of BPA was the diet, which had less than 3 ppb BPA.

BPA was purchased from TCI America (Portland, OR; product #B0494, lot #6052012) and verified by NTP contractors to be 99.9% pure. BPA, formulated in 0.3% carboxymethylcellulose (CMC), was administered by oral gavage to pregnant rats from gestation day (GD) 6 through the start of labor and then by oral gavage to the pups, at the same dose (μg/kg bw/day) given to the dams from postnatal day (PND) 1 (day of birth = PND 0) until termination. Treatment groups included 0 (CMC vehicle control), 2.5, 25, 250, 2,500, and 25,000 μg BPA/kg bw/day. CMC (sodium salt; product #C5013, lot #041M0105V) was obtained from Sigma-Aldrich (St. Louis, MO). The low dose selected, 2.5 μg BPA/kg bw/day, provided a margin of exposure at least 10-fold higher than the maximum allowed background dietary exposure in the animal feed, while the high dose of 25,000 μg BPA/kg bw/day was viewed as providing an adequate margin of human exposure, greater than 25,000-fold based on the aggregate human exposure estimates of <0.5 μg BPA/kg bw/day as mentioned above. Dose formulations were periodically certified to be within 10% of the target dose and were used within their established stability window. In addition to animals that were dosed daily throughout the study, the core study also included a stop-dose arm with animals dosed daily until PND 21 and then maintained without sham gavage or other further dosing until termination to assess any potential BPA effects that were due to early exposure only. Because many of the effects of BPA reported in the literature are associated with estrogen signaling pathways, two dose groups of the orally active estrogen ethinyl estradiol (EE2; administered at 0.05 and 0.5 μg/kg bw/day) were also included in the continuous-dose arm to assess the sensitivity of the test system to an estrogen. Females were singly housed during gestation and with their litters following delivery until PND 21.

At weaning on PND 21, one animal per sex per litter was assigned to each of the following study arms of the core study (Figure 1):

Figure 1

CLARITY-BPA Core Study Design

The core study began with five partial study loads from September through December 2012, with in-life study termination from October 2014 through January 2015.

1. Continuous dosing to sacrifice at 2 years (continuous-dose terminal sacrifice, 46–50 animals per sex per vehicle control or BPA treatment group and 26 animals per sex per EE2 group)
2. Continuous dosing to sacrifice at 1 year (continuous-dose interim sacrifice, 20–26 animals per sex for all groups)
3. No further treatment after PND 21 until sacrifice at 2 years (stop-dose terminal sacrifice, 46–50 animals per sex per preweaning vehicle control or BPA group)
4. No further treatment after PND 21 until sacrifice at 1 year (stop-dose interim sacrifice, 20–26 animals per sex for preweaning vehicle control and BPA groups)

The investigational studies used siblings from the core study animals, which were housed and dosed under the same conditions. Animals from the core study assigned to the investigational studies were sacrificed at PND 1, PND 15, PND 21, PND 90, 6 months, or 1 year of age. The number, sex, dosing arm (continuous or stop, after weaning), and sacrifice times, as well as other design elements (e.g., restrictions on litter size and sex ratios) used in each investigational study, were determined by the grantee and each request was matched to the extent possible by NCTR. In some cases, insufficient numbers of pups were produced to provide all the animals requested by the grantees. In these cases, some pups were reallocated from the core study to grantee studies to partially mitigate this shortfall. The sacrifices were conducted at NCTR, and tissues were isolated and sent to the respective grantee laboratories following the instructions provided a priori by each grantee to NCTR. An effort was made to collect tissues for as many investigational studies as possible from the same animals to minimize animal usage. For the behavior tests, grantees traveled to NCTR to conduct the tests, which followed pre-agreed protocols; tissues were then collected from these animals at NCTR for later evaluation at the grantees’ laboratories. The penile function tests were conducted at NCTR by a grantee who also collected tissues to further evaluate in his laboratory.

Two additional sets of animals were generated at the request of two of the grantees. For the thyroid focus area study, a subset of animals was dosed via drinking water with propylthiouracil to assess the responsiveness of the experimental system to alterations in thyroid hormone status. For testis function and sperm profiles, the investigational study by Dere et al. (2018) also included a 250,000 μg BPA/kg bw/day treatment, which was given by daily oral gavage to pregnant dams at NCTR from GD 6 through the start of labor and to pups from PND 1 until they were sacrificed at PND 90. Following the start of the CLARITY-BPA in-life phase of the study, analysis of serum samples collected for internal dosimetry assessments in a 90-day pre-chronic study performed at NCTR utilizing BPA doses as high as 300,000 μg/kg bw/day, indicated that serum from control rats was found to contain BPA glucuronide at levels comparable to those found in the 2.5 μg BPA/kg bw/day dose group, suggesting contamination from an unidentified source (Churchwell et al. 2014; Delclos et al. 2014). Although similar “contamination” was not exhaustively investigated in the CLARITY-BPA study (Heindel et al. 2015), it thus was assumed possible. For that reason, steps were taken to individually track and evaluate animals for the core and grantees’ studies that were housed in the same room as the animals receiving the 250,000 μg BPA/kg bw/day dose. When this occurred, statistical analyses that include or omit the animals co-housed with the 250,000 μg BPA/kg bw/day dose group are provided in the various chapters. The results of these sensitivity analyses that excluded the co-housed animals were only reported if they resulted in a change in an “adverse” direction for histopathology, that is, reduced incidences in the sensitivity analysis that were not significant in the inclusive tests were not reported.

With respect to analysis, there were several statistical approaches applied to the core study data, and these are outlined in the respective study chapters and in the core study report (NTP 2018). Statistical analyses of the histopathology data were conducted for any lesion that was diagnosed in two or more animals in any dose group in the interim sacrifice groups or four or more animals in the control and BPA groups at the terminal sacrifice. Lesion incidences in interim sacrifice animals were analyzed by the Cochran-Armitage trend test and Fisher’s exact (CAFE) tests to compare the trend across dose groups and the pairwise comparisons in each dose group to the vehicle control. Lesion incidences in terminal sacrifice animals were analyzed by the Poly-3 test, which adjusts for intercurrent mortality. Two secondary statistical tests were applied to incorporate severity scores in addition to lesion incidences—the Jonckheere-Terpstra trend test/Shirley-Williams pairwise comparison (JT/SW) test, which enforces an assumption of a monotonic response, and the relative treatment effect (RTE) test, which does not enforce monotonicity. Neither the JT/SW nor RTE test adjusts for survival.

In the core study, statistical outcomes were adjusted for multiple comparisons across dose groups for each endpoint with the exception of histopathology. For histopathology data, single-sided p values were used, and no adjustments were made for multiple comparisons. No corrections for the multiplicity of endpoints measured in the study were made in any case. This approach is standard for NTP chronic studies.

Additional statistical approaches were used by individual grantees, and these are also outlined in detail in their respective publications. All statistically significant findings reported in the publications are reflected in the tables and text in each outcome chapter.