# Introduction

## Background

Current methods for assessing the toxicity of chemicals are primarily based on two main sources of information: “investigational” research and guideline-compliant studies. Investigational research is typically conducted by investigators who are usually employed at a university and fund their research through federal or other sourced grants. Investigational research studies tend to be hypothesis-driven studies that are conducted on a relatively modest scale using a variety of experimental models to characterize a chemical's effect on a variety of biological or disease-related endpoints. In contrast, guideline-compliant studies are typically larger-scale efforts that follow established validated protocols for assessing toxicity and, often, to meet regulatory needs. Guideline studies are usually conducted in accordance with good laboratory practices (GLP), which are a set of internationally recognized quality assurance and quality control processes developed to standardize the conduct, record-keeping, and reporting of study results. Because of the extensive documentation requirements, guideline and GLP studies require a high level of quality control and management oversight and, thus, are generally conducted by accredited government or commercial laboratories.

Both investigational research and guideline-compliant studies make important contributions to the understanding of the potential health effects of chemicals, and both types of studies are taken into account at the regulatory level. As stated in Schug et al. (2013), “The strengths of academic research include a greater flexibility to respond to new scientific developments and experiment with new technologies, methods, or less-characterized endpoints. Hypothesis-driven academic research is also often driven to explore fundamental mechanisms of biological phenomena, not just assessment of potential toxicity or risk. On the other hand, guideline studies conducted in accordance with GLP benefit from validated methods and established protocols, transparent data recording and reporting systems, and a level of standardization, quality control, statistical power, and consistency that allows results to be compared more easily among studies.”

## Bisphenol A

Bisphenol A (BPA) is a chemical used to produce polycarbonate plastics and epoxy resins. It is used in the manufacture of many products, including plastic food and beverage containers, thermal receipt papers, the lining of some food cans, and other products. BPA can migrate into foods and beverages from food packaging and reusable containers. Because BPA is used in diverse consumer and commercial products, it is ubiquitous in the environment. As a result, detectable levels of BPA and/or its metabolites in human serum, saliva, urine, amniotic fluid, and breast milk have been reported. The estimated 95th–97th percentile of typical daily aggregate exposure to BPA is <0.6–1.5 μg/kg body weight (bw)/day for adult humans and 0.3–1.1 μg/kg bw/day for children and teenagers (WHO 2011).

BPA has been shown to bind to both nuclear and cell membrane estrogen receptors. At higher exposure levels, BPA is an androgen receptor antagonist and interacts with other nuclear receptors, including the glucocorticoid receptor, peroxisome proliferator-activated receptor gamma, and thyroid hormone receptor (Delfosse et al. 2014; MacKay and Abizaid 2018; Sheng et al. 2019). In addition, it has been reported that BPA at micromolar concentrations may also exert its action on GnRH neurons via the nuclear receptor transcription factor estrogen-related receptor gamma and other pathways, including voltage-gated sodium channels (Klenke et al. 2016). Although BPA can have hormone-like effects among other reported effects [e.g., Hunt et al. (2003)], whether BPA can exert adverse effects at human exposure levels remains a point of contention. Many studies of experimental animals and human research have reported an association of BPA exposure with a variety of health problems including infertility, weight gain, behavioral changes, early-onset puberty, prostate and mammary gland cancers, cardiovascular effects, and diabetes (Rochester 2013; Vandenberg 2014; vom Saal and Vandenberg 2020). BPA has been identified as a substance meeting the WHO/IPCS definition of an endocrine disruptor by the French Agency for Food, Environmental and Occupational Health and Safety (ANSES) (reviewed in Beausoleil et al. (2018). The European Chemicals Agency listed BPA in the Candidate List of Substances of Very High Concern (SVHC) due to its reproductive toxicity properties (ECHA 2017c) and identified BPA as a SVHC because of its endocrine disrupting properties causing probable serious effects to the environment and human health (ECHA 2017a; 2017b). In contrast, the European Panel on Food Contact Materials, Enzymes, Flavorings and Processing Aids assessed the risks to public health associated with BPA exposure and concluded there was no health concern for any age group from dietary exposure and low health concern from aggregated exposure (EFSA 2015). The U.S. Food and Drug Administration (FDA) released a series of comprehensive reviews of more than 300 scientific studies evaluating low doses of BPA (U.S. FDA 2011; 2012; 2014a; 2014b). In its 2014 review of the literature, the FDA concluded that, “Following our extensive review of ‘low-dose’ BPA literature, we are unable to construct a plausible or logical comprehensive toxicological profile or explanation for the many claimed effects of BPA, largely due to the inconsistencies that currently exist within this literature” (U.S. FDA 2014b).

## CLARITY-BPA Program

In 2010, the National Toxicology Program (NTP) and National Institute of Environmental Health Sciences (NIEHS) developed a new guideline-compliant study, conducted in accordance with GLP, to reconcile uncertainties in the scientific literature on the potential for toxicity of lower dose levels of BPA. Specifically, this chronic toxicity study would examine a wide dose range of BPA (including the lower dose range tested in many investigational research studies), use a long-term dosing protocol that encompassed developmental exposure, administer BPA via a human-relevant oral dose route, and assess additional endpoints not typically assessed in guideline-compliant studies. In addition to the periodic comprehensive reviews of BPA literature and safety assessment by the FDA, this research effort would offer an opportunity to test a new, collaborative research model based on enhancing the links between investigational and guideline-compliant research and possibly provide the risk assessment community a more comprehensive body of research to inform decision-making.

In response, NIEHS and FDA developed a consortium-based research program under the umbrella of NTP to link guideline-compliant research and investigational research. This initial proof-of-concept collaboration was called the Consortium Linking Academic and Regulatory Insights on BPA Toxicity (CLARITY-BPA), and it used BPA as a test chemical (Schug et al. 2013). The study design of the CLARITY-BPA program was structured to reduce many potential sources of bias. These study design features included such things as randomized allocation of animals to the study, use of a single pup per sex per litter for a given endpoint to control for litter effects, monitoring the purity of BPA and accuracy of dosing, quantification of the background dietary intake of BPA, and blinding of the treatment group of the biological samples, among others. The CLARITY-BPA program combined (1) a “core” study, a rat perinatal exposure guideline-compliant 2-year chronic toxicity study of BPA, with (2) an investigational research arm conducted by 14 university-based researchers funded for this purpose. The 14 grantees were selected by the NIEHS Division of Extramural Research and Training from responses to an open competitive request for application (RFA-ES-10-009) to collaborate with NIEHS and FDA in the overall study design and to conduct investigations using biological samples and animals from the core study. The selected grants were reviewed by NTP for feasibility of the proposed experimental design only. Thus, the CLARITY-BPA program, initiated and funded by NIEHS through NTP with the participation of FDA and grantee investigators, represents a new model for research.

## About the CLARITY-BPA Compendium Report

This report summarizes the experimental procedures, findings, and authors’ interpretations in each of the original peer-reviewed publications from the CLARITY-BPA research program. The findings from the core study presented in the following chapters include all measurements found significant (p < 0.05) by the statistical tests applied, which in the case of histopathology data did not include adjustment for multiple comparisons. The report is organized into 10 chapters by organ or organ system, including brain and behavior, cardiac, immune, mammary gland, ovary, penile function, prostate gland and urethra, testis and epididymis, metabolism and thyroid hormone, and uterus. The reader may refer to the raw data in the NTP’s Chemical Effects in Biological Systems (CEBS) database ([underlined: https://cebs.niehs.nih.gov/cebs/program/CLARITY-BPA]) and study details in the original peer-reviewed publications for more information. In addition, Camacho et al. (2019) presented a summary of the core study data but included a more expansive discussion of the FDA’s conclusions. An integrated analysis of findings from eight CLARITY-BPA grantee studies has also been published (Heindel et al. 2020); however, this paper is not summarized in this report.

Several grantee studies remain unpublished; the designs of these studies are briefly described in the following chapters, but their findings are not included. All data from the core study and the majority of data from the grantee studies, including unpublished studies, are available in the NTP CEBS database.

Effort has been made to provide an accurate account of the experimental procedures, findings, and authors’ interpretations reported in each of the peer-reviewed publications. No attempt was made to reconcile any differences in authors’ interpretations in common tissues or to reanalyze published data. For complete details of these studies and the authors’ conclusions, please refer to the original peer-reviewed publications.