# Conflict of Interest

This report should not be construed to represent FDA’s views or policies. This report provides a partial account of the findings and conclusions of the CLARITY-BPA core study conducted by FDA/NCTR staff and of the investigational studies conducted by each individual consortium grantee, as reported in their respective peer-reviewed publications. The summary of each peer-reviewed publication is the sole responsibility of the respective study authors, and participation in this report does not imply acceptance or agreement on the data reporting or interpretation in each peer-reviewed publication.