# Acknowledgments

The CLARITY-BPA core study and program was funded by the National Institute of Environmental Health Sciences (NIEHS) under an Interagency Agreement between FDA and NIEHS (FDA IAG #224-17-0502 and NIH IAG #AES12013) and extramural NIEHS grants to the investigational researchers. The CLARITY-BPA Compendium Report was supported by the Intramural Research Program (ES103316, ES103317) at NIEHS, National Institutes of Health, U.S. Department of Health and Human Services, under contracts HHSN316201200028W (Order No. HHSN27300006 and Order No. HHSN27300002) and GS00Q14OADU417 (Order No. HHSN273201600015U).