# Appendix A CLARITY-BPA Compendium Report Gene Glossary

  Acaca: Acetyl-CoA carboxylase alpha
  Acot1: Acyl-CoA thioesterase 1
  Ar: Androgen receptor
  Avp: Arginine vasopressin
  Avpr1a: Arginine vasopressin receptor 1A
  B2m: Beta-2 microglobulin
  Bdnf: Brain-derived neurotrophic factor
  Bmp4: Bone morphogenetic protein 4
  Camk4: Calcium/calmodulin-dependent protein kinase 4
  Ccl2: Chemokine (C-C motif) ligand 2
  Ccl6: Chemokine (C-C motif) ligand 6
  Cebpa: CCAAT/enhancer binding protein alpha
  Chga: Chromogranin A
  CK5: Cytokeratin 5
  CK8: Cytokeratin 8
  Cyp11a1: Cytochrome P450 family 11 subfamily A polypeptide 1
  Cyp19a1: Cytochrome P450 family 19 subfamily A member 1
  Dkk2: Dickkopf WNT signaling pathway inhibitor 2
  Dnmt1: DNA methyltransferase 1
  Dnmt3a: DNA methyltransferase 3 alpha
  Dnmt3b: DNA methyltransferase 3 beta
  Emr1: Adhesion G protein-coupled receptor E1
  Esr1: Estrogen receptor 1 (ER-alpha)
  Esr2: Estrogen receptor 2 (ER-beta)
  Erra/Esrra: Estrogen receptor-related alpha
  Errb: Estrogen receptor-related beta
  Esr1: Estrogen receptor 1
  Esr2: Estrogen receptor 2
  Gadd45b: Growth arrest and DNA damage inducible beta
  Gpr30: G protein coupled receptor 30
  Grm5: Glutamate metabotropic receptor 5
  Hmgcr: 3-hydroxy-3-methylglutaryl-CoA reductase
  Hmgcs1: 3-hydroxy-3-methylglutaryl-CoA synthase 1
  Hoxb13: Homeobox protein B13
  Hprt: Hypoxanthine phosphoribosyl transferase
  Igf1: Insulin-like growth factor 1
  Il1b: Interleukin 1 beta
  Il6: Interleukin 6
  Lepr: Leptin receptor
  Mag: Myelin associated glycoprotein
  Nr5a1: Nuclear receptor subfamily 5 group A member 1 (see also Sf-1)
  Otr/Oxtr: Oxytocin receptor
  Oxt: Oxytocin
  Ppara: Peroxisome proliferator-activated receptor alpha
  Pparg: Peroxisome proliferative activated receptor gamma
  Ppargc1a: Peroxisome proliferative activated receptor gamma coactivator 1 alpha
  Ppib: Peptidylprolyl isomerase B
  Ptgds: Prostaglandin D2 synthase
  Scd1: Stearoyl-Coenzyme A desaturase
  Sf1: Steroidogenic factor 1
  Sfrp4: Secreted frizzled-related protein 4
  Slc1a2: Solute carrier family 1 member 2
  Slc2a4: Glucose transporter 4 (Solute carrier family 2 (facilitated glucose transporter), member 4)
  Slc32a1: Solute carrier family 32 member 1
  Sox2: Sex-determining region Y box 2
  Sox9: Sex-determining region Y box 9
  Srebf1: Sterol regulatory element binding transcription factor 1
  Srebf2: Sterol regulatory element binding transcription factor 2
  Tbx3: T-box 3
  Thbs2: Thrombospondin 2
  Tnf: Tumor necrosis factor
  Tnfa: Tumor necrosis factor alpha
  Trh: Thyrotropin releasing hormone
  Trop2: Tumor-associated calcium signal transducer 2
  TshÎ²: Thyroid hormone stimulating hormone beta