# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: https://doi.org/10.22427/NTP-RR-17

Report Series: NTP Research Report Series

Report Series Number: 17

Official citation: National Toxicology Program (NTP). 2020. NTP research report on the scoping review of prenatal exposure to progestogens and adverse health outcomes. Research Triangle Park, NC: National Toxicology Program. Research Report 17.