# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Research Report on the Scoping Review of Prenatal Exposure to Progestogens and Adverse Health Outcomes by letter in June 2020 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

(1) Peer review the draft NTP Research Report on the Scoping Review of Prenatal Exposure to Progestogens and Adverse Health Outcomes.

(2) Comment on the adequacy of the scoping review in identifying and summarizing the relevant literature.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Marian McDonagh, Ph.D.
  Professor, Oregon Health and Science University School of Medicine
  Associate Director, Pacific Northwest Evidence-based Practice Center
  Portland, Oregon, USA
- Catherine Spong, Ph.D.
  Professor, Chief of Maternal Fetal Medicine
  Vice Chair, Department of Obstetrics and Gynecology; The University of Texas Southwestern Medical Center
  Dallas, Texas, USA