# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Contributed to conception or design and contributed to drafting of protocol
  Kembra L. Howdeshell, Ph.D., Project Lead
  Andrew A. Rooney, Ph.D.
  Michael D. Shelby, Ph.D.
- Screened studies, extracted data, and contributed to conception or design and drafting of report
  Kembra L. Howdeshell, Ph.D., Project Lead
  Michael D. Shelby, Ph.D.
- Contributed to conception or design and drafting of report
  Brandiese E. Beverly, Ph.D.
  Windy A. Boyd, Ph.D.
  Andrew A. Rooney, Ph.D.
  Kyla W. Taylor, Ph.D.
  Vickie R. Walker, B.S.
- ICF, Research Triangle Park, North Carolina, USA
  Assisted with literature screening, data extraction, and design of figures
  Alexandra E. Goldstone, M.P.H., Co-lead Work Assignment Manager
  Christopher A. Sibrizzi, M.P.H., Co-lead Work Assignment Manager
  Courtney Skuce, B.A.