# References

Aarskog D. 1971. Intersex conditions masquerading as simple hypospadias. Birth Defects Orig Artic Ser. 7(6):122–130. 5173749
Ahmad G, Zamenhof S. 1979. The effect of progesterone on brain and body growth of chick embryos. Growth. 43(1):58–61. 456930
Andrew FD, Staples RE. 1977. Prenatal toxicity of medroxyprogesterone acetate in rabbits, rats, and mice. Teratology. 15(1):25–32. 10.1002/tera.1420150104 841480
Beard CM, Melton LJ 3rd, O’Fallon WM, Noller KL, Benson RC. 1984. Cryptorchism and maternal estrogen exposure. Am J Epidemiol. 120(5):707–716. 10.1093/oxfordjournals.aje.a113938 6149686
Briery CM, Veillon EW, Klauser CK, Martin RW, Chauhan SP, Magann EF, Morrison JC. 2009. Progesterone does not prevent preterm births in women with twins. South Med J. 102(9):900–904. 10.1097/SMJ.0b013e3181afee12 19668021
Brucker M, Likis F. 2010. Steroid hormones. In: King T, Brucker M, editors. Pharmacology for Women’s Health. Burlington, MA: Jones & Bartlett Publishers.
Calzolari E, Contiero MR, Roncarati E, Mattiuz PL, Volpato S. 1986. Aetiological factors in hypospadias. J Med Genet. 23(4):333–337. 10.1136/jmg.23.4.333 3746833
Carbone JP, Brent RL. 1993. Genital and nongenital teratogenesis of prenatal progestogen therapy: The effects of 17 alpha-hydroxyprogesterone caproate on embryonic and fetal development and endochondral ossification in the C57B1/6J mouse. Am J Obstet Gynecol. 169(5):1292–1298. 10.1016/0002-9378(93)90296-U 8238197
Carmichael SL, Shaw GM, Laurent C, Croughan MS, Olney RS, Lammer EJ. 2005. Maternal progestin intake and risk of hypospadias. Arch Pediatr Adolesc Med. 159(10):957–962. 10.1001/archpedi.159.10.957 16203941
Colvin L, Slack-Smith L, Stanley FJ, Bower C. 2010. Linking a pharmaceutical claims database with a birth defects registry to investigate birth defect rates of suspected teratogens. Pharmacoepidemiol Drug Saf. 19(11):1137–1150. 10.1002/pds.1995 20602344
Coomarasamy A, Devall AJ, Cheed V, Harb H, Middleton LJ, Gallos ID, Williams H, Eapen AK, Roberts T, Ogwulu CC, 2019. A randomized trial of progesterone in women with bleeding in early pregnancy. N Engl J Med. 380(19):1815–1824. 10.1056/NEJMoa1813730 31067371
Coomarasamy A, Williams H, Truchanowicz E, Seed PT, Small R, Quenby S, Gupta P, Dawood F, Koot YE, Atik RB. 2015. A randomized trial of progesterone in women with recurrent miscarriages. N Engl J Med. 373(22):2141–2148. 10.1056/NEJMoa1504927 26605928
Coomarasamy A, Williams H, Truchanowicz E, Seed PT, Small R, Quenby S, Gupta P, Dawood F, Koot YE, Atik RB, 2016. PROMISE: First-trimester progesterone therapy in women with a history of unexplained recurrent miscarriages-a randomised, double-blind, placebo-controlled, international multicentre trial and economic evaulation. Health Technol Assess. 20(41):1–92. 10.3310/hta20410 27225013
Corona-Rivera JR, Bobadilla-Morales L, Corona-Rivera A, Pena-Padilla C, Olvera-Molina S, Orozco-Martin MA, Garcia-Cruz D, Rios-Flores IM, Gomez-Rodrigues BG, Rivas-Soto G, 2018. Prevalence of orofacial clefts and risks of nonsyndromic cleft lip with or without cleft palate in newborns at a university hospital from West Mexico. Congenit Anom (Kyoto). 58(4):117–123. 10.1111/cga.12276 29457660
Coyle IR, Anker R, Cragg B. 1976. Behavioral, biochemical and histological effects of prenatal administration of progesterone in the rat. Pharmacol Biochem Behav. 5(5):587–590. 10.1016/0091-3057(76)90274-4 1019189
Csaba G, Karabelyos C, Dallo J. 1993. Fetal and neonatal action of a polycyclic hydrocarbon (benzpyrene) or a synthetic steroid hormone (allylestrenol) as reflected by the sexual behaviour of adult rats. J Dev Physiol. 19(2):67–70. 8409276
Czeizel A, Huiskes N. 1988. A case-control study to evaluate the risk of congenital anomalies as a result of allylestrenol therapy during pregnancy. Clin Ther. 10(6):725–739. 3219686
Czeizel A, Kodaj I. 1995. A changing pattern in the association of oral contraceptives and the different groups of congenital limb deficiencies. Contraception. 51(1):19–24. 10.1016/0010-7824(94)00008-K 7750279
Dalton K. 1968. Ante-natal progesterone and intelligence. Br J Psychiatry. 114(516):1377–1382. 10.1192/bjp.114.516.1377 5702278
Dalton K. 1976. Prenatal progesterone and educational attainments. Br J Psychiatry. 129:438–442. 10.1192/bjp.129.5.438 990657
De Santis M, Cavaliere AF, Straface G, Carducci B, Caruso A. 2005. Failure of the emergency contraceptive levonorgestrel and the risk of adverse effects in pregnancy and on fetal development: An observational cohort study. Fertil Steril. 84(2):296–299. 10.1016/j.fertnstert.2005.01.136 16084867
Dohler KD, Coquelin A, Davis F, Hines M, Shryne JE, Sickmoller PM, Jarzab B, Gorski RA. 1986. Pre- and postnatal influence of an estrogen antagonist and an androgen antagonist on differentiation of the sexually dimorphic nucleus of the preoptic area in male and female rats. Neuroendocrinology. 42(5):443–448. 10.1159/000124484 2939360
Dudas I, Gidai J, Czeizel A. 2006. Population-based case-control teratogenic study of hydroxyprogesterone treatment during pregnancy. Congenit Anom (Kyoto). 46(4):194–198. 10.1111/j.1741-4520.2006.00128.x 17096820
Ehrhardt AA, Grisanti GC, Meyer-Bahlburg HF. 1977. Prenatal exposure to medroxyprogesterone acetate (MPA) in girls. Psychoneuroendocrinology. 2(4):391–398. 10.1016/0306-4530(77)90010-5 601176
Ehrhardt AA, Meyer-Bahlburg HF, Feldman JR, Ince SE. 1984. Sex-dimorphic behavior in childhood subsequent to prenatal exposure to exogenous progestogens and estrogens. Arch Sex Behav. 13(5):457–477. 10.1007/BF01541430 6240240
Eibs HG, Spielmann H, Hagele M. 1982. Teratogenic effects of cyproterone acetate and medroxyprogesterone treatment during the pre- and postimplantation period of mouse embryos. I. Teratology. 25(1):27–36. 10.1002/tera.1420250105 6461082
El Kholy M, Hamza RT, Saleh MHE. 2013. Penile length and genital anomalies in Egyptian male newborns: Epidemiology and influence of endocrine disruptors. J Pediatr Endocrinol Metab. 26(5-6):509–513. 10.1515/jpem-2012-0350 23509209
El-Zibdeh MY. 2005. Dydrogesterone in the reduction of recurrent spontaneous abortion. J Steroid Biochem Mol Biol. 97(5):431–434. 10.1016/j.jsbmb.2005.08.007 16253504
Elovitz MA, Mrinalini C. 2006. The use of progestational agents for preterm birth: Lessons from a mouse model. Am J Obstet Gynecol. 195(4):1004–1010. 10.1016/j.ajog.2006.06.013 17000233
Etzel V, Schenck B, Neumann F. 1974. Influence of cyproterone acetate during pregnancy on the sexual behaviour of male guinea-pigs. J Reprod Fertil. 37(2):315–321. 10.1530/jrf.0.0370315 4856833
Ferencz C, Matanoski GM, Wilson PD, Rubin JD, Neill CA, Gutberlet R. 1980. Maternal hormone therapy and congenital heart disease. Teratology. 21(2):225–239. 10.1002/tera.1420210213 7394725
Foote WD, Foote WC, Foote LH. 1968. Influence of certain natural and synthetic steroids on genital development in guinea pigs. Fertil Steril. 19(4):606–615. 10.1016/S0015-0282(16)36735-8 5660245
Forsberg JG, Jacobsohn D. 1969. The reproductive tract of males delivered by rats given cyproterone acetate from days 7 to 21 of pregnancy. J Endocrinol. 44(3):461–462. 10.1677/joe.0.0440461 5800458
Forsberg JG, Jacobsohn D, Norgren A. 1968. Development of the urogenital tract in male offspring of rats injected during pregnancy with a substance with antiandrogenic properties (cyproterone). Z Anat Entwicklungsgesch. 126(4):320–331. 10.1007/BF00520797 5691547
Gandelman R, Howard SM, Reinisch JM. 1981. Perinatal exposure to 19-nor-17 alpha-ethynyltestosterone (norethindrone) influences morphology and aggressive behavior of female mice. Horm Behav. 15(4):404–415. 10.1016/0018-506X(81)90005-2 7199016
Gellersen B, Fernandes MS, Brosens JJ. 2009. Non-genomic progesterone actions in female reproduction. Hum Reprod Update. 15(1):119–138. 10.1093/humupd/dmn044 18936037
Gerhard I, Gwinner B, Eggert-Kruse W, Runnebaum B. 1987. Double-blind controlled trial of progesterone substitution in threatened abortion. Biol Res Pregnancy Perinatol. 8(1 1ST Half):26-34.
Giannia T, Steinetz BG, Rassaert CL, McDougall EA, Meli A. 1969. Biological profile of quingestanol acetate. Proc Soc Exp Biol Med. 131(3):781–789. 10.3181/00379727-131-33977 5815452
Graf KJ, Neumann F. 1972. Influence of cyproterone acetate on sexual differentiation of male guinea pigs. Z Anat Entwicklungsgesch. 137(2):200–220. 10.1007/BF00538791 5055050
Grumbach MM, Ducharme JR, Moloshok RE. 1959. On the fetal masculinizing action of certain oral progestins. J Clin Endocrinol Metab. 19:1369–1380. 10.1210/jcem-19-11-1369 13829837
Guo X-Y, Liu X-M, Jin L, Wang T-T, Ullah K, Sheng J-Z, Huang H-F. 2017. Cardiovascular and metabolic profiles of offspring conceived by assisted reproductive technologies: A systematic review and meta-analysis. Fertil Steril. 107(3):622–631.e625. 10.1016/j.fertnstert.2016.12.007 28104241
Gupta C, Goldman AS. 1986. The arachidonic acid cascade is involved in the masculinizing action of testosterone on embryonic external genitalia in mice. Proc Natl Acad Sci USA. 83(12):4346–4349. 10.1073/pnas.83.12.4346 3086881
Hadjigeorgiou E, Malamitsi-Puchner A, Lolis D, Lazarides P, Nicolopoulos D, Kaskarelis D. 1982. Cardiovascular birth defects and antenatal exposure to female sex hormones. Dev Pharmacol Ther. 5(1-2):61–67. 10.1159/000481008 7151638
Hapgood JP, Africander D, Louw R, Ray RM, Rohwer JM. 2014. Potency of progestogens used in hormonal therapy: Toward understanding differential actions. J Steroid Biochem Mol Biol. 142:39–47. 10.1016/j.jsbmb.2013.08.001 23954501
Harini C, Sainath SB, Reddy PS. 2009. Progesterone administration induces preimplantation embryonic loss in mic. Fertil Steril. 91(5) Suppl:2137–2141. 10.1016/j.fertnstert.2008.06.031 18692799
Heinonen OP, Slone D, Monson RR, Hook EB, Shapiro S. 1977. Cardiovascular birth defects and antenatal exposure to female sex hormones. N Engl J Med. 296(2):67–70. 10.1056/NEJM197701132960202 830309
Hemminki E, Gissler M, Toukomaa H. 1999. Exposure to female hormone drugs during pregnancy: Effect on malformations and cancer. Br J Cancer. 80(7):1092–1097. 10.1038/sj.bjc.6690469 10362122
Hendrickx AG, Korte R, Leuschner F, Neumann BW, Poggel A, Binkerd P, Prahalada S, Gunzel P. 1987. Embryotoxicity of sex steroidal hormones in nonhuman primates: II. Hydroxyprogesterone caproate, estradiol valerate. Teratology. 35(1):129–136. 10.1002/tera.1420350116 3563931
Herrington J, Vallian C, Lickliter R. 2015. Increased yolk progesterone interferes with prenatal auditory learning and elevates emotional reactivity in bobwhite quail (Colinus virginianus) chicks. Dev Psychobiol. 57(2):255–262. 10.1002/dev.21274 25650094
Herrington JA, Rodriguez Y, Lickliter R. 2016. Elevated yolk progesterone moderates prenatal heart rate and postnatal auditory learning in bobwhite quail (Colinus virginianus). Dev Psychobiol. 58(6):784–788. 10.1002/dev.21419 27108924
Higgins JPT, Thomas J, Chandler J, Cumpston M, Li T, Page MJ, Welch VA.2019. Cochrane Handbook for Systematic Reviews of Interventions version 6.0 www.training.cochrane.org/handbook (https://training.cochrane.org/handbook/current). [Updated July 2019]
Hilgers TW, Keefe CE, Pakiz KA. 2015. The use of isomolecular progesterone in the support of pregnancy and fetal safety. Issues Law Med. 30(2):159–168. 26710374
Howard BE, Phillips J, Tandon A, Maharana A, Elmore R, Mav D, Sedykh A, Thayer K, Merrick BA, Walker V, 2020. SWIFT-Active Screener: Accelerated document screening through active learning and integrated recall estimation. Environ Int. 138:105623. 10.1016/j.envint.2020.105623 32203803
Howdeshell KL. 2002. A model of the development of the brain as a construct of the thyroid system. Environ Health Perspect. 110 Suppl 3:337–348. 10.1289/ehp.02110s3337 12060827
Hull EM, Franz JR, Snyder AM, Nishita JK. 1980. Perinatal progesterone and learning, social and reproductive behavior in rats. Physiol Behav. 24(2):251–256. 10.1016/0031-9384(80)90082-7 7189594
Institute of Medicine (IOM).2007. Preterm Birth: Causes, Consequences, and Prevention. Institute of Medicine U.S. Committee on Understanding Premature Birth and Assuring Health Outcomes Report. Washington, D.C.: National Academies Press. 10.17226/11622.
International Agency Research on Cancer (IARC). 1974. Sex Hormones IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Lyon, France: International Agency for Research on Cancer; Progesterone; p. 135–146.
International Agency Research on Cancer (IARC). 1979. Sex Hormones II IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans. Lyon, France: International Agency for Research on Cancer; Progesterone; p. 491–515.
International Agency Research on Cancer (IARC). 1982. Chemicals, Industrial Processes and Industries Associated with Cancer in Humans. Lyon, France: IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans; Progesterone; p. 202–203.
Iqbal I, Qamar K, Butt SA, Hayder O, Saeed I, Moor U. 2012. The role of folic acid in prevention of neural tube defects caused by high dose progesterone. Turk Neurosurg. 22(1):7–12. 22274964
Jaffe B, Harlap S, Baras M, Gordon L, Lieblich A, Magidor S, Sanchez M. 1988. Long-term effects of MPA on human progeny: Intellectual development. Contraception. 37(6):607–619. 10.1016/0010-7824(88)90007-8 2969321
Jaffe B, Shye D, Harlap S, Baras M, Belmaker E, Gordon L, Magidor S, Fortney J. 1990. Health, growth and sexual development of teenagers exposed in utero to medroxyprogesterone acetate. Paediatr Perinat Epidemiol. 4(2):184–195. 10.1111/j.1365-3016.1990.tb00637.x 2362875
Jaffe B, Shye D, Harlap S, Baras M, Lieblich A. 1989. Aggression, physical activity levels and sex role identity in teenagers exposed in utero to MPA. Contraception. 40(3):351–363. 10.1016/0010-7824(89)90098-X 2527728
Johnstone EE, Franklin RR. 1964. Assay of progestins for fetal virilizing properties using the mouse. Obstet Gynecol. 23:359–362. 14128463
Kane S.2018. The Top 300 of 2018, ClinCalc DrugStats Database, Version 18.0. ClinCalc. https://clincalc.com/DrugStats/Top300Drugs.aspx.
Karabelyos C, Csaba G, Dallo J. 1994 a. Effect of treatment with contraceptive steroids on the sexual behaviour of rats pretreated with benzpyrene or allylestrenol in fetal or neonatal age. Horm Metab Res. 26(8):371–373. 10.1055/s-2007-1001709 7806132
Karabelyos C, Dallo J, Csaba G. 1994 b. Effects of benzpyrene and allylestrenol administered during pregnancy on the sexual behaviour of castrated and hormone treated adult rats. Acta Physiol Hung. 82(2):175–180. 7887177
Katz Z, Lancet M, Skornik J, Chemke J, Mogilner BM, Klinberg M. 1985. Teratogenicity of progestogens given during the first trimester of pregnancy. Obstet Gynecol. 65(6):775–780. 10.1097/00006254-198511000-00016 3158848
Keith L, Berger GS. 1977. The relationship between congenital defects and the use of exogenous progestional “contraceptive” hormones during pregnancy: A 20-year review. Int J Gynaecol Obstet. 15(2):115–124. 10.1002/j.1879-3479.1977.tb00659.x 342297
Keppler-Noreuil KM, Conway KM, Shen D, Rhoads AJ, Carey JC, Romitti PA. 2017. Clinical and risk factor analysis of cloacal defects in the National Birth Defects Prevention Study. Am J Med Genet A. 173(11):2873–2885. 10.1002/ajmg.a.38469 28960693
Kester P. 1984. Effects of prenatally administered 17 alpha-hydroxyprogesterone caproate on adolescent males. Arch Sex Behav. 13(5):441–455. 10.1007/BF01541429 6517685
Kester P, Green R, Finch SJ, Williams K. 1980. Prenatal ‘female hormone’ administration and psychosexual development in human males. Psychoneuroendocrinology. 5(4):269–285. 10.1016/0306-4530(80)90032-3 7208750
Lammer EJ, Cordero JF. 1986. Exogenous sex hormone exposure and the risk for major malformations. JAMA. 255(22):3128–3132. 10.1001/jama.1986.03370220090033 3702023
Li L, Li M, Ge X, Xie W, Wang Z, Li X, Li C, Wang Y, Han Y. 2018. Prenatal progestin exposure is associated with Autism Spectrum Disorders. Front Psychiatry. 9:611. 10.3389/fpsyt.2018.00611 30510526
Louw-du Toit R, Perkins MS, Hapgood JP, Africander D. 2017. Comparing the androgenic and estrogenic properties of progestins used in contraception and hormone therapy. Biochem Biophys Res Commun. 491(1):140–146. 10.1016/j.bbrc.2017.07.063 28711501
Lynch A, Mychalkiw W, Hutt SJ. 1978. Prenatal progesterone. I. Its effect on development and on intellectual and academic achievement. Early Hum Dev. 2(4):305–322. 10.1016/0378-3782(78)90059-2 750191
Massaro PA, MacLellan DL, Anderson PA, Romao RLP. 2015. Does intracytoplasmic sperm injection pose an increased risk of genitourinary congenital malformations in offspring compared to in vitro fertilization? A systematic review and meta-analysis. J Urol. 193 5S:1837–1842. 10.1016/j.juro.2014.10.113 25813561
Matsunaga E, Shiota K. 1979. Threatened abortion, hormone therapy and malformed embryos. Teratology. 20(3):469–480. 10.1002/tera.1420200317 542899
Mavrogenis S, Urban R, Czeizel AE, Acs N. 2014. Maternal risk factors in the origin of isolated hypospadias: A population-based case-control study. Congenit Anom (Kyoto). 54(2):110–115. 10.1111/cga.12041 24279371
McNamara HC, Wood R, Chalmers J, Marlow N, Norrie J, MacLennan G, McPherson G, Boachie C, Norman JE. 2015. STOPPIT baby follow-up study: The effect of prophylactic progesterone in twin pregnancy on childhood outcome. PLoS One. 10(4):e0122341. 10.1371/journal.pone.0122341 25881289
Menzies KD, Drysdale DB, Waite PM. 1982. Effects of prenatal progesterone on the development of pyramidal cells in rat cerebral cortex. Exp Neurol. 77(3):654–667. 10.1016/0014-4886(82)90236-9 7117469
Meyer-Bahlburg HF, Feldman JF, Cohen P, Ehrhardt AA. 1988. Perinatal factors in the development of gender-related play behavior: Sex hormones versus pregnancy complications. Psychiatry. 51(3):260–271. 10.1080/00332747.1988.11024401 3217455
Meyer-Bahlburg HF, Feldman JF, Ehrhardt AA, Cohen P. 1984. Effects of prenatal hormone exposure versus pregnancy complications on sex-dimorphic behavior. Arch Sex Behav. 13(5):479–495. 10.1007/BF01541431 6240241
Meyer-Bahlburg HF, Grisanti GC, Ehrhardt AA. 1977. Prenatal effects of sex hormones on human male behavior: Medroxyprogesterone acetate (MPA). Psychoneuroendocrinology. 2(4):383–390. 10.1016/0306-4530(77)90009-9 564072
Michaelis J, Michaelis H, Gluck E, Koller S. 1983. Prospective study of suspected associations between certain drugs administered during early pregnancy and congenital malformations. Teratology. 27(1):57–64. 10.1002/tera.1420270109 6845218
Moore KL, Persaud TVN, Torchia MG. 2016. The Developing Human: Clinically Oriented Embryology. Philadelphia, PA: Elsevier.
National Toxicology Program (NTP).2016. Report on Carcinogens, Fourteenth Edition. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service. https://ntp.niehs.nih.gov/go/roc14
National Toxicology Program (NTP).2020. Tableau data on the scoping review of prenatal exposure to progestogens and adverse health outcomes. 10.22427/NTP-DATA-RR-17
Nora AH, Nora JJ. 1975. A syndrome of multiple congenital anomalies associated with teratogenic exposure. Arch Environ Health. 30(1):17–21. 10.1080/00039896.1975.10666626 1109267
Norman JE, Marlow N, Messow CM, Shennan A, Bennett PR, Thornton S, Robson SC, McConnachie A, Petrou S, Sebire NJ, 2016. Vaginal progesterone prophylaxis for preterm birth (the OPPTIMUM study): A multicentre, randomised, double-blind trial. Lancet. 387(10033):2106–2116. 10.1016/S0140-6736(16)00350-0 26921136
Norman JE, Marlow N, Messow CM, Shennan A, Bennett PR, Thornton S, Robson SC, McConnachie A, Petrou S, Sebire NJ, 2018. Does progesterone prophylaxis to prevent preterm labour improve outcome? A randomised double-blind placebo-controlled trial (OPPTIMUM). Health Technol Assess. 22(35):1–304. 10.3310/hta22350 29945711
Northern AT, Norman GS, Anderson K, Moseley L, Divito M, Cotroneo M, Swain M, Bousleiman S, Johnson F, Dorman K, 2007. Follow-up of children exposed in utero to 17 alpha-hydroxyprogesterone caproate compared with placebo. Obstet Gynecol. 110(4):865–872. 10.1097/01.AOG.0000281348.51499.bc 17906021
Palacio M, Cobo T, Antolin E, Ramirez M, Cabrera F, Mozo de Rosales F, Bartha JL, Juan M, Marti A, Oros D, 2016. Vaginal progesterone as maintenance treatment after an episode of preterm labour (PROMISE) study: A multicentre, double-blind, randomised, placebo-controlled tria. BJOG. 123(12):1990–1999. 10.1111/1471-0528.13956 27028759
Pamir E, Ali D, Ismail C, Sanli E, Ali K, Mustafa T. 2006. The effects of high dose progesterone on neural tube development in early chick embryos. Neurol India. 54(2):178–181. 16804264
Pandian RU. 2009. Dydrogesterone in threatened miscarriage: A Malaysian experience. Maturitas. 65 Suppl 1:S47–S50. 10.1016/j.maturitas.2009.11.016 20005647
Pardthaisong T, Gray RH, McDaniel EB, Chandacham A. 1988. Steroid contraceptive use and pregnancy outcome. Teratology. 38(1):51–58. 10.1002/tera.1420380108 2845595
Pardthaisong T, Yenchit C, Gray R. 1992. The long-term growth and development of children exposed to Depo-Provera during pregnancy or lactation. Contraception. 45(4):313–324. 10.1016/0010-7824(92)90053-V 1387602
Perakis A, Stylianopoulou F. 1986. Effects of a prenatal androgen peak on rat brain sexual differentiation. J Endocrinol. 108(2):281–285. 10.1677/joe.0.1080281 2936858
Plunchino N, Russo M, Genazzani AR. 2016. The fetal brain: Role of progesterone and allopregnanolone. Horm Mol Biol Clin Investig. 27(1):29–34X. 10.1515/hmbci-2016-0020 27442421
Pointis G, Latreille MT, Richard MO, D’Athis P, Cedard L. 1987. Effect of natural progesterone treatment during pregnancy on fetal testosterone and sexual behavior of the male offspring in the mouse. Dev Pharmacol Ther. 10(5):385–392. 10.1159/000457768 3652903
Prahalada S, Carroad E, Cukierski M, Hendrickx AG. 1985 a. Embryotoxicity of a single dose of medroxyprogesterone acetate (MPA) and maternal serum MPA concentrations in cynomolgus monkey (Macaca fascicularis). Teratology. 32(3):421–432. 10.1002/tera.1420320312 2934853
Prahalada S, Carroad E, Hendrickx AG. 1985 b. Embryotoxicity and maternal serum concentrations of medroxyprogesterone acetate (MPA) in baboons (Papio cynocephalus). Contraception. 32(5):497–515. 10.1016/0010-7824(85)90020-4 2935368
Pushpalatha T, Reddy PR, Reddy PS. 2005. Gestational exposure to hydroxyprogesterone caproate suppresses reproductive potential in male rats. Naturwissenschaften. 92(8):385–388. 10.1007/s00114-005-0005-x 16049688
Qin J, Liu X, Sheng X, Wang H, Gao S. 2016. Assisted reproductive technology and the risk of pregnancy-related complications and adverse pregnancy outcomes in singleton pregnancies: A meta-analysis of cohort studies. Fertil Steril. 105(1):73–85.e76. 10.1016/j.fertnstert.2015.09.007 26453266
Regestein QR, Williams GH, Rose LI. 1975. Influence of perinatal progesterone on sexual activity in the male guinea pig. J Psychiatr Res. 12(3):149–151. 10.1016/0022-3956(75)90022-9 1202201
Reinisch JM. 1977. Prenatal exposure of human foetuses to synthetic progestin and oestrogen affects personality. Nature. 266(5602):561–562. 10.1038/266561a0 859624
Reinisch JM. 1981. Prenatal exposure to synthetic progestins increases potential for aggression in humans. Science. 211(4487):1171–1173. 10.1126/science.7466388 7466388
Reinisch JM, Karow WG. 1977. Prenatal exposure to synthetic progestins and estrogens: Effects on human development. Arch Sex Behav. 6(4):257–288. 10.1007/BF01541201 889431
Reinisch JM, Mortensen EL, Sanders SA. 2017. Prenatal exposure to progesterone affects sexual orientation in humans. Arch Sex Behav. 46(5):1239–1249. 10.1007/s10508-016-0923-z 28374065
Resseguie LJ, Hick JF, Bruen JA, Noller KL, O’Fallon WM, Kurland LT. 1985. Congenital malformations among offspring exposed in utero to progestins, Olmsted County, Minnesota, 1936-1974. Fertil Steril. 43(4):514–519. 10.1016/S0015-0282(16)48490-6 3987922
Rice D, Barone S Jr. 2000. Critical periods of vulnerability for the developing nervous system: Evidence from humans and animal models. Environ Health Perspect. 108 Suppl 3:511–533. 10852851
Rode L, Klein K, Nicolaides KH, Krampl-Bettelheim E, Tabor A. 2011. Prevention of preterm delivery in twin gestations (PREDICT): A multicenter, randomized, placebo-controlled trial on the effect of vaginal micronized progesterone. Ultrasound Obstet Gynecol. 38(3):272–280. 10.1002/uog.9093 21739497
Romero R, Stanczyk FZ. 2013. Progesterone is not the same as 17alpha-hydroxyprogesterone caproate: Implications for obstetrical practice. Am J Obstet Gynecol. 208(6):421–426. 10.1016/j.ajog.2013.04.027 23643669
Rooney AA, Boyles AL, Wolfe MS, Burcher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Sannes E, Lyngest A, Nafstad I. 1983. Teratogenicity and embryotoxicity of orally administered lynestrenol in rabbits. Arch Toxicol. 52(1):23–33. 10.1007/BF00317979 6838375
Schardein JL, Birch R, Hesley R, Thorsrud BA. 2012. Multigeneration reproductive study of hydroxyprogesterone caproate (HPC) in the rat: Laboratory results and clinical significance. Birth Defects Res B Dev Reprod Toxicol. 95(2):160–174. 10.1002/bdrb.21000 22528880
Schindler AE. 2015. Progestogens in Obstetrics and Gynecology. Switzerland: Springer International Publishing; Pharmacology of progestins; p. 33–40. 10.1007/978-3-319-14385-9_2
Schindler AE, Campagnoli C, Druckmann R, Huber J, Pasqualini JR, Schweppe KW, Thijssen JH. 2008. Classification and pharmacology of progestins. Maturitas. 61(1-2):171–180. 10.1016/j.maturitas.2008.11.013 19434889
Scouten CW, Groteleuschen LK, Beatty WW. 1975. Androgens and the organization of sex differences in active avoidance behavior in the rat. J Comp Physiol Psychol. 88(1):264–270. 10.1037/h0076184 1120803
Seegmiller RE, Nelson GW, Johnson CK. 1983. Evaluation of the teratogenic potential of delalutin (17 alpha-hydroxyprogesterone caproate) in mice. Teratology. 28(2):201–208. 10.1002/tera.1420280208 6648824
Shaw JC, Palliser HK, Palazzi K, Hirst JJ. 2017. Administration of progesterone throughout pregnancy increases maternal steroids without adverse effect on mature oligodendrocyte immunostaining in the guinea pig. Reprod Sci. 25(3):395–405. 10.1177/1933719117715125 28631553
Shepard TH, Lemire RJ. 2004. Catalog of Teratogenic Agents. Baltimore, MD: The John Hopkins University Press.
Silva M, Silva JFD, Santon TP, Silva N, Santos ARD, Andrade ALC, Souza E, Sales Cadena MR, Sa FB, Silva VAD Junior, 2019. The complexation of steroid hormones into cyclodextrin alters the toxic effects on the biological parameters of zebrafish (Danio rerio). Chemosphere. 214:330–340. 10.1016/j.chemosphere.2018.09.116 30267906
Snyder AM, Hull EM. 1980. Perinatal progesterone affects learning in rats. Psychoneuroendocrinology. 5(2):113–119. 10.1016/0306-4530(80)90014-1 7394127
Soyer-Gobillard MO, Gaspari L, Courtet P, Puillandre M, Paris F, Sultan C. 2019. Neurodevelopmental disorders in children exposed in utero to synthetic progestins: Analysis from the national cohort of the Hhorages Association. Gynecol Endocrinol. 35(3):247–250. 10.1080/09513590.2018.1512968 30626235
Stanczyk FZ, Hapgood JP, Winer S, Mishell DR Jr. 2013. Progestogens used in postmenopausal hormone therapy: Differences in their pharmacological properties, intracellular actions, and clinical effects. Endocr Rev. 34(2):171–208. 10.1210/er.2012-1008 23238854
Taraborrelli S. 2015. Physiology, production and action of progesterone. Acta Obstet Gynecol Scand. 94 Suppl 161:8–16. 10.1111/aogs.12771 26358238
Thomson P, Langlois VS. 2018. Developmental profiles of progesterone receptor transcripts and molecular responses to gestagen exposure during Silurana tropicalis early development. Gen Comp Endocrinol. 265:4–14. 10.1016/j.ygcen.2018.05.017 29778442
Turcu AF, Auchus RJ. 2015. The next 150 years of congenital adrenal hyperplasia. J Steroid Biochem Mol Biol. 153:63–71. 10.1016/j.jsbmb.2015.05.013 26047556
Uher J, Jirasek JE, Cernoch A. 1965. On the activity of 16-methylen-6-dehydro-17-alpha-acetoxyprogesterone (MDAP) on human foetus. Gynaecologia. 159(6):377–383. 5319574
van Marthens E, Zamenhof S, Firestone C. 1979. The effect of progesterone on fetal and placental development in normal and protein-energy-restricted rats. Nutr Metab. 23(6):438–448. 10.1159/000176290 121153
Varma TR, Morsman J. 1982. Evaluation of the use of Proluton-Depot (hydroxyprogesterone hexanoate) in early pregnancy. Int J Gynaecol Obstet. 20(1):13–17. 10.1016/0020-7292(82)90039-X 6126401
Vedel C, Larsen H, Holmskov A, Andreasen KR, Uldbjerg N, Ramb J, Bodker B, Skibsted L, Sperling L, Krebs L, 2016. Long-term effects of prenatal progesterone exposure: Neurophysiological development and hospital admissions in twins up to 8 years of age. Ultrasound Obstet Gynecol. 48(3):382–389. 10.1002/uog.15948 27106105
Vega Matuszczyk JV, Larsson K. 1995. Sexual preference and feminine and masculine sexual behavior of male rats prenatally exposed to antiandrogen or antiestrogen. Horm Behav. 29(2):191–206. 10.1006/hbeh.1995.1014 7557922
Wang T, Chen L, Yang T, Wang L, Zhao L, Zhang S, Ye Z, Chen L, Zheng Z, Qin J. 2019. Cancer risk among children conceived by fertility treatment. Int J Cancer. 144(12):3001–3013. 10.1002/ijc.32062 30548591
Ward IL. 1972. Female sexual behavior in male rats treated prenatally with an anti-androgen. Physiol Behav. 8(1):53–56. 10.1016/0031-9384(72)90129-1 4665331
Ward IL, Renz FJ. 1972. Consequences of perinatal hormone manipulation on the adult sexual behavior of female rats. J Comp Physiol Psychol. 78(3):349–355. 10.1037/h0032375 5016278
Whalen RE, Peck CK, LoPiccolo J. 1966. Virilization of female rats by prenatally administered progestin. Endocrinology. 78(5):965–970. 10.1210/endo-78-5-965 5935508
Wharton LR Jr, Scott RB. 1964. Experimental production of genital lesions with norethindrone. Obstet Gynecol. 89:701–715. 10.1016/0002-9378(64)90170-X 14198966
Wilkins L, Jones HW Jr, Holman GH, Stempfel RS Jr. 1958. Masculinization of the female fetus associated with administration of oral and intramuscular progestins during gestation: Non-adrenal female pseudohermaphrodism. J Clin Endocrinol Metab. 18(6):559–585. 10.1210/jcem-18-6-559 13539170
Witchel SF. 2017. Congenital adrenal hyperplasia. J Pediatr Adolesc Gynecol. 30(5):520–534. 10.1016/j.jpag.2017.04.001 28450075
Yovich JL, Turner SR, Draper R. 1988. Medroxyprogesterone acetate therapy in early pregnancy has no apparent fetal effects. Teratology. 38(2):135–144. 10.1002/tera.1420380206 3175947
Zaqout M, Aslem E, Abuqamar M, Abughazza O, Panzer J, De Wolf D. 2015. The impact of oral intake of dydrogesterone on fetal heart development during early pregnancy. Pediatr Cardiol. 36(7):1483–1488. 10.1007/s00246-015-1190-9 25972284
Zhang L, Chen J, Wang Y, Ren F, Yu W, Cheng L. 2009. Pregnancy outcome after levonorgestrel-only emergency contraception failure: A prospective cohort study. Hum Reprod. 24(7):1605–1611. 10.1093/humrep/dep076 19336440
Zhang L, Ye W, Yu W, Cheng L, Shen L, Yang Z. 2014. Physical and mental development of children after levonorgestrel emergency contraception exposure: A follow-up prospective cohort study. Biol Reprod. 91(1):1–7. 10.1095/biolreprod.113.117226 24899575