# Discussion

Using systematic review methodology, this scoping review characterized the available published literature on adverse health outcomes in offspring associated with progestogen exposure during pregnancy in humans and in animal models. The comprehensive literature search and screening steps focused on identifying studies reporting on congenital malformations and the health outcomes of liveborn offspring. Among the 212 studies identified as relevant, a wide range of progestogens was evaluated, including bioidentical progesterone or 1 of 23 different synthetic progestogens. The most commonly reported outcomes were growth outcomes (primarily birth weight), prematurity-related neonatal outcomes, congenital malformations, neurological outcomes, and reproductive system outcomes.

Genital malformations were the most commonly induced group of malformations associated with prenatal exposure to progestogens. Of the studies reporting first-trimester exposure in humans, significantly higher rates of genital malformations were reported for 3 of 8 studies specifically evaluating genital malformations and 2 of 20 studies evaluating any malformation (Figure 4). Higher frequencies of genital malformations were also observed in animals in 10 of 12 studies specifically evaluating genital malformations and 2 of 17 evaluating any malformation (Figure 5). The exposures eliciting greater rates of reproductive tract malformations in males in these studies included 19-nortestosterone derivatives, allylestrenol, lynestrenol, norethindrone and norethindrone acetate, and 17-alpha-acetoxyprogesterone derivative MPA; these exposures are reported to have androgen agonist activity (Schindler et al. 2008), which might compete with the endogenous androgen levels. The 17-alpha-acetoxyprogesterone derivative cyproterone acetate was also associated with reproductive malformations in male animals consistent with inhibited testosterone (e.g., presence of a vaginal anlage, prostate agenesis); this exposure is reported to have anti-androgenic activity (Schindler et al. 2008). Consistent with the congenital malformation data, these agents also feminized the AGD of male animals (i.e., cyproterone acetate) or masculinized the AGD in female animals following developmental exposure to these same synthetic progestogens (i.e., MPA or the 17-nortestosterone derivatives). Of the remaining studies on congenital malformations reporting effects, findings for the type of malformations reported were inconsistent or different results were obtained for the same exposure (Table 2) [see (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/ReadMe) Malformations-Animal (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Animal) Filter - Evidence Significance in Tableau (NTP 2020)].

Similar rates of congenital malformations were reported between control and exposed offspring following exposure during organogenesis to either 17OHPC (five human and five animal studies). First-trimester exposure to 17OHPC has been hypothesized to be without elevated risk for congenital malformations (Dudas et al. 2006; Hilgers et al. 2015) and might be a candidate for a future systematic review to evaluate a lack of effect. Progesterone exposure did not result in higher rates of congenital malformation in humans (four studies) and nonhuman mammalian animal models (five studies), but was reported to induce spinal and tail malformations in embryonic zebrafish (Silva et al. 2019) and neural tube defects when administered to chick embryos at reportedly supranormal levels (Iqbal et al. 2012; Pamir et al. 2006). Progesterone is regularly administered in the first trimester to aid in the maintenance of pregnancy in women undergoing infertility treatment and is generally accepted to have no risk of congenital malformations (Hilgers et al. 2015).

Although a large number of studies evaluated nervous system effects, relatively few studies evaluated the same exposure-outcome pair because of the large number of exposures (e.g., progesterone, 13 different synthetic progestogens) and the wide range of the neurological effects assessed (6 neurobehavioral domains and 12 morphological or functional domains) (Figure 6). Progesterone was the most commonly evaluated exposure across both human and animal studies. The reported results across the same outcome were, however, often inconsistent. For example in animal studies, whole brain (or a specific region of brain) weight was higher in some studies (Ahmad and Zamenhof 1979; Menzies et al. 1982; van Marthens et al. 1979) and unaffected in others (Coyle et al. 1976; Shaw et al. 2017; Snyder and Hull 1980). Some studies of prenatal progesterone exposure reported greater performance in the learning and cognition domain in exposed versus unexposed children (Dalton 1968; 1976), while other studies reported no difference from controls (Lynch et al. 1978; McNamara et al. 2015; Norman et al. 2016). One neurological outcome had more consistent significant findings: sexual behavior (e.g., mating behavior). Specifically, 11 of 14 animal studies reported a defeminization of mating behavior with exposure to allylestrenol (Csaba et al. 1993; Karabelyos et al. 1994a; Karabelyos et al. 1994b), cyproterone acetate (Etzel et al. 1974; Perakis and Stylianopoulou 1986; Vega Matuszczyk and Larsson 1995; Ward 1972; Ward and Renz 1972), or progesterone (Hull et al. 1980; Pointis et al. 1987; Regestein et al. 1975). Cyproterone acetate is used to treat hypersexuality in men, consistent with the effects reported in animal studies. Cyproterone acetate is administered to women as a combination estrogen/progestogen treatment for severe acne and hirsutism in women and is contraindicated for use during pregnancy. Several studies, mainly published in the 1970s and 1980s, evaluated the influence of progestogens on sexual behavior and sexually dimorphic behavior with inconsistent findings (Table 3).

Although many studies reported on growth and prematurity-related neonatal health outcomes for human infants, preterm birth was not commonly observed in unhandled laboratory animals. Thus, no studies reported on neonatal health outcomes in animal studies related to prematurity. In addition, the current scoping review did not include animal models of preterm birth because the models required additional exposures or physical manipulation to induce the condition (Elovitz and Mrinalini 2006). As stated in the methods, studies reporting premature birth were not included in the scoping review because threatened premature birth or the prevention thereof was the predominant reason for the administration of progestogens. Mortality (e.g., miscarriage and stillbirth) was not assessed in the current scoping review because it was often the reason for administration of drug and the focus of the current review was on liveborn offspring.

## Limitations of the Evidence

Precise drug nomenclature is a major challenge in characterizing the literature available on the potential adverse health effects associated with the progestogens (Hilgers et al. 2015; Keith and Berger 1977; Romero and Stanczyk 2013). For example, the term progestin is defined as synthetic progestogens in some research groups (Stanczyk et al. 2013), whereas others have used the term progestin to refer to both the bioidentical progesterone and the synthetic progestogens (Carmichael et al. 2005; Heinonen et al. 1977; Li et al. 2018). In addition, some authors use the abbreviations of endogenous progestogens to refer to synthetic progestogen; for example, the abbreviation for the endogenous hormone 17-alpha-hydroxyprogesterone is 17P, but this abbreviation has often been used to refer to the synthetic progestogen 17-alpha-hydroxyprogesterone caproate [reviewed in Romero (2013)]. For the purposes of this scoping review, the bioidentical (plant-based) progesterone drugs were referred to as progesterone, synthetic progestogens as synthetic progestogens, and progestogens as the general category for both bioidentical progesterone and synthetic progestogens.

One reason imprecision in the nomenclature is a challenge is that progesterone and the individual synthetic progestogens each have different biological properties (Hapgood et al. 2014; Schindler et al. 2008). Thus, for the 24 progestogens identified in the scoping efforts, the evidence base is smaller for any given progestogen due to their unique bioactivities. The common feature of the progestogens is that they all bind to the progesterone receptor to initiate development of the endometrial lining of the uterus to maintain a pregnancy, although they bind to the progesterone receptor with different relative binding affinities. Some synthetic progestogens also act as androgen agonists (e.g., many of the 19-nortestosterone derivatives like norethindrone and levonorgestrel), although the literature is inconsistent on progesterone. Other synthetic progestogens appear to have anti-androgenic properties (e.g., the pregnane derivatives such as cyproterone acetate, the spironolactone derivative drospirenone), although progesterone appears to be weakly anti-androgenic. Finally, a few synthetic progestogens are reported to act as glucocorticoid agonists (e.g., gestodene, drospirenone) or mineralocorticoid receptor antagonists (drospirenone), although the activity of progesterone on these receptors is inconclusive.

Many early reports of congenital malformations were associated with combined exposure to progestogens and estrogens [reviewed in Ferencz (1980) and Keith (1977)]. Determining the association of progestogens with an adverse health effect in some studies is not possible because individual progesterone or synthetic progestogen exposure is added to a general category called female hormones that includes combination drugs with progestogen and estrogen (Ferencz et al. 1980; Hadjigeorgiou et al. 1982; Nora and Nora 1975).

## Limitations of the Scoping Review

Several limitations of the data hampered their utility to assess the association between progestogens with select adverse health outcomes:

- The current scoping review excluded an important population exposed to progestogens during pregnancy: offspring conceived with assisted reproductive technology. Many studies reporting on pregnancy outcomes and health of offspring conceived by assisted reproductive technologies do not detail the hormonal regimen followed, which made it challenging to identify relevant progestogen exposures, or the studies report limited information on the health of the offspring. Also, most treatments in assisted reproductive technology involve combinations of gonadotropins and steroid hormone drugs as well as physical manipulation of the gametes/embryo, which makes attributing an effect to progestogens alone difficult. The literature base evaluating the health of offspring conceived with assisted reproductive technologies is increasing, and systematic reviews and meta-analyses have been published in recent years on a number of health outcomes [e.g., adverse pregnancy outcomes (Qin et al. 2016); cancer (Wang et al. 2019); cardiovascular and metabolic profiles (Guo et al. 2017); genitourinary malformations (Massaro et al. 2015)].
- Studies exposing farm animals (livestock) to progestogens were also excluded from this scoping review as they often reported on methods of assisted reproduction or were investigating the role of endogenous progesterone on pregnancy through hormonal and often surgical manipulation of pregnancy. In addition, these studies frequently had limited information on the outcome of the exposed offspring as the studies were focused on maintenance of pregnancy. A more refined literature search targeting mechanistic studies of progesterone might identify relevant studies in this literature base.
- The current scoping review did not exclude studies with co-exposure to tocolytics and associated drugs used during pregnancy or delivery. A subsequent systematic review might consider conducting a sensitivity analysis without offspring from pregnancies at high risk of preterm birth, to minimize the potential adverse health effects of co-exposures on the offspring.
- The current scoping review included only studies with exposure during pregnancy, yet some offspring in animal models are born precociously (e.g., mice and rats). Thus, the current scoping review could have missed some relevant animal studies of nervous system development, which are relevant to the period of in utero brain development in humans (Howdeshell 2002; Rice and Barone 2000).
- The literature search strategy was not sensitive to identifying in vitro or mechanistic studies with progestogen exposure relevant to miscarriage or preterm birth. Future scoping efforts or systematic reviews could be tailored to search for in vitro models or mechanistic targets for pregnancy outcomes and other adverse health outcomes in offspring, of interest.
- The current scoping review focused only on two databases (PubMed and Cochrane Reviews), which likely identified most but not all the relevant literature on the topic. In contrast, a systematic review evaluation would use multiple databases, perform snowballing (i.e., reviewing the reference lists of relevant studies and reviews to retrieve additional relevant papers), and conduct a risk-of-bias assessment of the quality of the literature to inform level of evidence conclusions on the body of evidence.

## Research Needs

The scoping review identified several areas of research needed to address gaps in our knowledge of possible health effects associated with prenatal exposure to progestogens in humans, including neurobehavioral outcomes and cancer.

Relatively few studies evaluate the incidence of congenital malformations following first-trimester exposure to progestogen medication intended for use during pregnancy to ensure it is safe for both women and their fetuses.

Longer-term follow-up health evaluations of offspring prenatally exposed to progestogens are needed. For example, the few available studies of long-term evaluations of neurological outcomes associated with prenatal progestogen exposure only examined children up to age 60 months (Vedel et al. 2016). Similarly, very few studies have evaluated the association between cancer incidence in adulthood following prenatal exposure to progestogens. Progesterone was identified by the National Toxicology Program’s Report on Carcinogens as reasonably anticipated to be a human carcinogen in accordance with evidence from experimental animal studies observing cancers of the breast, ovary, and uterus following postnatal exposure to progesterone (NTP 2016); however, human data are not conclusive (IARC 1974; IARC 1979; IARC 1982). Early neonatal exposure to progesterone was reported to induce tumors of the mammary glands, vagina, and cervix in female rats (IARC 1974; IARC 1979; IARC 1982); however, information is lacking on cancer incidence in experimental animals following prenatal exposure. Even less information is available about synthetic progestogens.

As more literature on this topic is available, systematic reviews are needed that evaluate a specific progestogen (bioidentical progesterone or an individual synthetic progestogen) or class of synthetic progestogen (19-nortestosterone derivatives) to better understand the association between prenatal exposure to specific groups or individual progestogens.

On a related topic not covered in this evaluation, increased understanding is needed of the effects of early postnatal exposure to progestogens on the developing brain. Bioidentical progesterone is currently being explored as a neuroprotective treatment to reduce the effects of hypoxia and excitotoxic brain damage for preterm infants (Plunchino et al. 2016).

## Summary

This scoping review identified and characterized a limited body of evidence on potential adverse health effects associated with exposure to progestogens during in utero development. The evidence was inadequate to recommend an evaluation of these potential health effects in a systematic review due to heterogeneity of the endpoints evaluated per health outcome and inconsistencies in the results. Also, the wide variety of synthetic progestogens administered and their biological properties unique from bioidentical progesterone limit the ability to assess the health effects of a general category of progestogens (bioidentical progesterone and synthetic progestogens) or synthetic progestogens. More research is needed to better understand the potential association between prenatal exposure to progestogens with adverse pregnancy outcomes, congenital malformation incidence, and longer-term health outcomes of prenatally exposed offspring.