# Results

## Study Selection Results

The screening results and reasons for exclusion are outlined in the study selection diagram (Figure 1). The electronic database searches retrieved 7,729 individual references. After duplicate removal, 7,650 unique references were screened for relevance and eligibility in the title-and-abstract screen using text-mining software. Of these references, 4,292 references were manually screened to achieve >95% recall on the basis of predicted relevance and 3,358 references were not screened (and assumed to be not relevant) as determined by the machine-learning algorithm. At the title-and-abstract level, 3,220 references were excluded manually because they were not relevant to the PECO criteria, did not contain original data, or were not written in English. In the title-and-abstract screening, 1,072 references were identified as potentially relevant to exposure to progestogens during pregnancy and were then reviewed in the full-text screen. After full-text review, 858 references were excluded and 212 studies were considered relevant, of which 123 were human studies and 90 were animal studies, including one study that evaluated both human and animal subjects (Li et al. 2018). No in vitro or mechanistic studies relevant to embryonic or fetal exposure were identified by the literature screening. Three relevant studies (Coomarasamy et al. 2016 Norman et al. 2018; Reinisch and Karow 1977) reporting on human subjects were excluded because the publications included data presented in more detail in a subsequent publication (Reinisch 1977) or were peer-reviewed government reports of data previously reported in journal publications (Coomarasamy et al. 2015; Norman et al. 2016). Some references excluded from the current scoping review were identified as potentially relevant to future research or systematic reviews on prenatal exposure to progestogens associated with pregnancy outcomes and offspring health; the references are collated in the interactive Tableau file [see Relevant Literature (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/RelevantLiterature) tab in Tableau; (NTP 2020)]. The potentially relevant reference categories included: meta-analyses and systematic reviews, narrative reviews, protocols or program descriptions, case report or case series, and original research studies of assisted reproductive technologies or livestock studies.

Figure 1

Study Selection Diagram

The number of relevant studies identified was 212, including 123 human studies and 90 animal studies, including one study reporting on both human and animal subjects (Li et al. 2018).

The reported data of the 212 relevant health outcome studies were mapped by exposure, evidence stream (e.g., human, animal), and outcome measured [see All Outcomes (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/AllOutcomes) tab in Tableau; (NTP 2020)]. The studies reported on bioidentical progesterone, 23 individual synthetic progestogens, and two general categories of exposures: synthetic progestogens (i.e., exposure to one of many synthetic progestogens) progestogens (i.e., offspring exposed to either bioidentical progesterone or synthetic progestogens) (Figure 2). The most frequently reported exposures were bioidentical progesterone (86 studies), 17-alpha-hydroxyprogesterone caproate (17OHPC; 47 studies), and medroxyprogesterone acetate (MPA; 26 studies). More individual synthetic exposures were evaluated in animal studies (21 drugs) than were in human studies (9 drugs).

Figure 2

Number of Studies Evaluating the Association between Prenatal Exposure to Progestogens and Adverse Health Outcomes

17OHPC = 17-alpha-hydroxyprogesterone caproate; MDAP = 16-methlyene-6-dehydro-17-alpha-acetoxyprogesterone; MPA = medroxyprogesterone acetate.

Progestogen indicates exposure to (bioidentical) progesterone or synthetic progestogen evaluated as a general category of exposure. Numbers in the grand total row and column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available (i.e., darker shading indicates more studies, lighter shading indicates fewer studies, and a white space with no number indicates no studies identified). Interactive figure with study details are available on the Tableau All Outcomes (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/AllOutcomes) tab (NTP 2020). In the interactive figure, the health outcomes can be expanded to view the number of studies per evidence stream (i.e., human or animal).

Among the human studies identified as relevant, the predominant indication for progestogen administration was the treatment (or prevention) of preterm birth or the treatment (or prevention) of miscarriage (79 studies; 64% of human studies). Twenty-five human studies did not state the reason for drug administration to the mother, and four studies evaluated the health of offspring born to a group of women treated for different individual health conditions. Other reasons these drugs were administered to women included contraception, preeclampsia, or preterm premature rupture of membranes.

The literature search strategy was tailored to retrieve adverse health outcomes in offspring prenatally exposed to progestogens informed by the results of a preliminary literature search. As expected, most of the relevant studies were related to growth (109 studies; predominantly measurements of birth weight), congenital malformations (80 studies), neurological outcomes (61 studies), adverse neonatal health outcomes related to prematurity (referred to as prematurity-related neonatal outcomes; 48 studies), and reproductive effects (30 studies) (Figure 2). Thirty-two studies (30 animal and 2 human studies) evaluated health effects related to the endocrine system, including primarily sex hormone-related endpoints (e.g., levels of hormones, receptors, steroidogenic enzymes) [see[underlined: Endocrine] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Endocrine) tab in Tableau; (NTP 2020)]. Other health outcomes were evaluated in five or fewer studies, including cancer incidence in adults following developmental exposure [see [underlined: Other Outcomes] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/OtherOutcomes) tab in Tableau; (NTP 2020)].

The sections that follow further describe the health outcome categories with 30 or more studies and provide additional study details for congenital malformations and neurological outcomes.

## Growth and Prematurity-related Neonatal Outcomes

### Human Studies

Growth was the most frequently measured outcome (76 studies) in offspring prenatally exposed to progestogens [see Growth (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Growth) tab in Tableau; (NTP 2020)]. Most of these studies tested the efficacy of bioidentical progesterone or 17OHPC for treating or preventing preterm birth, thus treatment occurred primarily in the second and third trimesters of pregnancy (data not shown). Birth weight was the most frequently reported growth outcome in humans (71 studies) and was measured in a variety of ways, including continuous measures (grams body weight), intrauterine growth restriction, low birth weight, very low birth weight, high birth weight, small for gestational age, and large for gestational age. Only six studies reported on infant and child growth endpoints in follow-up evaluations of prenatally exposed offspring (Jaffe et al. 1990; McNamara et al. 2015; Norman et al. 2016; Northern et al. 2007; Pardthaisong et al. 1992; Zhang et al. 2014). Most studies of growth outcomes reported no association with prenatal exposure to progestogens [see Growth (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Growth) tab in Tableau, Filter - Evidence type: Human, Filter - Evidence Significance (NTP 2020); see studies reporting significant findings for direction of effect].

Adverse neonatal health outcomes reported in the literature base were predominantly related to health conditions reported for premature infants. Thus, the scoping review categorized individual adverse neonatal health outcomes identified by the U.S. Institute of Medicine as outcomes commonly observed in premature infants (IOM 2007). These outcomes included apnea/bradycardia, bronchopulmonary dysplasia (also called chronic lung disease), respiratory distress syndrome, pneumothorax, pneumonia, patent ductus arteriosus, intraventricular hemorrhage, periventricular leukomalacia, retinopathy of prematurity, necrotizing enterocolitis, sepsis, hypoglycemia, and hyperbilirubinemia. In the 48 studies reporting on prematurity-related neonatal outcomes, respiratory distress syndrome, necrotizing enterocolitis, and intraventricular hemorrhage were the most frequently evaluated (Figure 3). Most studies of prematurity-related neonatal outcomes reported no association with prenatal exposure to progestogen [see Prematurity-related (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Prematurity-Related) tab in Tableau, Filter - Evidence Significance (NTP 2020); see studies reporting significant findings for direction of effect].

Figure 3

Number of Studies Evaluating the Association between Prenatal Exposure to Progestogens and Adverse Neonatal Outcomes in Humans Associated with Prematurity

17OHPC = 17-alpha-hydroxyprogesterone caproate.

Numbers in the grand total row and column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available (i.e., darker shading indicates more studies, lighter shading indicates fewer studies, and a white space and no number indicates no studies identified). Interactive figure with study details available at Tableau Prematurity-related (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Prematurity-Related) tab (NTP 2020).

### Animal Studies

Growth outcomes evaluated in animal studies (32 studies) were predominantly fetal weight or birth weight. Most studies reporting on growth reported no effect of prenatal progestogen exposure [see Growth (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/RelevantLiterature) tab in Tableau, Filter - Evidence type: Animal, Filter - Evidence Significance (NTP 2020); see studies reporting significant findings for direction of effect]. No animal studies were identified as relevant to prematurity-related neonatal outcomes following prenatal exposure to progestogens.

## Congenital Malformations

### Human Studies

The scoping review identified 48 studies evaluating an association between congenital malformations and prenatal exposure to progestogens in humans. The critical period of organogenesis in humans occurs during the first trimester [from approximately 3 to 12 weeks gestation (Moore et al. 2016)] and is particularly sensitive to chemical exposure (Shepard and Lemire 2004). Of the 48 studies, 32 evaluated the incidence of congenital malformations during the first trimester, including exposure to bioidentical progesterone, 1 of 9 different synthetic progestogens, or the general categories of synthetic progestogen or progestogen (bioidentical progesterone or synthetic progestogen) [Figure 4; see Malformations-Human (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Human) tab, Filter - Exposure Timing in Tableau: select all categories with first trimester; (NTP 2020)]. Twenty studies measured any congenital malformation and 13 studies evaluated specific types of congenital malformations. The most frequently evaluated category of specific malformations was genital organ malformations (seven studies total).

Figure 4

Number of Studies Evaluating the Association between Progestogen Exposure in the First Trimester of Pregnancy and Congenital Malformations in Humans

17OHPC = 17-alpha-hydroxyprogesterone caproate; MDAP = 16-methlyene-6-dehydro-17-alpha-acetoxyprogesterone; MPA = medroxyprogesterone acetate.

Progestogen indicates exposure to (bioidentical) progesterone or synthetic progestogen evaluated as a general category of exposure. Numbers in the grand total row and column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available (i.e., darker shading indicates more studies, lighter shading indicates fewer studies, and a white space with no number indicates no studies available). Interactive figure available at the Tableau Malformations-Human (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Human) tab; Filter - Exposure Timing and select all exposures that include first trimester (NTP 2020). To view the specific malformations evaluated, expand the Malformation Category column in the interactive Tableau figure (NTP 2020). To identify studies reporting significant effects, click “significant” in the Filter - Effect Significance in Tableau (NTP 2020). To identify studies that did not report statistical analyses, click “not reported” in the Filter - Effect Significance in Tableau (NTP 2020).

Significant findings for congenital malformations were reported in 10 studies reporting first-trimester exposure to progestogens, including 3 studies evaluating any malformation (Colvin et al. 2010; Czeizel and Huiskes 1988; Hemminki et al. 1999) and 7 studies evaluating specific malformations (Calzolari et al. 1986; Carmichael et al. 2005; Corona-Rivera et al. 2018; Heinonen et al. 1977; Lammer and Cordero 1986; Mavrogenis et al. 2014; Zaqout et al. 2015) (Table 2). Two studies reported that the overall incidence of any congenital malformation was significantly higher following prenatal exposure to MPA (Colvin et al. 2010) or to the general category of progestogen (Colvin et al. 2010; Hemminki et al. 1999). The incidence of hypospadias, a genital organ malformation in which the opening of the penis is incorrectly positioned, was significantly greater in five studies; the exposures included allylestrenol (Czeizel and Huiskes 1988), lynestrenol (Mavrogenis et al. 2014), MPA (Colvin et al. 2010), and the general category of progestogen (Calzolari et al. 1986; Carmichael et al. 2005). A higher risk of cardiovascular defects was reported in three studies following exposure to dydrogesterone (Zaqout et al. 2015), MPA (Colvin et al. 2010), or the general category of progestogen (Heinonen et al. 1977). One study each reported a higher incidence of cleft lip with or without cleft palate (Corona-Rivera et al. 2018) and esophageal atresia (Lammer and Cordero 1986). Of note, an absence of congenital malformations was reported in six human studies evaluating first-trimester exposure to bioidentical progesterone (Coomarasamy et al. 2019; Coomarasamy et al. 2015; Gerhard et al. 1987; Hilgers et al. 2015; Keppler-Noreuil et al. 2017; Mavrogenis et al. 2014). Similarly, no significant association was reported for first-trimester exposure to 17OHPC and congenital malformations (five studies) (Table 2) (Dudas et al. 2006; Mavrogenis et al. 2014; Michaelis et al. 1983; Resseguie et al. 1985; Varma and Morsman 1982).

Table 2 Summary of Studies Evaluating the Association of Congenital Malformations in Humans Following Exposure to Progestogens in the First Trimester of Pregnancy

Exposure | Study Design (Location) [n] | Exposure Details | Congenital Malformation Measured | Results | Study
17OHPC | Case-control (Hungary) [22,843 cases, 38,151 controls] | 250 mg, im injection | Any | No statistically significant difference in the prevalence of any congenital malformation in the offspring exposed to 17OHPC in gestational months 2 and 3 compared to matched controls (adjusted pOR = 1.2, 95% CI = 0.9–1.6). | Dudas et al. (2006)
| Prospective cohort (Germany) [186 progesterone exposed; 462 17OHPC exposed; 648 matched unexposed] | Not reported | Any | No increased risk for any congenital malformation in the 17OHPC exposed cohort compared to matched controls (OR = 0.66, 95% CI = 0.17–2.30). | Michaelis et al. (1983)
| Retrospective cohort (United States) [988 exposed offspring; 988 matched controls] | 125–11,250 mg total dose, route not reported | Any | No association of congenital malformation with exposure to 17OHPC (HR not reported). Nonsignificant higher frequency of abnormal testes (primarily undescended testes) in 17OHPC exposed cohort compared to controls. | Resseguie et al. (1985)^a^
| Retrospective cohort (England) [150 exposed, 150 control pregnancies] | 250–500 mg, im injection weekly | Any | No incidence of masculinization observed in liveborn female infants or female fetuses aborted before the 28th week of gestation in the 17OHPC exposed or control cohorts. | Varma and Morsman (1982)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | No statistically significant difference in odds of hypospadias in offspring exposed to 17OHPC during the critical period of development for hypospadias (7–16 weeks of gestation) compared to matched controls (similar rate of 0.7% reported for study groups; OR not reported). | Mavrogenis et al. (2014)
Allylestrenol | Case-control (Hungary) [7,686 congenital anomaly cases; 221 Down syndrome cases; 10,962 controls] | Not reported | Any | Significant difference (p < 0.05 by McNemar analysis) in the incidence rate of hypospadias of offspring exposed to allylestrenol during the second and third month of pregnancy (3–10 weeks of gestation), but not in the fourth month of pregnancy (11–14 weeks gestation), when compared to matched controls: the critical period of development for hypospadias (5–14 weeks of gestation). | Czeizel and Huiskes (1988)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | Positive association between isolated hypospadias in male infants and exposure to allylestrenol (specifically, medically recorded treatments) during the critical period of development for hypospadias (7–16 weeks of gestation) compared to population controls (adjusted OR = 1.55, 95% CI = 1.10–1.91) or matched controls (adjusted OR = 1.46, 95% CI = 1.09–1.39). Association disappeared when restricted to medically recorded allylestrenol treatments. | Mavrogenis et al. (2014)
Dydrogesterone | Randomized controlled trial (Jordan) [82 exposed, 48 controls] | 10 mg, orally twice daily | Any | No statistically significant difference in the incidence of any congenital malformation in offspring exposed to dydrogesterone (n = 2, 2.8%) compared to controls (n = 1, 2.9%). | El-Zibdeh (2005)
| Randomized controlled trial (Malaysia) [96 exposed pregnancies, 95 unexposed pregnancies] | 40 mg stat followed by 10 mg, twice daily | Any | No congenital malformations reported in offspring exposed to dydrogesterone or in controls. | Pandian (2009)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | No statistically significant difference in odds of hypospadias in offspring exposed to dydrogesterone in the first or second gestational months compared to population controls (adjusted OR = 1.11, 95% CI = 0.33–3.72) or matched controls (adjusted OR = 0.78, 95% CI = 0.22–2.72). | Mavrogenis et al. (2014)^a^
| Case-control (Palestine) [202 cases, 200 controls] | 10 mg, orally twice daily | Congenital heart defects | Positive association between congenital heart defects in offspring and maternal usage of dydrogesterone during first trimester of pregnancy (adjusted OR = 2.71; 95% CI = 1.64–4.24). | Zaqout et al. (2015)
Ethynodiol Diacetate | Case-control (Hungary) [537 cases; 537 controls] | Not reported | Congenital limb reduction | Higher, but not statistically significant (p = 0.06), use of ethynodiol diacetate during pregnancy in cases with a terminal transverse defect. | Czeizel and Kodaj (1995)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | No difference in odds of hypospadias in offspring exposed to ethynodiol diacetate in the first or second gestational months compared to population controls (adjusted OR = 0.94, 95% CI = 0.29–3.12) or matched controls (adjusted OR = 1.22, 95% CI = 0.33–4.50). | Mavrogenis et al. (2014)^a^
Levonorgestrel | Retrospective cohort (Italy) [25 exposed, 80 controls] | 0.75 mg, orally twice daily or 1.5 mg, orally once daily | Any | No statistically significant difference in the rate of congenital malformations in offspring exposed to levonorgestrel (n = 1, 4.0%) compared to controls (n = 1, 1.4%). | De Santis et al. (2005)
| Prospective cohort (China) [332 treated pregnant women (272 infants); 332 untreated controls (298 infants)] | ≤1.5 mg (90.1% of cohort) or >1.5 mg (9.9% of cohort), orally | Any | No statistically higher incidence of congenital malformations in offspring exposed to levonorgestrel (n = 4, 1.5%) compared to controls (n = 4, 1.3%). | Zhang et al. (2009)
| Case-control (Hungary) [537 cases; 537 controls] | Not reported | Congenital limb reduction | No higher risk of congenital limb reductions in offspring exposed to levonorgestrel (also called D-norgestrel) compared to controls. | Czeizel and Kodaj (1995)
Lynestrenol | Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | Significantly higher odds of isolated hypospadias in offspring exposed to lynestrenol during the first and second gestational month compared to population control (adjusted OR = 26.66, 95% CI = 8.69–81.80) or matched controls (adjusted OR = 47.68, 95% CI 6.23–364.64). | Mavrogenis et al. (2014)^a^
MDAP | Prospective cohort (Czech Republic) [5 exposed, 10 unexposed fetuses] | 10 mg, orally daily | Genital organ malformations | No deviations in the development of the external genitalia observed in male or female fetuses exposed to MDAP compared to control fetuses. No statistical analysis conducted. | Uher et al. (1965)
MPA | Retrospective cohort (Western Australia) [106,074 births] | Not reported | Any | Higher odds of any malformations (OR = 1.8, 95% CI = 1.4–2.3), hypospadias (in male infants) (OR = 2.7; 95% CI = 1.3–5.8), cardiovascular malformations (OR = 1.9, 95% CI 1.1–3.1), gastrointestinal malformations (OR = 2.3, 95% CI = 1.2–4.2), congenital malformations of the integument (OR = 2.6, 95% CI = 1.1–5.8), and chromosome anomalies (OR = 3.3, 95% CI = 1.5–7.4) in exposed infants versus controls. | Colvin et al. (2010)
| Prospective cohort (Thailand) [1,229 exposed women; 4,023 unexposed women] | 150 mg, im injection every 3 months or 450 mg, im injection every 6 months | Any | Significantly higher rates of any congenital malformations in offspring exposed to MPA compared to nonusers (RR = 1.7), due to higher rates of limb malformations (i.e., polysyndactyly) and chromosome anomalies. | Pardthaisong et al. (1988))
| Prospective cohort (Australia) [pregnancies of 508 exposed, 508 matched controls] | 80 or 120 mg, oral capsule daily | Any | No statistically significant difference in incidence of congenital malformations in offspring exposed to MPA (4.1%) compared to matched controls (3.5%). | Yovich et al. (1988)
| Prospective cohort study (Israel) [74 exposed boys, 385 control boys] | 150 mg, injection daily or ≥1 mg, oral tablet daily | Undescended testes and inguinal hernia^b^ | Higher, nonstatistically significant, incidence of inguinal hernia (p = 0.20) and undescended left (p = 0.14) or right testicles (p = 0.11) in male offspring exposed to MPA compared to controls. | Jaffe et al. (1990)
Norethindrone | Retrospective cohort (Western Australia) [106,074 births] | Not reported | Any | No statistically significant difference in odds of any congenital malformation in offspring exposed to norethindrone compared to controls (OR = 2.2, 95% CI = 0.3–17.8). | Colvin et al. (2010)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | No statistically significant difference in odds of hypospadias in offspring exposed to norethindrone during the first and second gestational month compared to population controls (adjusted OR = 0.93, 95% CI = 0.33–2.63) or matched controls (adjusted OR = 3.66, 95% CI = 0.91–14.63). | Mavrogenis et al. (2014)^a^
Progesterone | Randomized controlled trial (United Kingdom and The Netherlands) [266 exposed, 276 control neonates] | 400 mg, vaginal pessary daily | Any | Relative risk for genital anomalies was higher, but not statistically significant (RR = 1.04, 95% CI = 0.07–16.50), in the offspring exposed to progesterone versus controls. The risk of total congenital anomalies was similar between the two groups (RR = 0.75, 95% CI = 0.31–1.85). | Coomarasamy et al. (2015)
| Randomized controlled trial (United Kingdom) [2,025 exposed, 2,013 controls] | 400 mg, vaginal pessary twice daily | Any | No statistically significant difference in the risk of congenital malformations in exposed (n = 53, 1.1%) versus control infants (RR = 1.0, 95% CI = 0.69–1.47). | Coomarasamy et al. (2019)
| Randomized controlled trial (Germany) [27 exposed, 29 controls] | 25 mg, vaginal pessary twice daily | Any | No congenital malformations or virilization were observed in offspring exposed to progesterone compared to controls. | Gerhard et al. (1987)
| Retrospective cohort study (United States) [1,310 exposed; 453 unexposed] | | Any | No statistically significant difference in the incidence of any congenital malformation in offspring exposed to progesterone (n = 10; 2.2%) compared to controls (n = 29; 2.2%). | Hilgers et al. (2015)
| Case-control (Hungary) [3,038 cases with isolated hypospadias; 24,814 population male controls with no defects; 11,096 malformed male controls with another isolated defect] | Not reported | Hypospadias | No statistically significant difference in odds of hypospadias in offspring exposed to progesterone during the first and second gestational month compared to positive controls (adjusted OR = 1.89, 95% CI = 0.54–6.62) or matched controls (adjusted OR = 1.57, 95% CI = 0.40–6.06). | Mavrogenis et al. (2014)^a^
| Case-control (United States) [101 cases, 11,829 controls] | Not reported | Cloacal malformations^c^ | No statistically significant difference in odds of any cloacal malformation in offspring exposed to progesterone compared to controls following adjustment for child plurality and maternal age at delivery (adjusted OR = 1.9, 95% CI = 0.8–4.5). | Keppler-Noreuil et al. (2017)
Synthetic Progestogen | Prospective cohort study (Israel) [1,608 exposed, 1,146 controls] | 20 or 30 mg, im injection daily (MPA) and/or 500 mg, im injection weekly (17OHPC) | Any | No statistically significant difference in incidence of any congenital malformation in offspring exposed to synthetic progestogens (specifically, 17OHPC or MPA) compared to controls. | Katz et al. (1985)
Progestogen^c^ | Case-control (United States) [113 cases, 226 medical practice controls, 226 birth certificate controls] | Not reported | Undescended testes | No statistically significantly difference in odds of undescended testes in offspring exposed to synthetic progestogen as compared to either the medical practice control group I (adjusted RR = 0.9, 95% CI = 0.3–3.3), or the birth certificate control group II (adjusted RR = 0.7, 95% CI = 0.2–2.3). | Beard et al. (1984)^a^
| Case-control (Italy) [168 cases, 378 controls] | Not reported | Hypospadias | Significantly higher number of hypospadias cases were exposed to synthetic progestogen compared to controls (Χ^2^ = 5.68, df = 1, p < 0.05). | Calzolari et al. (1986)^a^
| Case-control (United States) [502 cases, 1,286 controls] | Not reported | Hypospadias | Higher odds of progestogen exposure in hypospadias cases compared to controls. 42 case mothers (8.4%) and 31 control mothers (2.4%) reported any pregnancy-related progestogen intake from 4 weeks before through 14 weeks after conception (OR = 3.7, 95% CI = 2.3–6.0). | Carmichael et al. (2005)
| Case-control (Mexico) [105 cases, 315 controls] | Not reported | Cleft lip with or without cleft palate | Higher odds of first-trimester exposure to progestogen in cases with nonsyndromic cleft lip with or without cleft palate versus controls (adjusted OR = 6.8, 95% CI = 1.8–25.3). | Corona-Rivera et al. (2018)
| Retrospective cohort study (Finland) [1,484 exposed, 1,601 control offspring] | Not reported | Any | Significantly higher (p < 0.001) incidence of congenital malformations (major and minor) in offspring exposed to progestogen compared to controls, but no difference in the incidence of major congenital malformations, male genital organ malformations, or related reproductive or urinary system anomalies. | Hemminki et al. (1999)
| Prospective cohort (Egypt) [1,000 newborns total, 99 exposed] | Not reported | Genital organ malformations | No statistically significant difference in the incidence of genital anomalies in male neonates exposed to synthetic progestogens (2%) compared to controls (1.8%). | El Kholy et al. (2013)
| Retrospective cohort and nested case-control (Japan) [667 embryos with maternal genital bleeding: 130 exposed to hormone therapy, 537 unexposed; Nested case-control: 90 embryos with polydactyly and 38 with limb reductions matched 1:1 to controls (normal embryos)] | 15–125 mg daily, route not reported | Any | Higher, but not statistically significant different, frequency of major malformations in embryos with progestogen exposure (19.2%) compared to matched control embryos (14.4%) (X^2^ = 1.03, p > 0.2). The authors considered the association of progestogens with malformations secondary to genital bleeding (the indication for treatment with progestogens). | Matsunaga and Shiota (1979)
| Retrospective cohort (United States) [988 exposed offspring, 988 matched controls] | Not reported | Any | No statistically significant difference in the hazard ratio for any congenital malformation in offspring exposed to any progestogen exposure compared to matched controls [hazard ratio not reported]. | Resseguie et al. (1985)^a^
| Prospective cohort (United States) [50,282 total, 1042 exposed] | Not reported | Circulatory system malformations | Higher risk of cardiovascular malformations in progestogen in exposed versus control offspring (adjusted RR = 1.5). | Heinonen et al. (1977)
| Case-control (United States) [1,091 cases, 1,055 controls (Note: for each malformation, infants with other malformations served as control)] | Not reported | 11 non-genital organ malformations | Higher odds of esophageal atresia and maternal exposure to progestogen versus controls (OR = 2.87, 95% CI = 1.16–7.12); most cases were exposed to a progestogen hormonal pregnancy test (OR = 3.0, 95% CI = 1.07–8.46). No greater odds of progestogen exposure observed for any other congenital malformations evaluated, including anencephaly, spina bifida, encephalocele, Down syndrome, anterior abdominal wall defect, diaphragmatic hernia, small bowel atresia, and rectal anal atresia, limb reduction, and cleft lip ± palate, cleft palate. | Lammer and Cordero (1986))

17OHPC = 17-alpha-hydroxyprogesterone acetate; CI = confidence interval; df = degrees of freedom; HR = hazard ratio; im = intramuscular injection; MPA = medroxyprogesterone acetate; MDAP = 16-methlyene-6-dehydro-17-alpha-acetoxyprogesterone; OR = odds ratio; RR = relative risk; X^2^ = chi-squared test.

^a^ Study identified exposure as during pregnancy, but was inferred to include the first trimester because progestogens were administered to women for threatened abortion or a history of threatened abortion (Beard et al. 1984; Calzolari et al. 1986); in case of (Resseguie et al. 1985), 75% of offspring were exposed to progestogen in the first trimester.

^b^ Study evaluated cloacal exstrophy and persistent cloaca (also called urorectal septum malformation sequence); these malformations include anorectal malformations that might also involve colon, bladder, gastrointestinal, skeletal, spinal, and genitourinary systems.

^c^ Progestogen indicates exposure to (bioidentical) progesterone or synthetic progestogen evaluated as a general category of exposure. Note: First trimester of pregnancy is the first 13 weeks of gestation (weeks since last menstrual period).

Studies reporting timing of exposure other than during first trimester were considered less informative of the association between progestogens and congenital malformations [see [underlined: Malformations-Human] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Human)[underlined: ,] Filter - Exposure Timing in Tableau (NTP 2020)]. Eight studies reported exposure only as during pregnancy, which might or might not have included exposure during the first trimester. The studies reporting exposure only during the second and/or third trimester would have been less likely to detect malformations because exposure did not encompass the period of organogenesis.

### Animal Studies

The available literature on congenital malformations included 32 studies in laboratory animals (Figure 5). Most of the studies used rats or mice, although a wide range of animal models were tested (e.g., primates, fish). Cyproterone and progesterone were the most commonly evaluated gestational exposures among the animal studies. Most animal studies evaluated the incidence of any congenital malformation (15 studies), while 14 studies specifically evaluated the incidence of genital organ malformations and 2 studies specifically evaluated neural tube defects. Ten of these studies were descriptive in nature and did not include statistical analysis (Foote et al. 1968; Forsberg and Jacobsohn 1969; Forsberg et al. 1968; Johnstone and Franklin 1964; Pamir et al. 2006; Prahalada et al. 1985b; Vega Matuszczyk and Larsson 1995; Ward and Renz 1972; Whalen et al. 1966; Wharton and Scott 1964).

Figure 5

Number of Studies Evaluating the Association between Prenatal Exposure to Progestogens and Congenital Malformations in Animal Models

17OHPC = 17-alpha-hydroxyprogesterone caproate; MPA = medroxyprogesterone acetate.

Numbers in the grand total row or column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available (i.e., darker shading indicates more studies, lighter shading indicates fewer studies, and a white space with no number indicates no studies available). Interactive figure with study details for studies evaluating nervous system effects at the Tableau [underlined: Malformations-Animal] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Animal) [underlined: tab] (NTP 2020). To identify studies reporting significant effects, click “significant” in the Filter - Effect Significance in Tableau (NTP 2020). To identify studies that did not report statistical analyses, click “not reported” in the Filter - Effect Significance in Tableau (NTP 2020).

Higher frequencies of congenital malformations were reported in 18 animal studies, including 6 studies evaluating any congenital malformation (Andrew and Staples 1977; Eibs et al. 1982; Prahalada et al. 1985a; Prahalada et al. 1985b; Sannes et al. 1983; Silva et al. 2019 and 12 studies measuring specific congenital malformations (Dohler et al. 1986; Foote et al. 1968; Forsberg and Jacobsohn 1969; Forsberg et al. 1968; Graf and Neumann 1972; Iqbal et al. 2012; Johnstone and Franklin 1964; Pamir et al. 2006; Vega Matuszczyk and Larsson 1995; Ward 1972; Whalen et al. 1966; Wharton and Scott 1964). Of note, the animal studies reporting higher rates of congenital malformations included the 10, predominantly older, studies that were descriptive in nature and did not conduct statistical analyses [[underlined: see] [underlined: Malformations-Animal] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Animal), Filter - Effect Significance in Tableau (NTP 2020)].

Genital organ malformations were the most frequently observed malformations with effects reported in 11 studies, including 2 studies evaluating any congenital malformation (Prahalada et al. 1985a; Prahalada et al. 1985b) and 9 studies specifically evaluating genital malformations [[underlined: see] [underlined: Malformations-Animal] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Malformations-Animal), Filter - Effect Significance in Tableau (NTP 2020)]. Demasculinizing effects on male reproductive development (e.g., hypospadias, undescended testes) were reported following exposure to cyproterone acetate (a synthetic progestogen with anti-androgenic action) (five studies) (Forsberg and Jacobsohn 1969; Forsberg et al. 1968; Graf and Neumann 1972; Vega Matuszczyk and Larsson 1995; Ward 1972), MPA (two studies) (Prahalada et al. 1985a; Prahalada et al. 1985b) and norethindrone (Wharton and Scott 1964). In addition, masculinizing effects on female development (e.g., clitoral enlargement, lack of vaginal opening) were reported with exposure to synthetic progestogens with known androgenic action, including norethindrone (three studies) (Foote et al. 1968; Whalen et al. 1966; Wharton and Scott 1964), norethindrone acetate (Johnstone and Franklin 1964), and medroxyprogesterone acetate (three studies) (Foote et al. 1968; Prahalada et al. 1985a; Prahalada et al. 1985b). Although not a congenital malformation, anogenital distance was reported to be altered in several nonhuman animal models after in utero exposure to the same synthetic progestogens, which were reported to induce genital organ malformations (see Reproductive System Effects section below for a complete description of this effect).

Except for genital organ malformations, very few types of malformations were reported to be induced by individual progestogen exposure. In studies evaluating any congenital malformation, significantly higher rates of cleft palate were reported following exposure to cyproterone acetate or MPA (two studies) (Andrew and Staples 1977; Eibs et al. 1982) as were central nervous system defects (other than neural tube defects), heart defects, and skeletal malformations following exposure to cyproterone acetate (Eibs et al. 1982) or lynestrenol (Sannes et al. 1983). Higher rates of neural tube defects were reported in chicks following a dose of progesterone reported to be 20 times the endogenous progesterone level for Stage 8 period of development in the chicken (157 ng), while the lower dose of progesterone (2 ng) had no effect (Iqbal et al. 2012; Pamir et al. 2006). Another study evaluating any malformation in zebrafish reported spinal and tail deformations following exposure to different forms of bioidentical progesterone (free and micronized forms) (Silva et al. 2019).

No congenital malformations were observed following prenatal exposure to 17OHPC (five studies) (Carbone and Brent 1993; Hendrickx et al. 1987; Johnstone and Franklin 1964; Schardein et al. 2012; Seegmiller et al. 1983), similar to its absence of effect in human studies. In contrast to the bird and fish models, no congenital malformations were reported in the studies evaluating progesterone in nonhuman mammalian models (Foote et al. 1968; Harini et al. 2009; Pointis et al. 1987; Wharton and Scott 1964) or in an amphibian model (Thomson and Langlois 2018).

## Neurological Effects

### Human Studies

The available literature on prenatal progestogen exposure associated with neurological effects was evaluated in 24 human studies (Figure 6). The literature base included 10 prospective cohort studies of 4 unique populations, 7 retrospective cohort studies with 6 unique populations, 6 randomized controlled trials of 5 unique populations, and 1 case-control study (Table 3). Most studies evaluated neurological outcomes in humans following prenatal exposure to progesterone and MPA. Neurological effects were categorized into five domains: brain development (e.g., neurological handicap at discharge) and the neurobehavioral domains of learning and memory, sexually dimorphic behavior (i.e., gender roles/sexual identity), motor activity, and social/emotional measures. Several studies reported results relevant to more than one domain; for example, studies evaluating child development included assessments of learning and memory, motor activity, and social and emotional measure domains (McNamara et al. 2015; Norman et al. 2016; Northern et al. 2007; Rode et al. 2011; Vedel et al. 2016; Zhang et al. 2014).

Figure 6

Number of Studies Evaluating the Association between Prenatal Exposure to Progestogens and Nervous System Effects in Humans and Animals

17OHPC = 17-alpha-hydroxyprogesterone caproate; MPA = medroxyprogesterone acetate.

Progestogens indicates exposure to (bioidentical) progesterone or synthetic progestogens evaluated as a general category of exposure. Numbers in the grand total row or column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available (i.e., darker shading indicates more studies, lighter shading indicates fewer studies, and a white space with no number indicates no available studies). Interactive figure with study details available at the Tableau Nervous System (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/NervousSystem) outcomes tab (NTP 2020). To view the specific outcome evaluated, expand the Specific Outcome column in the Tableau figure (NTP 2020). To identify studies reporting significant effects, click “significant” in the Filter - Effect Significance in Tableau (NTP 2020). To identify studies that did not report statistical analyses, click “not reported” in the Filter - Effect Significance in Tableau (NTP 2020).

Table 3 Summary of Studies Evaluating Neurological Effects in Humans Associated with In Utero Exposure to Progestogens

Exposure Measured | Study Design (Location/Subjects) [n] | Exposure Details | Outcome Measured | Results | Study
17OHPC | Randomized controlled trial (United States/neonates) [32 exposed and 28 unexposed] | 250 mg, im injection weekly in second and/or third trimesters | Brain development (any neurological defect upon discharge from hospital) | No statistically significant difference in the incidence of neurological defects on discharge between exposed and unexposed neonates. | Briery et al. (2009)
| Retrospective cohort (United States/teenagers, age range 12–18 years) [25 exposed males, 25 unexposed males] | 250 mg, im injection weekly in first, second and third trimesters | Sexually dimorphic behavior | Significantly more (p < 0.05) time spent watching television by exposed than unexposed males; however, no differences in aggression, gender identity, need to conform to group norms of social behavior, interest in play activity (sports, games, rough-and-tumble play), visual spatial ability, interest in reading and types of books, television program preferences. | Kester (1984)
| Prospective cohort (United States; follow-up to the National Institute of Child Health and Human Development Maternal-Fetal Medicine Units Network study/children at age 48 months) [194 exposed, 84 unexposed] | 250 mg, im injection weekly in second and third trimesters | Learning and memory, social/emotional, motor activity, and sexually dimorphic behavior | No statistically significant difference in the neurodevelopment or gender-specific roles scores between exposed and unexposed children. | Northern et al. (2007)
Levonorgestrel | Prospective cohort (China/infants and toddlers at ages 3, 6, 12 and 24 months) [195 exposed, 214 unexposed] | ≤1.5 mg or >1.5 mg, orally in first trimester | Learning and memory, motor activity, and social/emotional | No statistically significant difference in the mental development of exposed infants or toddlers compared to unexposed children. | Zhang et al. (2014)
MPA | Prospective cohort (Israel/teenagers at age 18.6 ± 11.6 years) [73 exposed males, 97 exposed females; 377 unexposed males, 440 unexposed females] | 150 mg per injection or ≥1 mg oral tablet, daily in first and second trimesters | Learning and memory | No statistically significant differences in verbal and spatial tests between the exposed and unexposed children. | Jaffe et al. (1988) [same cohort as Jaffe et al. (1989)]
| Prospective cohort (Israel/teenagers) [74 exposed boys, 98 exposed girls; 381 unexposed boys, 444 unexposed girls] | 150 mg per injection or ≥1 mg oral tablet, daily in first and second trimesters | Aggression and sexually dimorphic behavior | No statistically significant differences in sex role or behavioral tests (aggressiveness, assertiveness, and physical activity levels) between the exposed and unexposed children. | Jaffe et al. (1989) [same cohort as Jaffe et al. (1988)]
| Prospective cohort (United States/female children, age range 8–12 years) [15 exposed, 15 unexposed] | 140–2,020 mg total dose during pregnancy, im injection | Sexually dimorphic behavior | Significantly (p < 0.05) more females in the exposed group had a clear preference for feminine clothing styles and tended (p = 0.06) to show less tomboy-ism on a long-term basis than the control group. | Ehrhardt et al. (1977) [Preliminary study of Ehrhardt et al. (1984)]
| Prospective cohort (United States/ children, age range 8–12 years) [15 exposed, 15 unexposed] | 140–3,900 mg total dose during pregnancy, im injection | Sexually dimorphic behavior | No statistically significant findings of greater frequency of stereotypic femininity in exposed females on the basis of reported less physical activity, and greater rates of playing with dolls and interest in feminine clothing than unexposed females. | Ehrhardt et al. (1984)
| Prospective cohort (United States/male children, age range 9–14 years) [13 exposed males, 13 matched unexposed males] | 140–2,020 mg total dose during pregnancy, im injection | Sexually dimorphic behavior | No statistically significant difference in sexually dimorphic behavior in the exposed compared to unexposed male children. Slight tendencies of less interest in marriage and having children in the exposed group. | Meyer-Bahlburg et al. (1977) [Preliminary study of Ehrhardt et al. (1984)]
| Same as 25">Ehrhardt et al. (1984) | Same as 25">Ehrhardt et al. (1984) | Sexually dimorphic behavior | No statistically significant differences in sexually dimorphic behavior between the exposed girls and their controls. However, the children’s interview suggested that boys in the exposed group appear more masculine on the general factor (p = 0.016) than their male controls. | Meyer-Bahlburg et al. (1984) [Reanalysis of Ehrhardt et al. (1984)]
| Same as 25">Ehrhardt et al. (1984) | Same as 25">Ehrhardt et al. (1984) | Sexually dimorphic behavior | Lower masculine nonathletic play behavior (p < 0.05) in exposed males after adjusting for pregnancy complications and age at time of study compared to unexposed. No statistically significant effects were observed in exposed compared to unexposed females. | Meyer-Bahlburg et al. (1988) [Reanalysis of Ehrhardt et al. (1984)]
Progesterone | Prospective cohort (United Kingdom/ infants and children) [infants: 29 exposed, 31 normal unexposed; children: 29 exposed, 21 normal unexposed, and 29 toxemia controls] | 50–300 mg, im injection daily in second and third trimesters | Learning and memory, motor activity | At age 1 year, significantly (p < 0.05) more exposed infants were standing and walking than unexposed infants. More exposed infants were breast-fed than unexposed infants. At age 9–10 years, exposed children had significantly more above average school grades compared to unexposed children in all subjects except physical education. | Dalton (1968)
| Prospective cohort (United Kingdom/teenagers and young adults) [34 exposed, 37 normal unexposed, 12 toxemia controls] | 500 mg, im injection during pregnancy, frequency not reported | Learning and memory | At ages 17–20 years, a significantly (p < 0.05) higher number of exposed teenagers and young adults achieved advanced grades and were accepted into university than unexposed groups. | Dalton (1976) [Same cohort as Dalton (1968)]
| Retrospective cohort (United States/adults, age range 19–24 years) [10 males exposed to progesterone, 13 males exposed to progestogens,^a^ 23 unexposed males] | 25–1,955 mg total dose during pregnancy, route not reported | Sexually dimorphic behavior | Significantly lower scores (p < 0.05) on the feminine and masculine scales of the Bem Sex Role Inventory in men exposed to higher doses of progesterone in utero, resulting in an undifferentiated score pattern. Significantly higher rate (p < 0.05) of erectile failure in men exposed to progesterone compared to unexposed men. | Kester et al. (1980)
| Retrospective cohort (United Kingdom/toddlers at age 2 years and teenagers at age 16 years) [toddlers: 19 exposed, 13 unexposed; and teenagers: 15 exposed, 11 unexposed] | 50 mg on alternate days or 300 mg daily, im injection in second and third trimesters (16-year-old subjects) | Toddler: learning and memory, motor activity, social/emotional; teenager: learning and memory, sexually dimorphic behavior | Significantly lower (p < 0.05) scores for extroverted personality traits in exposed females than control females. No statistically significant effect on mental (learning and memory, social/emotional) or motor development in the age 2 group; no statistically significant enhanced intellectual and academic attainment in the age 16 group of exposed children compared to control group. | Lynch et al. (1978) [16-year old subjects in same cohort as Dalton (1968)]
| Randomized controlled trial (United Kingdom; follow-up to STOPPIT trial/neonates, infants, and preschoolers) [386 exposed, 395 unexposed] | 90 mg, vaginal gel daily in second and third trimesters | Learning and memory, motor activity, social/emotional | No statistical differences in childhood development, emotion, or cognition at any life stage measured in exposed children compared to controls. | McNamara et al. (2015)
| Randomized controlled trial (United Kingdom and Sweden; the OPPTIMUM study/neonate and toddler) [neonates: 589 exposed, 587 unexposed; toddlers: 430 exposed, 439 unexposed] | 200 mg, vaginal capsule daily in second and third trimesters | Neonate: brain development (brain injury diagnosed by ultrasound); toddler: learning and memory, motor activity, social/emotional | No statistically significant effect on incidence of neonatal brain injury or neurological developmental outcomes in toddlers, either as cognitive scores or neurological impairments, between exposed and unexposed subjects. | Norman et al. (2016)
| Retrospective cohort (Denmark/young adults) [34 exposed, 34 matched unexposed] | 18.41 mg average, daily during third trimester, route not reported | Sexually dimorphic behavior | Lower rates (p < 0.01) of self-identification as heterosexual, and greater engagement in same-sex sexual behaviors (p < 0.03), attraction to the same or both sexes (e.g., ever attracted, p < 0.02), and higher scores on attraction to males (p < 0.02) for exposed men and women compared to controls. | Reinisch et al. (2017)
| Randomized controlled trial (Denmark and Austria; PREDICT trial/infants and toddlers) [664 exposed, 678 unexposed] | 200 mg, vaginal pessary daily in second and third trimesters | Learning and memory, motor activity, social/emotional | No statistically significant difference in Ages and Stages Questionnaire scores between exposed and unexposed group. | Rode et al. (2011)
| Randomized controlled trial follow-up to PREDICT trial (Denmark/children at ages 48 and 60 months) [225 exposed, 212 unexposed] | 200 mg, vaginal pessary daily in second and third trimesters | Learning and memory, motor activity, social/emotional | Mean Ages and Stages Questionnaire score was significantly higher (p = 0.03) (significant for total score and gross motor skills) in the exposed group compared with controls. In dichorionic twins, significantly lower risks of a low Ages and Stages Questionnaire score (<10th centile; (OR = 0.34, 95% CI = 0.14–0.86) or low gross motor skills score (OR, 0.43, 95% CI, 0.21–0.90) as well as higher communication (p = 0.01), gross motor skills (p = 0.02), and social/personality scores (p = 0.04) in the exposed versus control group. | Vedel et al. (2016) [Follow-up of the Danish cohort Rode et al. (2011)]
Synthetic progestogen | Retrospective cohort (United States/adults, age range 19–24 years) [10 males exposed to progesterone, 13 males exposed to progestogens, 23 unexposed males] | 125–2,198 mg total dose, route not reported | Sexually dimorphic behavior | Higher scores (p < 0.05) on feminine scale, greater number (p < 0.01) of girls as friends in boyhood (based on timing of exposure during pregnancy), and a lower sex drive (p < 0.01) in exposed compared to control men. | Kester et al. (1980)
| Retrospective cohort (United States/children and teenagers at ages 5–18 years) [26 exposed, 26 unexposed] | 525–9,890 mg total dose during pregnancy including first trimester (some were exposed to 1 mg estrogen), route not reported | Learning and memory, social/emotional | Significantly higher (p < 0.05) scores for independence and being self-assured, individualistic, and self-sufficient in exposed compared to unexposed siblings, but no statistically significant difference in IQ. | Reinisch and Karow (1977)
| Retrospective cohort (location not reported/children and adolescents, at ages 6–18 years) [25 exposed and 29 unexposed] | 590–8,790 mg total dose in the first and second trimesters or first, second, and third trimesters, route not reported | Learning and memory, social/emotional | Significantly higher (p < 0.01) physical aggression scores in exposed children than their sex-matched unexposed siblings, especially with exposure to norethindrone. No statistically significant differences in verbal aggression or IQ. | Reinisch (1981)
Progestogen^a^ | Case-control (China/children, ages ≤6 years) [235 cases and 37, 627 typically developing controls] | Not reported | ASD | Significantly higher odds of ASD with maternal use of progestogen to prevent threatened abortion (OR = 14.631, 95% CI = 5.103–41.952) or with use of progestogen contraceptives at time of conception (OR = 15.743, 95% CI = 7.610–32.568). Likewise, significantly higher odds of ASD with maternal consumption of progestogen-contaminated seafood during pregnancy (100–400 g/week, reference): 400–800 g/week (OR = 35.998, 95% CI = 16.589–78.115) or 800–1,200 (OR = 103.863, 95% CI = 30.128–358.057). | Li et al. (2018)
| Retrospective cohort (France; French Hhorages Association/children, ages not provided) [62 exposed, 18 unexposed firstborn siblings] | Not reported | Psychiatric disorders^b^ and somatic disorders | Higher incidence of psychiatric disorders (79%) and somatic disorders (10%) in exposed children compared to firstborn unexposed siblings (0% for both types of disorder). | Soyer-Gobillard et al. (2019)

17OHPC = 17-alpha-hydroxyprogesterone caproate; Hhorages = Halt to Synthetic Hormones for Pregnancies; im = intramuscular injection; IQ = intelligence quotient; MPA = medroxyprogesterone acetate; n = number of subjects; OPPTIMUM = does progesterone prophylaxis to prevent preterm labor improve outcome; OR = odds ratio; PREDICT = prevention of preterm delivery in twin gestations; STOPPIT = study of progesterone for the prevention of preterm birth in twins; ASD = autism spectrum disorder.

^a^ Progestogen refers to (bioidentical) progesterone or synthetic progestogens evaluated as general category of exposure.

^b^ Psychiatric disorders included schizophrenia, manic-depressive psychosis, severe depression, behavior disorders, aggressiveness, or eating disorders.

The body of evidence for neurological development in human studies had a high degree of heterogeneity in the exposures and the neurological domains. Most of these studies were also older literature with publication dates between 1968 and 1989 (14 of 24 studies) [see Study Details and Timeline (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/StudyDetailsandTimeline), Filter - Health Outcome in Tableau (NTP 2020)].

Significant effects were reported in 12 of 24 studies measuring neurodevelopmental and behavior effects in humans (Table 3). No evidence of consistent effects was observed across studies on an outcome basis or across an individual neurological domain considered broadly (e.g., learning, memory). Similarly, few studies focused on individual progestogen exposures and no evidence of consistent effects was observed among studies evaluating the same individual progestogen exposure with the largest literature bases. For example, the seven studies evaluating learning and memory associated with progesterone exposure assessed different endpoints (e.g., intelligence quotient, personality traits associated with good academic performance) with only three studies reporting significantly greater performance relevant to controls (Dalton 1968; 1976; Vedel et al. 2016).

### Animal Studies

Thirty-seven studies of nonhuman animal models reporting on neurological effects were identified in the available literature (Figure 6). Similar to the human studies, progesterone was the most frequently evaluated exposure for nervous system effects in animals (19 studies). Neurobehavioral outcomes evaluated were grouped into five main categories: sexually dimorphic behavior (i.e., mating behavior; 14 studies), social/emotional skills (e.g., emotional reactivity, aggression; 9 studies), learning and memory (7 studies), motor activity (7 studies), and motor sensory reflexes (2 studies). Several non-neurobehavioral outcomes were assessed, including: brain weight (e.g., weight of whole brain or specific brain regions; nine studies), cholesterol levels (one study), DNA damage (two studies), DNA levels (two studies), enzyme levels and/or activity (two studies), epigenetic modification (two studies), evoked potential (one study), fatty acid metabolism (two studies), immunohistochemistry/histology (four studies), mitochondrial function (two studies), oxidative stress (two studies), and total brain protein levels (one study) (Figure 6). Among the studies, seven different animal models were tested, with rat the most commonly used (22 studies) [see Nervous System (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/NervousSystem), Filter - Animal Model in Tableau (NTP 2020)].

Significant results were reported in 20 of the 28 studies evaluating nervous system effects; however, assessing the evidence for any potential pattern of effects for most outcomes was difficult due to too few studies per exposure and outcome pair, heterogeneity in the endpoints assessed within a domain, and/or heterogeneity in the results (Figure 6). The most consistent results were reported for studies evaluating sexually dimorphic behavior, with 10 of 12 studies reporting significant findings of alteration in mating behavior with apparent feminization of males and masculinization of females following exposure to progesterone (3 studies) (Hull et al. 1980; Pointis et al. 1987; Regestein et al. 1975), cyproterone acetate (4 studies) (Etzel et al. 1974; Perakis and Stylianopoulou 1986; Vega Matuszczyk and Larsson 1995; Ward 1972; Ward and Renz 1972), or allylestrenol (3 studies) (Csaba et al. 1993; Karabelyos et al. 1994a; Karabelyos et al. 1994b) in various animal models (e.g., rats, mice, guinea pig) [see Nervous System (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/NervousSystem), Filter - Effect Significance in Tableau (NTP 2020)]. An additional study that did not conduct statistical analyses reported that 11 of 14 male guinea pigs prenatally exposed to cyproterone acetate did not display mating behavior toward females in estrus (Etzel et al. 1974). In contrast, a study of mating behavior following prenatal exposure to 17OHPC in a rat model reported a significantly greater number of copulation attempts (Pushpalatha et al. 2005). Studies reporting on other neurobehavioral domains yielded less consistent results or were assessed using a variety of tests measured in only a few studies each, which limited the ability to compare among studies. For example, of the five studies evaluating the effects of developmental exposure to progesterone on learning and memory, two studies reported apparent higher scores for learning and memory endpoints (Herrington et al. 2016; Snyder and Hull 1980), two reported lower scores (Herrington et al. 2015; Hull et al. 1980), and one study reported no effect (Coyle et al. 1976).

## Reproductive System Effects

### Human Studies

Three human studies addressed reproductive system effects associated with in utero exposure to progestogens evaluated in a single prospective cohort study and two retrospective cohort studies. Only two reproductive effects were evaluated in humans: fertility and timing of puberty [see the [underlined: Reproductive] (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Reproductive) [underlined: tab] in Tableau; (NTP 2020)]. In the one study evaluating fertility, the authors reported no association of prenatal exposure to progestogens on fertility, which was measured as the number of women with a live birth (Hemminki et al. 1999). The appearance of pubic hair, a sign of onset of puberty, was reported delayed in girls exposed to MPA relative to controls in one study (X^2^ = 3.99, p = 0.05 by Mantel-Haenszel weighted chi-square for all age strata, but not by another statistical method (RR = 0.61, 95% CI = 0.4–1.0) (Pardthaisong et al. 1992). Another study reported no statistically significant difference in timing of puberty in girls following multiple regression analysis (Jaffe et al. 1990). The timing of puberty for boys was not significantly different in either study (Jaffe et al. 1990; Pardthaisong et al. 1992).

### Animal Studies

Reproductive system effects associated with in utero exposure to progestogens were reported in 26 animal studies. The most frequently evaluated reproductive outcome was anogenital distance (16 studies). Other outcomes reported included reproductive organ weights, reproductive organ histology, sperm parameters, timing of puberty, estrous cyclicity, fertility, fecundity, and gene expression (e.g., vitellogenin mRNA levels in fish).

Anogenital distance (AGD) is often measured in studies of humans and mammalian animal models to determine whether an exposure resulted in hormone disruption during the period of sexual differentiation in utero. In normal development, AGD in males is consistently longer than in females. Exposure to anti-androgenic chemicals or weak androgen agonists during pregnancy has been demonstrated to significantly shorten AGD in males. Significant findings were reported in 13 animal studies evaluating AGD following prenatal progestogen exposure and two studies that reported effects of progestogens but did not conduct statistics (Giannia et al. 1969; Johnstone and Franklin 1964) (Figure 7). The direction of the effect was consistent with in utero exposure to progestogens lengthening the AGD of female offspring (Foote et al. 1968; Gandelman et al. 1981; Giannia et al. 1969; Johnstone and Franklin 1964; Prahalada et al. 1985a; Prahalada et al. 1985b; Whalen et al. 1966) and shortening the AGD in male offspring (Gupta and Goldman 1986; Scouten et al. 1975). Similar effects were reported across species (mice, rats, guinea pigs, baboons, and cynomolgus monkeys) and across synthetic progestogen exposures with known anti-androgenic (e.g., cyproterone acetate) or androgenic effects (e.g., MPA, norethindrone, norethindrone acetate, quingestanol acetate). One exception was a report of greater AGD than controls in male guinea pigs prenatally exposed to norethindrone (Foote et al. 1968).

Figure 7

Reported Results of Animal Studies Evaluating the Association between Prenatal Exposure to Progestogens and Anogenital Distance by Sex

17OHPC = 17-alpha-hydroxyprogesterone caproate; MPA = medroxyprogesterone acetate.

Numbers in the grand total row and column refer to the number of unique studies per each exposure or health outcome; some studies might evaluate more than one exposure or health outcome. Cell shading indicates the number of studies available; i.e., darker shading indicates more studies; lighter shading indicates fewer studies; and a white space with no number indicates no studies available. Effect symbols: - = no effect (data similar to control), ↑ = greater than control, and ↓ = less than control. Interactive figure with study details available at the Tableau Reproductive (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/Reproductive) outcomes tab (NTP 2020).