# Methods

The systematic review techniques in this scoping review adhere to the framework developed by the National Toxicology Program’s (NTP’s) Office of Health Assessment and Translation (OHAT) (Rooney et al. 2014). This report was restricted to the first three steps of the seven-step OHAT systematic review framework: (1) problem formulation, (2) literature search and selection of studies for inclusion, and (3) abbreviated data extraction. The data extraction step for the scoping review involves characterizing the studies to identify the areas of published research on the exposures by health outcomes of interest. The remaining four steps of the OHAT systematic review framework, which are relevant for assessing study quality and synthesizing evidence across evidence streams, were beyond the scope of the current report.

## Problem Formulation and Protocol Development

Prenatal progestogen exposure and fetal germ-line (epigenetic) effects were nominated to NTP for possible literature evaluation and laboratory research studies in spring 2013. The first nomination was focused on the possible relationship between progestogen use during pregnancy and autism in the F_2_ generation (grandchildren; exposed as germ cells). A second and related nomination was also received in 2013 with an interest in neurodevelopmental outcomes related to prenatal progestogen exposure. A preliminary, focused literature search of the PubMed database was conducted on progestogens (including both bioidentical progesterone and synthetic progestogens) and any adverse pregnancy outcome or health effects in prenatally exposed offspring. Informed by the results of the preliminary literature search, the final literature search was designed to identify literature reporting on the health outcomes evaluated in liveborn offspring, including adverse neonatal health effects, congenital malformations, and neurological effects (e.g., neurodevelopmental and behavioral effects). Cancer incidence following prenatal exposure to progestogens was included in the final literature search due to the listing of progesterone as reasonably anticipated to be a human carcinogen by NTP’s Report on Carcinogens (NTP 2016). Known relevant references from the preliminary targeted search were used to train the machine-learning model used by SWIFT-Active Screener (Sciome, Research Triangle Park, NC) for the initial title-and-abstract screening of this scoping review (Howard et al. 2020). A protocol was developed and used to conduct this review (Appendix B). A brief summary of the methods is presented below.

## PECO Statement

A PECO (Population, Exposure, Comparator, and Outcome) statement (Table 1) was developed to address and understand the adverse effects of prenatal exposure to progestogens reported in humans, animals, and in vitro model systems (Table 1). The following PECO statement was used to develop the specific research questions, search terms, and inclusion/exclusion criteria for the systematic review (Higgins et al. 2019). Of note, the exposures included in the literature search strategy were identified from the literature as progestogens prescribed to reproductive-aged women (Brucker and Likis 2010; Schindler et al. 2008).

Table 1 PECO ([underlined: P]opulation, [underlined: E]xposure, [underlined: C]omparator, and [underlined: O]utcome) Statement

Element | Type of Evidence
[underlined: P]opulation | Human: any population without restriction Animal: Nonhuman, vertebrate laboratory animal models, including but not limited to mice, monkeys, rats, fish, and amphibians In vitro: in vitro models using organs, tissues, cell lines, or cellular components relating to embryonic or fetal exposure
[underlined: E]xposure | Progestogens, including bioidentical (plant-based) progesterone or synthetic progestogens (e.g., 17-alpha-hydroxyprogesterone caproate) administered during pregnancy
[underlined: C]omparators | A comparison population exposed to lower levels (or no exposure) of progestogen; experimental studies should include an untreated or vehicle control
[underlined: O]utcomes | Adverse neonatal outcomes,^a^ congenital malformations,^b^ neurological effects (e.g., neurodevelopmental and behavioral effects), cancer, and other associated health outcomes (e.g., reproductive system effects)

^a^ Adverse neonatal outcomes included those effects frequently associated with prematurity, such as apnea/bradycardia, bronchopulmonary dysplasia (also called chronic lung disease), respiratory distress syndrome, pneumothorax, pneumonia, patent ductus arteriosus, intraventricular hemorrhage, periventricular leukomalacia, retinopathy of prematurity, necrotizing enterocolitis, seizures, sepsis, hypoglycemia, and hyperbilirubinemia (IOM 2007).

^b^ Studies reporting on congenital malformations in miscarried fetuses, stillborn, and liveborn infants were included.

Several health outcomes were not included in the scoping review. Mortality-related outcomes, such as miscarriage, stillbirth, or neonatal death, were not included because the focus of the scoping review was on adverse health outcomes of liveborn offspring (e.g., autism). Preterm birth was not included in the scoping review because progestogens often were administered to treat threatened miscarriage or preterm birth or to prevent these conditions from developing. Composite health outcomes (e.g., composite morbidity/mortality) and hospitalization-related endpoints (e.g., admittance or time in the neonatal intensive care unit) were not included because although they are general indicators of health, they were not usually informative of a specific health outcome. Furthermore, studies measuring composite health outcomes often included different combinations of health endpoints [e.g., composite morbidity/mortality (Palacio et al. 2016), global health rating (McNamara et al. 2015)].

## Literature Search

The literature search strategy was designed to identify: (1) progesterone or synthetic progestogen as title-and-abstract search terms, (2) specific synthetic progestogen or progestin medical subject heading (MeSH) terms, and (3) specific progestogen drug names as title-and-abstract terms, each in combination with health outcomes of interest (e.g., pregnancy outcomes, congenital anomalies, neurological effects, cancer) associated with prenatal exposure (full details of the search strategy are presented in Appendix A). This scoping review considered two databases (PubMed and Cochrane Library) sufficient to map the major health effects categories for each evidence stream to identify in the literature and principal health effects categories that could be further evaluated by future research or a subsequent systematic review. PubMed and Cochrane Library databases were searched through September 13, 2019. The Database of Abstracts of Reviews of Effects (DARE), which stopped collecting records in 2015, was also searched for meta-analyses and systematic reviews addressing prenatal exposure to progestogens and offspring health. Although these types of studies were excluded from the scoping review, a list of the meta-analyses and systematic reviews was collated in the case of scientific interest in this body of literature [see Relevant Literature (https://public.tableau.com/profile/ntp.visuals#!/vizhome/051518-p_0/RelevantLiterature) tab in Tableau; (NTP 2020)]. No restrictions were placed on study design type or publication year. There were no language restrictions in the literature search; however, non-English language studies were excluded in the study selection step.

The reference lists of relevant studies and authoritative reviews or government-authored (state and federal) technical reports identified during the literature screening were hand searched for additional original research references not identified through the electronic searches. These additional studies were collated for use in a potential future systematic review and were not added to the current scoping review.

## Study Selection

### Evidence Selection Criteria

Studies were eligible for inclusion if they satisfied the eligibility criteria in the PECO statement. Inclusion and exclusion criteria used to screen articles for relevance and eligibility at both the title-and-abstract and full-text screening stages are summarized in Table 1. The reason for exclusion at the full-text review stage was recorded and is reported in the study flow diagram. A study was excluded if it was: (1) a review, commentary, or editorial with no original data; (2) an original research article that lacked relevant PECO characteristics (no relevant population, exposure, comparator, or health outcome information); (3) a conference abstract or thesis/dissertation; (4) not available in full text (as a PDF); or (5) not published in the English language. In addition, this scoping review excluded studies reporting on assisted reproductive technologies because they generally lacked information about the health outcome of the offspring (e.g., most studies reported on ongoing pregnancy or live birth), and they usually involved physical manipulation of the gametes and multiple hormone exposures (e.g., evaluating the effect of progestogens alone was not possible) or lacked information about hormone drugs administered. References reporting on livestock animal models were considered not relevant because most of these studies used natural (bioidentical) progesterone to understand the role of endogenous progesterone on establishing and maintaining pregnancy, or they evaluated assisted reproductive technologies with minimal reporting on offspring outcomes.

### Title-and-abstract Review

Title-and-abstract screening was performed in SWIFT-Active Screener (Sciome, Research Triangle Park, NC) to identify references with exposure to bioidentical progesterone or synthetic progestogens during pregnancy; this software uses machine-learning and text-mining technology to prioritize the unscreened references in order of most relevant to least relevant on the basis of the results of manually screened references (Howard et al. 2020 In brief, title-and-abstract screening was conducted independently by two screeners per reference to determine whether the reference met the inclusion criteria and screening continued until the software predicted that at least 95% of the relevant references were identified. Screeners were trained using project-specific written instructions in a pilot phase undertaken to improve clarity of the inclusion and exclusion instructions and to improve accuracy and consistency among screeners. The project lead scientist resolved screening conflicts.

### Full-text Review

After the title-and-abstract screening, references identified as potentially relevant or of unclear relevancy to the PECO statement were manually curated through full-text screening with the assistance of an online literature screening software database program (DistillerSR^®^, Evidence Partners, Ottawa, Canada). Screening at the full-text level were conducted independently by two screeners per reference to determine whether a reference met the inclusion criteria. The project lead scientist resolved screening conflicts.

## Data Extraction

Relevant studies identified in the full-text screening were characterized by evidence stream, study design, exposure (e.g., progesterone or individual synthetic progestogen), and category of health outcomes. Due to the potential effect of confounding, the indication for administration of the progestogens also was characterized for all human studies. This data extraction step was conducted independently by two screeners per reference as part of the full-text level screening. The data extraction of the relevant studies was verified in a quality assurance step by the project lead scientist or a third member of the team in cases where the project lead extracted data. Because this was a scoping effort and not a systematic review, the quality of the relevant literature was not assessed.

The relevant studies were summarized in an evidence map of health outcomes by drug exposure using Tableau (Seattle, WA) and summarized in the text. These visualizations can be viewed online in Tableau, and the associated data file in Microsoft Excel format can be downloaded here: https://doi.org/10.22427/NTP-DATA-RR-17. The Read Me page in Tableau includes descriptions of each data tab and detailed instructions for how to expand and filter the data. Some figures in the scoping review were created by filtering the data (e.g., congenital malformations in human following first-trimester exposure, anogenital distance in animals); instructions on how to replicate these figures in Tableau are in the footnote of each figure. The Effect Significance filter allows for data to be sorted by statistical significance as reported by the authors (NTP 2020).

### Data Availability

Interactive versions of each figure can be accessed directly using the link beneath each figure. In addition, all interactive figures and additional study details can be viewed online and data can be downloaded from [underlined: Tableau] in Microsoft Excel format here: https://doi.org/10.22427/NTP-DATA-RR-17 (NTP 2020).