# Introduction

Endogenous progesterone is a steroid hormone that is involved in reproduction by inducing cellular differentiation and vascularization of the uterus to support the embryo during early pregnancy. It inhibits further ovulation and myometrium contractility throughout the pregnancy and suppresses the maternal immune response to allow for implantation and maintenance of the developing embryo and fetus. Similar to other steroid hormones, progesterone acts via both genomic (nuclear receptor) and nongenomic (extranuclear receptor) mechanisms [reviewed in Taraborrelli (2015)] The genomic action of progesterone is exerted via three known progesterone nuclear receptors that interact with DNA to produce proteins responsible for regulating female reproduction. The nongenomic action of progesterone occurs via cell-membrane-localized progesterone receptors, which induce many physiological reactions involved in reproduction (e.g., acrosome reaction in sperm, oocyte maturation) through activation of various signaling pathways (e.g., G protein activation, Ca^2+^ homeostasis, phospho-inositol-3-kinase activation) [reviewed in Gellersen (2009)].

Progestogens (also called progestins) are compounds that exert progestational activity. They include two broad categories of drugs: bioidentical progesterone and synthetic progestogens. Bioidentical (sometimes referred to as natural) progesterone is prepared from plant sources (e.g., Mexican yams). Synthetic progestogens (also called synthetic progestins) are structurally related to progesterone and testosterone. Synthetic progestogens also are reported to interact with other steroid hormone receptors leading to diverse biological activities among these agents (Hapgood et al. 2014; Louw-du Toit et al. 2017; Schindler 2015; Stanczyk et al. 2013).

Progestogens are most commonly administered to women for contraception and hormone replacement therapy. For example, medroxyprogesterone acetate, bioidentical progesterone, and norethindrone were among the top 300 most prescribed drugs in 2018 along with several combination progestin/estrogen contraceptives (Kane 2018). Progestogens are also prescribed to reproductive-aged women for treatment of infertility, menstrual disorders (e.g., amenorrhea, menorrhagia, premenstrual syndrome), and prevention or treatment of miscarriage and preterm labor, among other complications of pregnancy (Brucker and Likis 2010). Thus, fetal exposure to progestogens could occur due to intentional (e.g., treatment of miscarriage) or unintentional (e.g., contraceptive failure or an undiagnosed pregnancy) exposure. Early periods of development are sensitive to exogenous hormonal drug exposure, such as the period of sexual differentiation of the reproductive tract that occurs during the first trimester of pregnancy in humans.

Concerns about possible adverse effects of progestogens on the developing fetus stem from the observation that alterations in the normal levels of endogenous steroid hormones during development have been shown to cause adverse effects on offspring health and development. For example, congenital adrenal hyperplasia is a genetic disorder that causes a deficiency of the enzymes involved in steroidogenesis (e.g., 21-hydroxylase enzyme), which results in elevated progesterone and androgen levels. Health outcomes associated with classical congenital adrenal hyperplasia resulting in moderate 21-hydroxylase deficiency are ambiguous genitalia at birth, accelerated development of external genitalia during childhood, menstrual cycle irregularities, difficulties getting pregnant, and altered sexually dimorphic behaviors (Turcu and Auchus 2015; Witchel 2017). In addition, several case reports and studies have reported virilization of female infants and hypospadias (opening of the penis on the underside of the penis, instead of the tip) in male infants of women administered different progestogens during the first trimester of pregnancy (Aarskog 1971; Grumbach et al. 1959; Wilkins et al. 1958). Similar effects have been reported in studies of animals exposed in utero to some synthetic progestogens, including the masculinization of external genitalia of female offspring, reproductive malformations in male offspring (e.g., hypospadias), and alterations in sexually dimorphic behavior.

## Significance

In 2013, the association between prenatal exposure to progestogens and potential adverse health effects was identified as a potential candidate for systematic review or toxicology research by two separate groups of concerned public citizens with a special interest in neurological outcomes and transgenerational effects. The National Toxicology Program conducted this scoping review to characterize the extent of evidence from human and animal studies that focused primarily on the following four health outcome categories in exposed offspring: adverse neonatal health effects, congenital malformations, neurological effects, and cancer incidence. The literature on adverse health outcomes associated with prenatal exposure to progestogens was systematically collected and categorized to develop an interactive evidence map to enable individuals to explore published studies by the types of exposure, potential health effects, and evidence stream (e.g., human, animal) to identify bodies of evidence and data gaps in the available research. This scoping review, which includes an interactive evidence map of the data, was developed to support decision-making on whether the database is likely to support hazard characterization conclusions for one or more health effects in a full systematic review or for consideration of future research on prenatal exposure to progestogens and adverse health effects in offspring.

## Objective and Specific Aims

### Objective

The primary objective of this scoping review was to identify and characterize the literature relevant to prenatal exposure to progestogens (bioidentical progesterone and synthetic progestogens) during pregnancy and adverse health outcomes, including adverse neonatal health effects, congenital anomalies, neurological effects (e.g., neurodevelopmental and behavioral effects), and cancer incidence. This scoping review did not categorize adverse health effects associated with prenatal exposure to endogenous progesterone (e.g., congenital adrenal hyperplasia). Although assisted reproductive technologies represent a significant opportunity for exposure to natural (biological) progesterone drugs in the first trimester, these studies were not included in the current scoping review. The rationale for their exclusion was because the preliminary literature screening effort resulted in the observation that the studies often lacked reporting on the hormonal drug regimen used and often reported only the number of ongoing pregnancies or liveborn infants, without additional details on offspring health (see Limitations of the Scoping Review below).

### Specific Aims

- Screen studies to identify relevant literature reporting on the association of prenatal exposure to progestogens and adverse neonatal health effects, congenital malformations, neurological effects (e.g., neurodevelopmental and behavioral effects), and incidence of cancer from epidemiological, experimental animal, and in vitro studies relating to embryonic or fetal exposure.
- Extract data from relevant studies on health effects and the association with exposure to progestogens (i.e., the extent and types of health effects evidence available by individual progestogens).
- Create an interactive evidence map summarizing the characteristics of the data health effects by exposure to progestogens (i.e., the extent and types of health effects evidence available by individual progestogens) to identify data-rich and data-poor areas of the literature that could be addressed in future research or for which a systematic review might be useful.
- Summarize the reported conclusions available on the health effects.