# Appendix B Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-RR-17.

## B.1 Protocol Information

NTP Protocol Revised

NTP Protocol

## B.2 Tableau Dataset

Progestogens Dataset