# Appendix A Literature Search Strategy

The literature search involved three databases: PubMed, Cochrane Library, and Database of Abstracts of Reviews of Effects (DARE). The literature search for PubMed included a separate set of search terms from the literature search for Cochrane Library and DARE databases (Table A-1 and Table A-2).

Table A-1 PubMed Database Search Terms

Set | Search Terms
Exposure/Progestogens | ((Progesterone[mh] OR progesterone-congeners[mh] OR progestins[mh] OR exogenous-progesterone[tiab] OR Algestone[tiab] OR Algestone-acetophenide[tiab] OR Allylestrenol[tiab] OR Chlormadinone-acetate[tiab] OR cyproterone-acetate[tiab] OR desogestrel[tiab] OR dydrogesterone[tiab] OR Ethisterone[tiab] OR ethynodiol-diacetate[tiab] OR Flurogestone-acetate[tiab] OR Gestonorone-caproate[tiab] OR Gestrinone[tiab] OR Levonorgestrel[tiab] OR Lynestrenol[tiab] OR medrogestone[tiab] OR medroxyprogesterone-acetate[tiab] OR Megestrol-acetate[tiab] OR Norethindrone[tiab] OR norethynodrel[tiab] OR Norgestrel[tiab] OR Promegestone[tiab] OR 11-hydroxyprogesterone[tiab] OR 17-alpha-hydroxy-progesterone-caproate[tiab] OR 17-alpha-hydroxyprogesterone-caproate[tiab] OR 17-hydroxyprogesterone-caproate[tiab] OR Demegestone[tiab] OR Dienogest[tiab] OR Drospirenone[tiab] OR Etonogestrel[tiab] OR Gestodene[tiab] OR Nomegestrol-acetate[tiab] OR Norelgestromin[tiab] OR Norethindrone-acetate[tiab] OR Norgestimate[tiab] OR ST-1435[tiab] OR Trimegestone[tiab] OR 11-hydroxyprogesterone[nm] OR 17-alpha-hydroxy-progesterone-caproate[nm] OR Demegestone[nm] OR Dienogest[nm] OR Drospirenone[nm] OR Etonogestrel[nm] OR Gestodene[nm] OR Nomegestrol-acetate[nm] OR Norelgestromin[nm] OR Norethindrone-acetate[nm] OR Norgestimate[nm] OR ST-1435[nm] OR Trimegestone[nm] OR Algestone[mh] OR Algestone-acetophenide[mh] OR Allylestrenol[mh] OR Chlormadinone-acetate[mh] OR cyproterone-acetate[mh] OR desogestrel[mh] OR dydrogesterone[mh] OR Ethisterone[mh] OR ethynodiol-diacetate[mh] OR Flurogestone-acetate[mh] OR Gestonorone-caproate[mh] OR Gestrinone[mh] OR Levonorgestrel[mh] OR Lynestrenol[mh] OR medrogestone[mh] OR medroxyprogesterone-acetate[mh] OR Megestrol-acetate[mh] OR Norethindrone[mh] OR norethynodrel[mh] OR Norgestrel[mh] OR Promegestone[mh] OR progestogens[tiab] OR progestogen[tiab] OR Hydroxyprogesterone-caproate[tiab]) OR ((progesterone[tiab] OR progestins[tiab]) NOT medline[sb]))
Window of Exposure | AND (animals,-newborn[mh] OR child[mh] OR infant[mh] OR maternal-exposure[mh] OR Maternal-Fetal Exchange[mh] OR babies[tiab] OR baby[tiab] OR child*[tiab] OR embryo[tiab] OR embryonic[tiab] OR embryos[tiab] OR fetal[tiab] OR fetus[tiab] OR foetal[tiab] OR gestation*[tiab] OR infant*[tiab] OR in-utero[tiab] OR maternal[tiab] OR neonat*[tiab] OR newborn*[tiab] OR offspring[tiab] OR perinat*[tiab] OR postnat*[tiab] OR prenat*[tiab] OR progeny[tiab] OR pups[tiab])
Outcome | AND (pregnancy-outcomes[mh] OR prenatal-exposure-delayed-effects[mh] OR premature-birth[mh] OR premature-birth[tiab] OR abortion,-spontaneous[mh] OR spontaneous-abortion[tiab] OR live-born[tiab] OR still-born[tiab] OR stillborn[tiab] OR stillbirth[tiab] OR still-birth[tiab] OR Congenital-Abnormality[tiab] OR Congenital-Abnormalities[tiab] OR Congenital-Abnormalities[mh] OR Deformities[tiab] OR Deformity[tiab] OR Congenital-defect[tiab] OR Congenital-defects[tiab] OR birth-defects[tiab] OR birth-defect[tiab] OR Congenital-anomalies[tiab] OR Congenital-anomaly[tiab] OR hypospadias[tiab] OR Behavior-and-Behavior-Mechanisms[mh] OR Gene-Expression-Regulation[mh] OR Glucuronosyltransferase[mh] OR Intelligence-tests[mh] OR Malate-Dehydrogenase[mh] OR Mediator-Complex-Subunit-1[mh] OR Mental-disorders[mh] OR Mental-processes[mh] OR Monocarboxylic-Acid-Transporters[mh] OR Myelin-Basic-Protein[mh] OR nervous-system[mh] OR nervous-system-diseases[mh] OR nervous-system-physiological-phenomena[mh] OR Neurogranin[mh] OR Oligodendroglia[mh] OR Peroxisome-Proliferator-Activated-Receptors[mh] OR Psychological-Phenomena-and-Processes[mh] OR Academic-performance[tiab] OR auditory[tiab] OR cortical[tiab] OR delayed-development[tiab] OR developmental-impairment[tiab] OR developmental-delay*[tiab] OR developmental-disorder*[tiab] OR euthyroid[tiab] OR gait[tiab] OR glia*[tiab] OR gliogenesis[tiab] OR hyperactiv*[tiab] OR impulse-control[tiab] OR IQ[tiab] OR ischemi*[tiab] OR locomotor[tiab] OR mental-deficiency[tiab] OR mental-development[tiab] OR mental-illness[tiab] OR mental-deficit[tiab] OR mobility[tiab] OR mood[tiab] OR morris-maze[tiab] OR morris-water[tiab] OR motor-abilit*[tiab] OR Motor-activities[tiab] OR motor-performance[tiab] OR nerve[tiab] OR neural[tiab] OR neurobehav*[tiab] OR Neurocognitive-impairment[tiab] OR neurodegenerat*[tiab] OR Neurodevelopment*[tiab] OR neurodisease*[tiab] OR neurologic*[tiab] OR neuromuscular[tiab] OR neuron*[tiab] OR neuropath*[tiab] OR obsessive-compulsive[tiab] OR OCD[tiab] OR olfaction[tiab] OR olfactory[tiab] OR open-field-test[tiab] OR passive-avoidance[tiab] OR plasticity[tiab] OR sociab*[tiab] OR speech*[tiab] OR spelling[tiab] OR stereotypic-movement*[tiab] OR synap*[tiab] OR tauopath*[tiab] OR visual-motor[tiab] OR Visuospatial-processing[tiab] OR water-maze[tiab] OR active-avoidance[tiab] OR ADHD[tiab] OR amygdala[tiab] OR antisocial[tiab] OR anxiety[tiab] OR anxious[tiab] OR asperger*[tiab] OR attention-deficit[tiab] OR autism[tiab] OR autistic[tiab] OR behavioral[tiab] OR behaviors[tiab] OR behavioural[tiab] OR behaviours[tiab] OR bipolar[tiab] OR cerebellum[tiab] OR cognition[tiab] OR cognitive[tiab] OR comprehension[tiab] OR cranial[tiab] OR dementia[tiab] OR dendrit*[tiab] OR dentate-gyrus[tiab] OR depression[tiab] OR down-syndrome[tiab] OR dyslexia[tiab] OR entorhinal-cortex[tiab] OR epilep*[tiab] OR ganglia*[tiab] OR ganglion*[tiab] OR hearing[tiab] OR hippocamp*[tiab] OR human-development[tiab] OR impulsiv*[tiab] OR Intellectual-disability[tiab] OR intelligence[tiab] OR language[tiab] OR learning[tiab] OR lewy-bod*[tiab] OR long-term-potentiation[tiab] OR long-term-synaptic-depression[tiab] OR memory[tiab] OR mental-disorder*[tiab] OR mental-recall[tiab] OR Motor-activity[tiab] OR motor-skill*[tiab] OR myxedema[tiab] OR Nervous-system[tiab] OR nervous-system[tiab] OR neurit*[tiab] OR optic[tiab] OR palsy[tiab] OR panic[tiab] OR parahippocamp*[tiab] OR paranoia[tiab] OR paranoid[tiab] OR perception[tiab] OR perforant*[tiab] OR personality[tiab] OR phobia[tiab] OR problem-solving[tiab] OR proprioception[tiab] OR psychomotor[tiab] OR reflex[tiab] OR risk-taking[tiab] OR schizophrenia[tiab] OR seizure*[tiab] OR sensation*[tiab] OR sleep[tiab] OR smell[tiab] OR spatial-behavior[tiab] OR substantia-nigra[tiab] OR child-development[mh] OR child-development[tiab] OR acanthoma*[tiab] OR acrochord*[tiab] OR acrospiroma*[tiab] OR adamantinoma*[tiab] OR adenoacanthoma*[tiab] OR adenoameloblast*[tiab] OR adenocarcin*[tiab] OR adenofibrom*[tiab] OR adenol*[tiab] OR adenom*[tiab] OR adenosquamous[tiab] OR ameloblast*[tiab] OR androblast*[tiab] OR angiofib*[tiab] OR angiog*[tiab] OR angiok*[tiab] OR angiol*[tiab] OR angiom*[tiab] OR angiomatosis[mh] OR angiosarc*[tiab] OR antibodies, neoplasm[mh] OR antigens, neoplasm[mh] OR apudom*[tiab] OR argentaffin*[tiab] OR arrhenoblast*[tiab] OR astroblast*[tiab] OR astrocytom*[tiab] OR astrogliom*[tiab] OR atypia[tiab] OR baltoma[tiab] OR barrett esophagus[mh] OR blastom*[tiab] OR cancer[tiab] OR cancero*[tiab] OR cancers[tiab] OR carcinog*[tiab] OR carcinogenicity tests[mh] OR carcinogens[mh] OR carcinoid*[tiab] OR carcinom*[tiab] OR carcinos*[tiab] OR cavernom*[tiab] OR cell line, tumor[mh] OR cementom*[tiab] OR cerumin*[tiab] OR chloroma*[tiab] OR cholangio*[tiab] OR chondrob*[tiab] OR chondrom*[tiab] OR chondros*[tiab] OR chord*[tiab] OR chorioa*[tiab] OR choriocarc*[tiab] OR chorioep*[tiab] OR chorionep*[tiab] OR chromaffinom*[tiab] OR collagenom*[tiab] OR comedocarcinom*[tiab] OR condylom*[tiab] OR condylomata acuminata[mh] OR corticotrop*[tiab] OR craniopharyng*[tiab] OR cylindrom*[tiab] OR cystadeno*[tiab] OR cystoma*[tiab] OR cystosa*[tiab] OR dentinom*[tiab] OR dermatofibro*[tiab] OR dermoid[tiab] OR desmoid[tiab] OR desmoplastic*[tiab] OR dictyota[tiab] OR dysgerm*[tiab] OR dyskerat*[tiab] OR dysmyelopoiesis[tiab] OR dysplas*[tiab] OR ectomesenchym*[tiab] OR elastofibr*[tiab] OR enchondrom*[tiab] OR endotheliom*[tiab] OR ependymo*[tiab] OR epidermoid*[tiab] OR epitheliom*[tiab] OR erythrol*[tiab] OR erythropl*[tiab] OR esthesioneuro*[tiab] OR etiolog*[tiab] OR fibroaden*[tiab] OR fibrochond*[tiab] OR fibroe*[tiab] OR fibrofol*[tiab] OR fibroid*[tiab] OR fibrolip*[tiab] OR fibrom*[tiab] OR fibroodontom*[tiab] OR fibrosarcom*[tiab] OR fibrothecom*[tiab] OR fibroxantho*[tiab] OR ganglioblast*[tiab] OR gangliocytom*[tiab] OR gangliogliom*[tiab] OR ganglioneuro*[tiab] OR gastrinom*[tiab] OR genes, neoplasm[mh] OR germinom*[tiab] OR glioblast*[tiab] OR gliom*[tiab] OR glomangio*[tiab] OR glucagonom*[tiab] OR gonadoblastom*[tiab] OR gonocytom*[tiab] OR gynandroblastom*[tiab] OR haemangio*[tiab] OR hamartom*[tiab] OR hemangio*[tiab] OR hepatoblastom*[tiab] OR hepatom*[tiab] OR hibernom*[tiab] OR hidradenom*[tiab] OR hidrocy*[tiab] OR hodgkin*[tiab] OR hydatidiform*[tiab] OR hydradenom*[tiab] OR hypernephrom*[tiab] OR IARC[tiab] OR immunocytom*[tiab] OR insulinom*[tiab] OR leiomyo*[tiab] OR lesion*[tiab] OR leukaemia*[tiab] OR leukemia*[tiab] OR leukoplak*[tiab] OR leukostas*[tiab] OR leukostasis[mh] OR lipoadenom*[tiab] OR lipoblastom*[tiab] OR lipom*[tiab] OR liposarcom*[tiab] OR luteinom*[tiab] OR luteom*[tiab] OR lymphangio*[tiab] OR lymphoepitheliom*[tiab] OR lymphom*[tiab] OR lymphoscintigraph*[tiab] OR macroglobulinem*[tiab] OR macroprolactinom*[tiab] OR malignan*[tiab] OR maltom*[tiab] OR masculinovoblastom*[tiab] OR mastocyto*[tiab] OR mcf-7[tiab] OR medullo*[tiab] OR meigs syndrome[tiab] OR melanoa*[tiab] OR melanocytom*[tiab] OR melanom*[tiab] OR meningio*[tiab] OR mesenchymom*[tiab] OR mesonephrom*[tiab] OR mesotheliom*[tiab] OR metaplas*[tiab] OR metaplasia[mh] OR metastas*[tiab] OR metastat*[tiab] OR microgliom*[tiab] OR micrometastas*[tiab] OR mucositis[mh] OR mycosis fungoides*[tiab] OR myelodysplas*[tiab] OR myelodysplastic syndromes[mh] OR myelodysplastic-myeloproliferative diseases[mh] OR myelofibrosis[tiab] OR myelol*[tiab] OR myeloma*[tiab] OR myeloproliferat*[tiab] OR myeloproliferative disorders[mh] OR myelosuppression*[tiab] OR myoblastom*[tiab] OR myoepitheliom*[tiab] OR myofibro*[tiab] OR myolipom*[tiab] OR myoma*[tiab] OR myosarcom*[tiab] OR myxof*[tiab] OR myxom*[tiab] OR naevus[tiab] OR neoplas*[tiab] OR neoplasm proteins[mh] OR neoplasms[mh] OR neoplastic stem cells[mh] OR nephroblastom*[tiab] OR neurilem*[tiab] OR neurinom*[tiab] OR neuroblastom*[tiab] OR neurocytom*[tiab] OR neuroepitheliom*[tiab] OR neurofibro*[tiab] OR neurolipocytom*[tiab] OR neuroma*[tiab] OR neuronevus[tiab] OR neurothekeom*[tiab] OR nevus[tiab] OR non coding RNA[tiab] OR nonseminom*[tiab] OR odontoam*[tiab] OR odontom*[tiab] OR oligoastrocytom*[tiab] OR oligodendrogliom*[tiab] OR oncocytom*[tiab] OR oncogen*[tiab] OR oncogene fusion[mh] OR oncogene proteins[mh] OR oncogenic viruses[mh] OR oncolog*[tiab] OR oncolytic viruses[mh] OR oncoprotein*[tiab] OR opsoclonus-myoclonus[tiab] OR orchioblastom*[tiab] OR osteoblastom*[tiab] OR osteoch*[tiab] OR osteofibrosarcom*[tiab] OR osteom*[tiab] OR osteosarcom*[tiab] OR pancreatoblastom*[tiab] OR papillom*[tiab] OR parachordom*[tiab] OR paragangliom*[tiab] OR paraneoplas*[tiab] OR perineuriom*[tiab] OR phaeochromocytom*[tiab] OR pheochromo*[tiab] OR pilomatri*[tiab] OR plasmacytom*[tiab] OR pneumoblast*[tiab] OR pneumocytom*[tiab] OR polyembryom*[tiab] OR polyhistiom*[tiab] OR polyp[tiab] OR polyps[mh] OR porocarcinom*[tiab] OR porom*[tiab] OR pre-cancer*[tiab] OR precancer*[tiab] OR preleukaem*[tiab] OR preleukem*[tiab] OR prelymphom*[tiab] OR pre-lymphom*[tiab] OR pre-malign*[tiab] OR premalignan*[tiab] OR preneoplas*[tiab] OR pre-neoplas*[tiab] OR prolactinom*[tiab] OR protooncogen*[tiab] OR pseudotum*[tiab] OR reninom*[tiab] OR retinoblastom*[tiab] OR rhabdo*[tiab] OR RNA, neoplasm[mh] OR sarcoma*[tiab] OR schwannom*[tiab] OR SEER program[mh] OR seminom*[tiab] OR sentinel lymph node[tiab] OR sentinel lymph node biopsy[mh] OR sertoli-leydig cell tumor[tiab] OR sezary syndrome[tiab] OR somatostatinom*[tiab] OR somatotropinom*[tiab] OR spermatocytom*[tiab] OR spiradenom*[tiab] OR spongioblastom*[tiab] OR subependymom*[tiab] OR thecom*[tiab] OR thymom*[tiab] OR trichilemmom*[tiab] OR trichoadenom*[tiab] OR trichoblastom*[tiab] OR trichodiscom*[tiab] OR trichoepitheliom*[tiab] OR trichofolliculom*[tiab] OR tricholemm*[tiab] OR tumor[tiab] OR tumor markers, biological[mh] OR tumorgen*[tiab] OR tumorig*[tiab] OR tumor-inhibit*[tiab] OR tumorog*[tiab] OR tumors[tiab] OR tumors[tiab] OR tumour[tiab] OR up-regulat*[tiab] OR vipom*[tiab] OR waldenstrom*[tiab] OR xanthoma*[tiab])

Table A-2 Cochrane and DARE (Database of Abstracts of Reviews of Effects) Database Search Terms

Set | Search Strategy
Exposure/Progestogens | (exogenous-progesterone OR Algestone OR Algestone-acetophenide OR Allylestrenol OR Chlormadinone-acetate OR cyproterone-acetate OR desogestrel OR dydrogesterone OR Ethisterone OR ethynodiol-diacetate OR Flurogestone-acetate OR Gestonorone-caproate OR Gestrinone OR Levonorgestrel OR Lynestrenol OR medrogestone OR medroxyprogesterone-acetate OR Megestrol-acetate OR Norethindrone OR norethynodrel OR Norgestrel OR Promegestone OR 11-hydroxyprogesterone OR 17-alpha-hydroxy-progesterone-caproate OR 17-alpha-hydroxyprogesterone-caproate OR 17-hydroxyprogesterone-caproate OR Demegestone OR Dienogest OR Drospirenone OR Etonogestrel OR Gestodene OR Nomegestrol-acetate OR Norelgestromin OR Norethindrone-acetate OR Norgestimate OR ST-1435 OR Trimegestone OR progesterone OR progestins OR progestogens OR progestogen OR Hydroxyprogesterone-caproate)
Window of Exposure | AND (babies OR baby OR child* OR embryo OR embryonic OR embryos OR fetal OR fetus OR foetal OR gestation* OR infant* OR in-utero OR maternal OR neonat* OR newborn* OR offspring OR perinat* OR postnat* OR prenat* OR progeny OR pups)