# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: https://doi.org/10.22427/NTP-RR-16

Report Series: NTP Research Report Series

Report Series Number: 16

Official citation: Boyd WA, Blain RB, Skuce CR, Thayer KA, Rooney AA. 2020. NTP research report on the scoping review of paraquat dichloride exposure and Parkinson’s disease. Research Triangle Park, NC: National Toxicology Program. Research Report 16.