# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Research Report on the Scoping Review of Paraquat Dichloride Exposure and Parkinson’s Disease by letter in April 2019 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the draft NTP Research Report on the Scoping Review of Paraquat Dichloride Exposure and Parkinson’s Disease and comment on the adequacy of the scoping report in identifying and summarizing the relevant literature.

NTP carefully considered reviewer comments in finalizing this report.

## Peer Reviewers

- Russell L. Carr, Ph.D.
  Associate Professor
  Mississippi State University
  Mississippi State, Mississippi, USA
- Marian S. McDonagh, Pharm.D.
  Professor
  Oregon Health & Science University
  Portland, Oregon, USA