# References

Ahmed H, Abushouk AI, Gabr M, Negida A, Abdel-Daim MM. 2017. Parkinson’s disease and pesticides: A meta-analysis of disease connection and genetic alterations. Biomed Pharmacother. 90:638–649. 10.1016/j.biopha.2017.03.100 28412655
Baltazar MT, Dinis-Oliveira RJ, de Lourdes Bastos M, Tsatsakis AM, Duarte JA, Carvalho F. 2014. Pesticides exposure as etiological factors of Parkinson’s disease and other neurodegenerative diseases—a mechanistic approach. Toxicol Lett. 230(2):85–103. 10.1016/j.toxlet.2014.01.039 24503016
Bromilow RH. 2004. Paraquat and sustainable agriculture. Pest Manag Sci. 60(4):340–349. 10.1002/ps.823 15119596
Brouwer M, Huss A, van der Mark M, Nijssen PCG, Mulleners WM, Sas AMG, van Laar T, de Snoo GR, Kromhout H, Vermeulen RCH. 2017. Environmental exposure to pesticides and the risk of Parkinson’s disease in the Netherlands. Environ Int. 107:100–110. 10.1016/j.envint.2017.07.001 28704700
Caroleo MC, Rispoli V, Arbitrio M, Strongoli C, Rainaldi G, Rotiroti D, Nistico G. 1996. Chronic administration of paraquat produces immunosuppression of T lymphocytes and astrocytosis in rats. Toxic Subst Mech. 15(3):183–194.
Chen Q, Niu Y, Zhang R, Guo H, Gao Y, Li Y, Liu R. 2010. The toxic influence of paraquat on hippocampus of mice: Involvement of oxidative stress. Neurotoxicology. 31(3):310–316. 10.1016/j.neuro.2010.02.006 20211647
Choi J, Polcher A, Joas A. 2016. Systematic literature review on Parkinson’s disease and Childhood Leukaemia and mode of actions for pesticides. EFSA J. 13(1):955E.10.2903/sp.efsa.2016.EN-955
Costello S, Cockburn M, Bronstein J, Zhang X, Ritz B. 2009. Parkinson’s disease and residential exposure to maneb and paraquat from agricultural applications in the central valley of California. Am J Epidemiol. 169(8):919–926. 10.1093/aje/kwp006 19270050
Dhillon AS, Tarbutton GL, Levin JL, Plotkin GM, Lowry LK, Nalbone JT, Shepherd S. 2008. Pesticide/environmental exposures and Parkinson’s disease in East Texas. J Agromed. 13(1):37–48. 10.1080/10599240801986215 19042691
Dinis-Oliveira RJ, Duarte JA, Sanchez-Navarro A, Remiao F, Bastos ML, Carvalho F. 2008. Paraquat poisonings: Mechanisms of lung toxicity, clinical features, and treatment. Crit Rev Toxicol. 38(1):13–71. 10.1080/10408440701669959 18161502
Engel LS, Checkoway H, Keifer MC, Seixas NS, Longstreth WT Jr, Scott KC, Hudnell K, Anger WK, Camicioli R. 2001. Parkinsonism and occupational exposure to pesticides. Occup Environ Med. 58(9):582–589. 10.1136/oem.58.9.582 11511745
Firestone JA, Lundin JI, Powers KM, Smith-Weller T, Franklin GM, Swanson PD, Longstreth WT Jr, Checkoway H. 2010. Occupational factors and risk of Parkinson’s disease: A population-based case-control study. Am J Ind Med. 53(3):217–223. 10.1002/ajim.20788 20025075
Firestone JA, Smith-Weller T, Franklin G, Swanson P, Longstreth WT Jr, Checkoway H. 2005. Pesticides and risk of Parkinson disease: A population-based case-control study. Arch Neurol. 62(1):91–95. 10.1001/archneur.62.1.91 15642854
Fredriksson A, Fredriksson M, Eriksson P. 1993. Neonatal exposure to paraquat or MPTP induces permanent changes in striatum dopamine and behavior in adult mice. Toxicol Appl Pharmacol. 122(2):258–264. 10.1006/taap.1993.1194 8212007
Furlong M, Tanner CM, Goldman SM, Bhudhikanok GS, Blair A, Chade A, Comyns K, Hoppin JA, Kasten M, Korell M, 2015. Protective glove use and hygiene habits modify the associations of specific pesticides with Parkinson’s disease. Environ Int. 75:144–150. 10.1016/j.envint.2014.11.002 25461423
Gatto NM, Cockburn M, Bronstein J, Manthripragada AD, Ritz B. 2009. Well-water consumption and Parkinson’s disease in rural California. Environ Health Perspect. 117(12):1912–1918. 10.1289/ehp.0900852 20049211
Gatto NM, Rhodes SL, Manthripragada AD, Bronstein J, Cockburn M, Farrer M, Ritz B. 2010. alpha-Synuclein gene may interact with environmental factors in increasing risk of Parkinson’s disease. Neuroepidemiology. 35(3):191–195. 10.1159/000315157 20664293
Goldman SM, Kamel F, Ross GW, Bhudhikanok GS, Hoppin JA, Korell M, Marras C, Meng C, Umbach DM, Kasten M, 2012. Genetic modification of the association of paraquat and Parkinson’s disease. Mov Disord. 27(13):1652–1658. 10.1002/mds.25216 23045187
Hertzman C, Wiens M, Bowering D, Snow B, Calne D. 1990. Parkinson’s disease: A case-control study of occupational and environmental risk factors. Am J Ind Med. 17(3):349–355. 10.1002/ajim.4700170307 2305814
Hertzman C, Wiens M, Snow B, Kelly S, Calne D. 1994. A case-control study of Parkinson’s disease in a horticultural region of British Columbia. Mov Disord. 9(1):69–75. 10.1002/mds.870090111 8139607
Higgins JPT, Green S. 2011. Cochrane handbook for systematic reviews of interventions. John Wiley & Sons.
Kamel F, Goldman SM, Umbach DM, Chen H, Richardson G, Barber MR, Meng C, Marras C, Korell M, Kasten M, 2014. Dietary fat intake, pesticide use, and Parkinson’s disease. Parkinsonism Relat Disord. 20(1):82–87. 10.1016/j.parkreldis.2013.09.023 24120951
Kamel F, Tanner CM, Umbach DM, Hoppin JA, Alavanja MCR, Blair A, Comyns K, Goldman SM, Korell M, Langston JW, 2007. Pesticide exposure and self-reported Parkinson’s disease in the agricultural health study. Am J Epidemiol. 165(4):364–374. 10.1093/aje/kwk024 17116648
Kang GA, Bronstein JM, Masterman DL, Redelings M, Crum JA, Ritz B. 2005. Clinical characteristics in early Parkinson’s disease in a central California population-based study. Mov Disord. 20(9):1133–1142. 10.1002/mds.20513 15954133
Lee PC, Bordelon Y, Bronstein J, Ritz B. 2012. Traumatic brain injury, paraquat exposure, and their relationship to Parkinson disease. Neurology. 79(20):2061–2066. 10.1212/WNL.0b013e3182749f28 23150532
Li HF, Zhao SX, Xing BP, Sun ML. 2015. Ulinastatin suppresses endoplasmic reticulum stress and apoptosis in the hippocampus of rats with acute paraquat poisoning. Neural Regen Res. 10(3):467–472. 10.4103/1673-5374.153698 25878598
Liou HH, Tsai MC, Chen CJ, Jeng JS, Chang YC, Chen SY, Chen RC. 1997. Environmental risk factors and Parkinson’s disease: A case-control study in Taiwan. Neurology. 48(6):1583–1588. 10.1212/WNL.48.6.1583 9191770
Lou D, Wang Q, Huang M, Zhou Z. 2016. Does age matter? Comparison of neurobehavioral effects of paraquat exposure on postnatal and adult C57BL/6 mice. Toxicol Mech Methods. 26(9):667–673. 10.1080/15376516.2016.1223241 27687147
Luty S, Lutaszyńska J, Halliop J, Tochman A, Obuchowska D, Korczak B, Przylepa E, Bychawski E. 1997. Dermal toxicity of paraquat. Ann Agric Environ Med. 4(2):217–227.
Malagelada C, Greene LA. 2008. Chapter 29, PC12 Cells as a model for parkinson’s disease research. In: Nass R, Przedborski S, editors. Parkinson’s Disease: Molecular and Therapeutic Insights From Model Systems. San Diego: Academic Press; p. 375–387. 10.1016/B978-0-12-374028-1.00029-4
Minnema DJ, Travis KZ, Breckenridge CB, Sturgess NC, Butt M, Wolf JC, Zadory D, Beck MJ, Mathews JM, Tisdel MO, 2014. Dietary administration of paraquat for 13 weeks does not result in a loss of dopaminergic neurons in the substantia nigra of C57BL/6J mice. Regul Toxicol Pharmacol. 68(2):250–258. 10.1016/j.yrtph.2013.12.010 24389362
Moher D, Liberati A, Tetzlaff J, Altman DG. 2009. Preferred reporting items for systematic reviews and meta-analyses: The PRISMA statement. PLoS Med. 6(7):e1000097. 10.1371/journal.pmed.1000097 19621072
National Institutes of Health (NIH).2018. ChemIDplus. U.S. Department of Health & Human Services, National Institutes of Health, National Toxicology Program. https://chem.nlm.nih.gov/chemidplus/. [Accessed: May 24, 2018]
National Toxicology Program (NTP).2015. Handbook for conducting a literature-based health assessment using ohat approach for systematic review and evidence integration. Research Triangle Park, NC: National Institute of Environmental Health Sciences, Office of Health Assessment and Translation, Division of the National Toxicology Program. https://ntp.niehs.nih.gov/go/38673.
National Toxicology Program (NTP).2019a. Health Assessment Workspace Collaborative (HAWC) page on paraquat and Parkinson's disease. https://hawcproject.org/assessment/475/.
National Toxicology Program (NTP).2019 b. Tableau page on the scoping review of paraquat dichloride and Parkinson’s disease. https://public.tableau.com/profile/ntp.visuals#!/vizhome/ParaquatandParkinsonsDisease/ReadMe.
Naudet N, Antier E, Gaillard D, Morignat E, Lakhdar L, Baron T, Bencsik A. 2017. Oral exposure to paraquat triggers earlier expression of phosphorylated alpha-synuclein in the enteric nervous system of A53T mutant human alpha-synuclein transgenic mice. J Neuropathol Exp Neurol. 76(12):1046–1057. 10.1093/jnen/nlx092 29040593
Peled-Kamar M, Lotem J, Wirguin I, Weiner L, Hermalin A, Groner Y. 1997. Oxidative stress mediates impairment of muscle function in transgenic mice with elevated level of wild-type Cu/Zn superoxide dismutase. Proc Natl Acad Sci USA. 94(8):3883–3887. 10.1073/pnas.94.8.3883 9108073
Pouchieu C, Piel C, Carles C, Gruber A, Helmer C, Tual S, Marcotullio E, Lebailly P, Baldi I. 2018. Pesticide use in agriculture and Parkinson’s disease in the AGRICAN cohort study. Int J Epidemiol. 47(1):299–310. 10.1093/ije/dyx225 29136149
Ranjbar A, Pasalar P, Sedighi A, Abdollahi M. 2002. Induction of oxidative stress in paraquat formulating workers. Toxicol Lett. 131(3):191–194. 10.1016/S0378-4274(02)00033-4 11992738
Ren JP, Zhao YW, Sun XJ. 2009. Toxic influence of chronic oral administration of paraquat on nigrostriatal dopaminergic neurons in C57BL/6 mice. Chin Med J (Engl). 122(19):2366–2371. 10.1016/S0161-813X(03)00057-3 20079141
Rojo AI, Cavada C, de Sagarra MR, Cuadrado A. 2007. Chronic inhalation of rotenone or paraquat does not induce Parkinson’s disease symptoms in mice or rats. Exp Neurol. 208(1):120–126. 10.1016/j.expneurol.2007.07.022 17880941
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Sanders LH, Paul KC, Howlett EH, Lawal H, Boppana S, Bronstein JM, Ritz B, Greenamyre JT. 2017. Editor’s highlight: Base excision repair variants and pesticide exposure increase Parkinson’s disease risk. Toxicol Sci. 158(1):188–198. 10.1093/toxsci/kfx086 28460087
Satpute RM, Pawar PP, Puttewar S, Sawale SD, Ambhore PD. 2017. Effect of resveratrol and tetracycline on the subacute paraquat toxicity in mice. Hum Exp Toxicol. 36(12):1303–1314. 10.1177/0960327116688070 28090784
Tanner CM, Kamel F, Ross GW, Hoppin JA, Goldman SM, Korell M, Marras C, Bhudhikanok GS, Kasten M, Chade AR, 2011. Rotenone, paraquat, and Parkinson’s disease. Environ Health Perspect. 119(6):866–872. 10.1289/ehp.1002839 21269927
Tanner CM, Ross GW, Jewell SA, Hauser RA, Jankovic J, Factor SA, Bressman S, Deligtisch A, Marras C, Lyons KE, 2009. Occupation and risk of Parkinsonism a multicenter case-control study. Arch Neurol. 66(9):1106–1113. 10.1001/archneurol.2009.195 19752299
Tomenson JA, Campbell C. 2011. Mortality from Parkinson’s disease and other causes among a workforce manufacturing paraquat: A retrospective cohort study. BMJ Open. 1(2):e000283. 10.1136/bmjopen-2011-000283 22080539
U.S. Environmental Protection Agency (US EPA). 1976. The effects of pesticide exposure on the life span of a selected segment of the population: Work Unit E-31 Final Report. Washington, DC: U. S. Environmental Protection Agency, ESP, Human Effects Monitoring Branch, Technical Services Division.
U.S. Environmental Protection Agency (US EPA). 1997. Reregistration eligibility decision document: Paraquat dichloride. Washington, DC: U.S. Environmental Protection Agency, Office of Pesticide Programs, Special Review and Reregistration Division. EPA-738-F-96-018
Vaccari C, El Dib R, Gomaa H, Lopes LC, de Camargo JL. 2019. Paraquat and Parkinson’s disease: A systematic review and meta-analysis of observational studies. J Toxicol Environ Health B Crit Rev. 22(5-6):172–202. 10.1080/10937404.2019.1659197 31476981
van der Mark M, Vermeulen R, Nijssen PC, Mulleners WM, Sas AM, van Laar T, Brouwer M, Huss A, Kromhout H. 2014. Occupational exposure to pesticides and endotoxin and Parkinson disease in the Netherlands. Occup Environ Med. 71(11):757–764. 10.1136/oemed-2014-102170 25104429
Wan N, Lin G. 2016. Parkinson’s disease and pesticides exposure: New findings from a comprehensive study in Nebraska, USA. J Rural Health. 32(3):303–313. 10.1111/jrh.12154 26515233
Wang A, Costello S, Cockburn M, Zhang X, Bronstein J, Ritz B. 2011. Parkinson’s disease risk from ambient exposure to pesticides. Eur J Epidemiol. 26(7):547–555. 10.1007/s10654-011-9574-5 21505849
Widdowson PS, Farnworth MJ, Upton R, Simpson MG. 1996. No changes in behaviour, nigro-striatal system neurochemistry or neuronal cell death following toxic multiple oral paraquat administration to rats. Hum Exp Toxicol. 15(7):583–591. 10.1177/096032719601500706 8818712
Wu B, Song B, Tian S, Huo S, Cui C, Guo Y, Liu H. 2012. Central nervous system damage due to acute paraquat poisoning: A neuroimaging study with 3.0 T MRI. Neurotoxicology. 33(5):1330–1337. 10.1016/j.neuro.2012.08.007 22947519
Zhang XF, Thompson M, Xu YH. 2016. Multifactorial theory applied to the neurotoxicity of paraquat and paraquat-induced mechanisms of developing Parkinson’s disease. Lab Invest. 96(5):496–507. 10.1038/labinvest.2015.161 26829122